# Appendix B: Advisory Meeting Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

H. Westley Clark, M.D., J.D., M.P.H., CAS, FASAM
Director
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Mady Chalk, Ph.D.
Director
Division of Services Improvement
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Christina Currier
Public Health Analyst
Practice Improvement Branch
Division of Services Improvement
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Michael T. Flaherty, Ph.D.
Northeast Addiction Technology Transfer Center
Institute for Research, Education and Training in Addictions
Pittsburgh, Pennsylvania

Kevin Hennessy, Ph.D.
Science to Service Coordinator
Substance Abuse and Mental Health Services Administration/OPPB
Rockville, Maryland

Constance M. Pechura, Ph.D.
Senior Program Officer
Robert Wood Johnson Foundation
Princeton, New Jersey

Richard A. Rawson, Ph.D.
Pacific Southwest Addiction Technology Transfer Center
Los Angeles, California

Jack B. Stein, Ph.D.
Acting Deputy Director
Division of Epidemiology, Services, and Prevention Research
National Institute on Drug Abuse
National Institutes of Health
Bethesda, Maryland

Richard T. Suchinsky, M.D.
Associate Chief for Addictive Disorders
Mental Health and Behavioral Sciences Service
U.S. Department of Veteran Affairs
Washington, D.C.

Karl D. White, Ed.D.
Public Health Analyst
Practice Improvement Branch
Division of Services Improvement
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Mark Willenbring, M.D.
Director
Division of Treatment and Recovery Research
National Institute on Alcohol Abuse and Alcoholism
National Institutes of Health
Bethesda, Maryland