# Appendix A: Bibliography

Addiction Technology Transfer Center. (2004). The change book: A blueprint for technology transfer (2nd ed.). Kansas City, MO: Author. Retrieved February 5, 2008, from http://www.nattc.org/pdf/The_Change_Book_2nd_Edition.pdf
American Association of Suicidology (2006). Assessment and management of suicide risk: Core competencies for mental health professionals. Participant manual. Washington, DC: Education Development Center.
American Psychiatric Association. (2003). Practice guideline and resources for the assessment and treatment of patients with suicidal behaviors. Arlington, VA: American Psychiatric Association. Retrieved July 2, 2008, from http://www.psychiatryonline.com/pracGuide/pracGuideHome.aspx.
Beck, A. T., Resnik, H. L. P., Lettieri, D. J., Pennsylvania University Department of Psychiatry, et al. (1974). The prediction of suicide. Bowie, MD: Charles Press Publishers.
Beck, A. T., Schuyler, D., & Herman, I. (1974). Development of suicidal intent scales. In A. T. Beck, H. L. P. Resnik, & D. J. Lettieri, (Eds.), The prediction of suicide (pp. 45–56). Bowie, MD: Charles Press Publishers.
Beck, A. T., Steer, R. A., & Brown, G. K. (1996). Beck Depression Inventory - II Manual. San Antonio, TX: The Psychological Corporation.
Beck, A. T., Ward, C. H., Mendelson, M., Mock, J., & Erbaugh, J. (1961). An inventory for measuring depression. Archives of General Psychiatry, 4, 561–571.13688369
Berk, M. S., Henriques, G. R., Warman, D. M., Brown, G. K., & Beck, A. T. (2004). A cognitive therapy intervention for suicide attempters: An overview of the treatment and case examples. Cognitive and Behavioral Practice, 11, 265–277.
Bongar, B. M. (1991). Suicide: Legal perspectives. In The suicidal patient: Clinical and legal standards of care (pp. 33–59). Washington, DC: American Psychological Association.
Bossarte, R. M., Simon, T. R., & Barker, L. (2006). Characteristics of homicide followed by suicide incidents in multiple states, 2003-04. Injury Prevention, 12, ii33–ii38.17170169
Brown, G. K., Henriques, G. R., Sosdjan, D., & Beck, A. T. (2004). Suicide intent and accurate expectations of lethality: Predictors of medical lethality of suicide attempts. Journal of Consulting and Clinical Psychology, 72, 1170–1174.15612863
Brown, G. K., Steer, R. A., Henriques, G. R., & Beck, A. T. (2005). The internal struggle between the wish to die and the wish to live: a risk factor for suicide. American Journal of Psychiatry, 162, 1977–1979.
Brown, G. K., Ten Have, H. T., Henriques, G. R., Xie, S. X., Hollander, J. E., & Beck, A. T. (2005). Cognitive therapy for the prevention of suicide attempts: A randomized controlled trial. JAMA, 294, 563–570.16077050
Brown, S. A., Inaba, R. K., Gillin, J. C., Schuckit, M. A., Stewart, M. A., & Irwin, M. R. (1995). Alcoholism and affective disorder: Clinical course of depressive symptoms. American Journal of Psychiatry, 152, 45–52.
Bucholz, K. K., Cadoret, R., Cloninger, C. R., Dinwiddie, S. H., Hesselbrock, V. M., Nurnberger, J. I., Jr., et al. (1994). A new, semi-structured psychiatric interview for use in genetic linkage studies: A report on the reliability of the SSAGA. Journal of Studies on Alcohol, 55, 149–158.8189735
Center for Substance Abuse Treatment. (1993a). Improving treatment for drug-exposed infants. Treatment Improvement Protocol (TIP) Series 5. (DHHS Publication No. (SMA) 95-3057). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1993b). Pregnant, substance-using women. Treatment Improvement Protocol (TIP) Series 2. (DHHS Publication No. (SMA) 93-1998). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1993c). Screening for infectious diseases among substance abusers. Treatment Improvement Protocol (TIP) Series 6. (DHHS Publication No. (SMA) 95-3060). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1994). Simple screening instruments for outreach for alcohol and other drug abuse and infectious diseases. Treatment Improvement Protocol (TIP) Series 11. (DHHS Publication No. (SMA) 94-2094). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1995a). Alcohol and other drug screening of hospitalized trauma patients. Treatment Improvement Protocol (TIP) Series 16. (DHHS Publication No. (SMA) 95-3041). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1995b). Combining alcohol and other drug treatment with diversion for juveniles in the justice system. Treatment Improvement Protocol (TIP) Series 21. (DHHS Publication No. (SMA) 95-3051). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1995c). Developing state outcomes monitoring systems for alcohol and other drug abuse treatment. Treatment Improvement Protocol (TIP) Series 14. (DHHS Publication No. (SMA) 95-3031). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1995d). The role and current status of patient placement criteria in the treatment of substance use disorders. Treatment Improvement Protocol (TIP) Series 13. (DHHS Publication No. (SMA) 95-3021). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1995e). The tuberculosis epidemic: Legal and ethical issues for alcohol and other drug abuse treatment providers. Treatment Improvement Protocol (TIP) Series 18. (DHHS Publication No. (SMA) 95-3047). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1996). Treatment drug courts: Integrating substance abuse treatment with legal case processing. Treatment Improvement Protocol (TIP) Series 23. (DHHS Publication No. (SMA) 96-3113). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1997a). A guide to substance abuse services for primary care clinicians. Treatment Improvement Protocol (TIP) Series 24. (DHHS Publication No. (SMA) 97-3139). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1997b). Substance abuse treatment and domestic violence. Treatment Improvement Protocol (TIP) Series 25. (DHHS Publication No. (SMA) 97-3163). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1998a). Comprehensive case management for substance abuse treatment. Treatment Improvement Protocol (TIP) Series 27. (DHHS Publication No. (SMA) 98-3222). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1998b). Continuity of offender treatment for substance use disorders from institution to community. Treatment Improvement Protocol (TIP) Series 30. (DHHS Publication No. (SMA) 98-3245). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1998c). Naltrexone and alcoholism treatment. Treatment Improvement Protocol (TIP) Series 28. (DHHS Publication No. (SMA) 98-3206). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1998d). Substance abuse among older adults. Treatment Improvement Protocol (TIP) Series 26. (DHHS Publication No. (SMA) 98-3179). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1998e). Substance use disorder treatment for people with physical and cognitive disabilities. Treatment Improvement Protocol (TIP) Series 29. (DHHS Publication No. (SMA) 98-3249). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1999a). Brief interventions and brief therapies for substance abuse. Treatment Improvement Protocol (TIP) Series 34. (DHHS Publication No. (SMA) 99-3353). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1999b). Enhancing motivation for change in substance abuse treatment. Treatment Improvement Protocol (TIP) Series 35. (DHHS Publication No. (SMA) 99-3354). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1999c). Screening and assessing adolescents for substance use disorders. Treatment Improvement Protocol (TIP) Series 31. (DHHS Publication No. (SMA) 99-3282). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1999d). Treatment of adolescents with substance use disorders. Treatment Improvement Protocol (TIP) Series 32. (DHHS Publication No. (SMA) 99-3283). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1999e). Treatment for stimulant use disorders. Treatment Improvement Protocol (TIP) Series 33. (DHHS Publication No. (SMA) 99-3296). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2000a). Integrating substance abuse treatment and vocational services. Treatment Improvement Protocol (TIP) Series 38. (DHHS Publication No. (SMA) 00-3470). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2000b). Substance abuse treatment for persons with child abuse and neglect issues. Treatment Improvement Protocol (TIP) Series 36. (DHHS Publication No. (SMA) 00-3357). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2000c). Substance abuse treatment for persons with HIV/AIDS. Treatment Improvement Protocol (TIP) Series 37. (DHHS Publication No. (SMA) 00-3459). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2004a). Clinical guidelines for the use of Buprenorphine in the treatment of opioid addiction. Treatment Improvement Protocol (TIP) Series 40. (DHHS Publication No. (SMA) 04-3939). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2004b). Substance abuse treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. (DHHS Publication No. (SMA) 04-3957). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2005a). Medication-assisted treatment for opioid addiction. Treatment Improvement Protocol (TIP) Series 43. (DHHS Publication No. SMA 05-4048). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2005b). Substance abuse treatment for adults in the criminal justice system. Treatment Improvement Protocol (TIP) Series 44. (DHHS Publication No. (SMA) 05-4056). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2005c). Substance abuse treatment: Group therapy. Treatment Improvement Protocol (TIP) Series 41. (DHHS Publication No. SMA 05-4056). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2005d). Substance abuse treatment for persons with co-occurring disorders. Treatment Improvement Protocol (TIP) Series 42. (DHHS Publication No. SMA 05-3992). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2006a). Detoxification and substance abuse treatment. Treatment Improvement Protocol (TIP) Series 45. (DHHS Publication No. SMA 06-4131). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2006b). Substance abuse: Administrative issues in intensive outpatient treatment. Treatment Improvement Protocol (TIP) Series 46. (DHHS Publication No. SMA 06-4151). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2006c). Substance abuse: Clinical issues in intensive outpatient treatment. Treatment Improvement Protocol (TIP) Series 47. (DHHS Publication No. 06-4182). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development a). Addressing suicidal thoughts and behaviors with clients in substance abuse treatment. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development b). Incorporating alcohol pharmacotherapies into medical practice. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development c). Improving cultural competence in substance abuse treatment. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development d). Management of chronic pain in people with substance use disorders. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development e). Managing depressive symptoms in substance abuse clients during early recovery. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development f). Relapse prevention and recovery promotion. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development g). Substance abuse treatment: Addressing the specific needs of women. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development h). Substance abuse treatment with American Indians and Alaska Natives. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development i). Substance abuse treatment and men's issues. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development j). Substance abuse treatment with people who are homeless. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development k). Substance abuse treatment and trauma. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development l). Supervision and the professional development of the substance abuse counselor. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (In development m). Viral hepatitis and substance use disorders. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Centers for Disease Control and Prevention. (1998). Suicide among African American youths—United States, 1980–1995. Morbidity and Mortality Weekly Report, 47, 193–196.9531022
Cherpitel, C. J., Borges, G. L., & Wilcox, H. C. (2004). Acute alcohol use and suicidal behavior: A review of the literature. Alcoholism: Clinical & Experimental Research, 28, 18S–28S.
Conner, K. R., Beautrais, A. L., & Conwell, Y. (2003). Risk factors for suicide and medically serious suicide attempts among alcoholics: Analyses of Canterbury Suicide Project data. Journal of Studies on Alcohol, 64, 551–554.12921197
Conner, K. R., Duberstein, P. R., & Conwell, Y. (2000). Domestic violence, separation, and suicide in young men with early onset alcoholism: Re-analyses of Murphy's data. Suicide and Life-Threatening Behavior, 30, 354–359.11210060
Conner, K. R., Duberstein, P. R., Conwell, Y., Herrmann, J. H., Jr., Cox, C., Barrington, D. S., et al. (2000). After the drinking stops: Completed suicide in individuals with remitted alcohol use disorders. Journal of Psychoactive Drugs, 32, 333–337.11061685
Conner, K. R., Hesselbrock, V. M., Meldrum, S. C., Schuckit, M. A., Bucholz, K. K., Gamble, S. A., et al. (2007). Transitions to, and correlates of, suicidal ideation, plans, and unplanned and planned suicide attempts among 3,729 men and women with alcohol dependence. Journal of Studies on Alcohol and Drugs, 68, 654–662.17690798
Conwell, Y., Duberstein, P. R., & Caine, E. D. (2002). Risk factors for suicide in later life. Biological Psychiatry, 52, 193–204.12182926
Cornelius, J. R., Salloum, I. M., Day, N. L., Thase, M. E., & Mann, J. J. (1996). Patterns of suicidality and alcohol use in alcoholics with major depression. Alcoholism, Clinical and Experimental Research, 20, 1451–1455.
Darke, S., & Ross, J. (2002). Suicide among heroin users: rates, risk factors and methods. Addiction, 97, 1383–1394.12410779
Duberstein, P. R., Conwell, Y., & Caine, E. D. (1993). Interpersonal stressors, substance abuse, and suicide. Journal of Nervous and Mental Disease, 181, 80–85.
Falvey, J. E. (2002). Managing clinical supervision: Ethical practice and legal risk management. Pacific Grove, CA: Brooks/Cole-Thomson Learning.
Fixsen, D. L., Naoom, S. F., Blase, K. A., Friedman, R. M., & Wallace, F. (2005). Implementation research: A synthesis of the literature. Tampa, FL: University of South Florida, Louis de la Parte Florida Mental Health Institute, The National Implementation Research Network. Retrieved November 19, 2007, from http://ctndisseminationlibrary.org/PDF/nirnmonograph.pdf
Goldsmith, S. K., Pellmar, T. C., Kleinman, A. M., & Bunney, W. E. (Eds.) Reducing suicide: A national imperative (2002). Washington, DC: National Academies Press.
Goldston, D. B., Molock, S. D., Whitbeck, L. B., Murakami, J. L., Zayas, L. H., & Hall, G. C. (2008). Cultural considerations in adolescent suicide prevention and psychosocial treatment. American Psychologist, 63, 14–31.
Gould, M. S., Marrocco, F. A., Kleinman, M., Thomas, J. G., Mostkoff, K., Cote, J., et al. (2005). Evaluating iatrogenic risk of youth suicide screening programs: a randomized controlled trial. JAMA, 293, 1635–1643.15811983
Gutheil, T. G., & Brodsky, A. (2008). Preventing boundary violations in clinical practice. New York: Guilford Press.
Hamilton, M. A. (1960). A rating scale for depression. Journal of Neurology, Neurosurgery, and Psychiatry, 23, 56–62.
Harriss, L., Hawton, K., & Zahl, D. (2005). Value of measuring suicidal intent in the assessment of people attending hospital following self-poisoning or self-injury. British Journal of Psychiatry, 186, 60–66.
Heikkinen, M. E., Aro, H. M., Henriksson, M. M., Isometsä, E. T., Sarna, S. J., Kuoppasalmi, K. I., et al. (1994). Differences in recent life events between alcoholic and depressive nonalcoholic suicides. Alcoholism: Clinical and Experimental Research, 18, 1143–1149.
Hendin, H., Haas, A. P., Maltsberger, J. T., Szanto, K., & Rabinowicz, H. (2004). Factors contributing to therapists'distress after the suicide of a patient. American Journal of Psychiatry, 161, 1442–1446.
Hendin, H., Lipschitz, A., Maltsberger, J. T., Haas, A. P., & Wynecoop, S. (2000). Therapists' reactions to patients' suicides. American Journal of Psychiatry, 157, 2022–2027.
Henriques, G., Beck, A. T., & Brown, G. K. (2003). Cognitive therapy for adolescent and young adult suicide attempters. American Behavioral Scientist, 46, 1258–1268.
Hufford, M. R. (2001). Alcohol and suicidal behavior. Clinical Psychology Review, 21, 797–811.11434231
Husband, S. D., Marlowe, D. B., Lamb, R. J., Iguchi, M. Y., Bux, D. A., Kirby, K. C., et al. (1996). Decline in self-reported dysphoria after treatment entry in inner-city cocaine addicts. Journal of Consulting and Clinical Psychology, 64, 221–224.8907102
Ilgen, M. A., Harris, A. H., Moos, R. H., & Tiet, Q. Q. (2007). Predictors of a suicide attempt one year after entry into substance use disorder treatment. Alcoholism: Clinical and Experimental Research, 31, 635–642.
Jobes, D. A. (2006). Managing suicidal risk: A collaborative approach. New York: Guilford Press.
Joe, S. (2003). Implications of focusing on black youth selfdestructive behaviors instead of suicide when designing preventative interventions. In D. Romer (Ed.), Reducing Adolescent Risk: Toward an Integrated Approach (pp. 325–332). Thousand Oaks, CA: Sage Publications.
Joe, S., Baser, R. E., Breeden, G. K., Neighbors, H. W., & Jackson, J. S. (2006). Prevalence of and risk factors for lifetime suicide attempts among blacks in the United States. JAMA, 296, 2112–2123.17077376
Joe, S., & Kaplan, M. S. (2002). Firearm-related suicide among young African-American males. Psychiatric Services, 53, 332–334.11875228
Joe, S., & Marcus, S. C. (2003). Trends by race and gender in suicide attempts among U.S. adolescents, 1991–2001. Psychiatric Services, 54, 454.12663832
Joe, S., Romer, D., & Jamieson, P. (2007). Suicide acceptability is related to suicidal behavior among U.S. adolescents. Suicide and Life Threatening Behavior, 37, 165–178.17521270
Kapur, N., Cooper, J., King-Hele, S., Webb, R., Lawlor, M., Rodway, C., et al. (2006). The repetition of suicidal behavior: A multi-center cohort study. Journal of Clinical Psychiatry, 67, 1599–1609.
Kessler, R. C., Borges, G., & Walters, E. E. (1999). Prevalence of and risk factors for lifetime suicide attempts in the National Comorbidity Survey. Archives of General Psychiatry, 56, 617–626.10401507
Linehan, M. M., Goodstein, J. L., Nielsen, S. L., & Chiles, J. A. (1983). Reasons for staying alive when you are thinking of killing yourself: The Reasons for Living Inventory. Journal of Consulting and Clinical Psychology, 51, 276–286.6841772
Linehan, M. M., Schmidt, H., III, Dimeff, L. A., Craft, J. C., Kanter, J., & Comtois, K. A. (1999). Dialectical behavior therapy for patients with borderline personality disorder and drug-dependence. American Journal on Addictions, 8, 279–292.
MacNeil, J. S. (2007). New JCAHO safety goal: Identify suicide risks. Clinical Psychiatry News, 35, 52–53.
Mann, J. J., Apter, A., Bertolote, J., Beautrais, A., Currier, D., Haas, A., et al. (2005). Suicide prevention strategies: A systematic review. JAMA, 294, 2064–2074.16249421
Maris, R. W., Berman, A. L., & Silverman, M. M. (2000a). Comprehensive textbook of suicidology. New York: The Guilford Press.
Maris, R. W., Berman, A. L., & Silverman, M. M. (2000b). Suicide and the law. In R. W. Maris, A. L. Berman, & M. M. Silverman (Eds.), Comprehensive textbook of suicidology (pp. 480–506). New York: The Guilford Press.
Marzuk, P. M., Tardiff, K., & Hirsch, C. S. (1992). The epidemiology of murder-suicide. JAMA, 267, 3179–3183.1593740
McLellan, A. T., Kushner, H., Metzger, D., Peters, R., Smith, I., Grissom, G., et al. (1992). The fifth edition of the Addiction Severity Index. Journal of Substance Abuse Treatment, 9, 199–213.1334156
Murphy, G. E., Armstrong, J. W., Hermele, S. L., Fischer, J. R., & Clendenin, W. W. (1979). Suicide and alcoholism: Interpersonal loss confirmed as a predictor. Archives of General Psychiatry, 36, 65–69.760697
Murphy, G. E., Wetzel, R. D., Robins, E., & McEvoy, L. (1992). Multiple risk factors predict suicide in alcoholism. Archives of General Psychiatry, 49, 459–463.1599370
National Center for Injury Prevention and Control (2007a). WISQARS fatal injuries: Leading causes of death reports. Atlanta, GA: Centers for Disease Control and Prevention. Retrieved May 30, 2007, from http://www.cdc.gov/injury/wisqars/fatal.html
National Center for Injury Prevention and Control (2007b). WISQARS nonfatal injuries reports. Atlanta, GA: Centers for Disease Control and Prevention. Retrieved June 30, 2008, from http://www.cdc.gov/injury/wisqars/nonfatal.html.
Nock, M. K., & Kessler, R. C. (2006). Prevalence of and risk factors for suicide attempts versus suicide gestures: Analysis of the National Comorbidity Survey. Journal of Abnormal Psychology, 115, 616–623.16866602
Ogbonna, E. & Harris, L. C. (1998). Organizational culture: It's not what you think. Journal of General Management, 23, 35–48.
Olson, L. M. & Wahab, S. (2006). American Indians and suicide: A neglected area of research. Trauma, Violence, & Abuse, 7, 19–33.
Oquendo, M. A., Dragasti, D., Harkavy-Friedman, J., Dervic, K., Currier, D., Burke, A. K., et al. (2005). Protective factors against suicidal behavior in Latinos. Journal of Nervous and Mental Disease, 193, 438–443.
Pokorny, A. D. (1983). Prediction of suicide in psychiatric patients: Report of a prospective study. Archives of General Psychiatry, 40, 249–257.6830404
Preuss, U. W., Schuckit, M. A., Smith, T. L., Danko, G. P., Buckman, K., Bierut, L., et al. (2002). Comparison of 3190 alcohol-dependent individuals with and without suicide attempts. Alcoholism: Clinical and Experimental Research, 26, 471–477.
Ries, R. K., Yuodelis-Flores, C., Comtois, K. A., Roy-Byrne, P. P., & Russo, J. E. (2008). Substance-induced suicidal admissions to an acute psychiatric service: characteristics and outcomes. Journal of Substance Abuse Treatment, 34, 72–79.17574802
Ross, J., Teesson, M., Darke, S., Lynskey, M., Ali, R., Ritter, A. et al. (2005). The characteristics of heroin users entering treatment: findings from the Australian treatment outcome study (ATOS). Drug and Alcohol Review, 24, 411–418.16298835
Roy, A. (2001). Characteristics of cocaine-dependent patients who attempt suicide. American Journal of Psychiatry, 158, 1215–1219.
Roy, A. (2002). Characteristics of opiate dependent patients who attempt suicide. Journal of Clinical Psychiatry, 63, 403–407.
Rudd, M. D. (2006). The assessment and management of suicidality. Sarasota, FL: Professional Resource Press.
Rudd, M. D., Berman, A. L., Joiner, T. E., Jr., Nock, M. K., Silverman, M. M., Mandrusiak, M., et al. (2006). Warning signs for suicide: Theory, research, and clinical applications. Suicide and Life-Threatening Behavior, 36, 255–262.16805653
Rudd, M. D., Mandrusiak, M., & Joiner Jr, T. E. (2006). The case against no-suicide contracts: The commitment to treatment statement as a practice alternative. Journal of Clinical Psychology, 62, 243–251.16342293
Rudd, M. D., Williamson, B., & Trotter, D. (in press). The psychological and behavioral treatment of suicidal behavior: What are the common elements of treatments that work? Oxford Textbook of Suicidology.
Schneider, M. (2002). A stakeholder model of organizational leadership. Organization Science, 13, 209–220.
Schneider, B., Georgi, K., Weber, B., Schnabel, A., Ackermann, H., & Wetterling, T. (2006). Risk factors for suicide in substance-related disorders. Psychiatrische Praxis, 33, 81–87.16502386
Shea, S. C. (2002). The practical art of suicide assessment: A guide for mental health professionals and substance abuse counselors. New York: John Wiley.
Shenassa, E. D., Catlin, S. N., & Buka, S. L. (2003). Lethality of firearms relative to other suicide methods: A population based study. Journal of Epidemiology and Community Health, 57, 120–124.12540687
Shneidman, E. S. (1985). Definition of suicide. New York: Wiley.
Silverman, M. M., Berman, A. L., Sanddal, N. D., O'Carroll, P. W., & Joiner, J. (2007). Rebuilding the Tower of Babel: A revised nomenclature for the study of suicide and suicidal behaviors: Part II: Suicide-related ideations, communications and behaviors. Suicide and Life-Threatening Behavior, 37, 264–277.17579539
Simon, R. I. (2007). Gun safety management with patients at risk for suicide. Suicide and Life-Threatening Behavior, 37, 518–526.17967118
Szanto, K., Gildengers, A., Mulsant, B. H., Brown, G., Alexopoulos, G. S., & Reynolds, C. F., III (2002). Identification of suicidal ideation and prevention of suicidal behaviour in the elderly. Drugs and Aging, 19, 11–24.11929324
Weiss, R. D., & Hufford, M. R. (1999). Substance abuse and suicide. In D. G. Jacobs (Ed.), The Harvard Medical School guide to suicide assessment and intervention (1st ed., pp. 300–310). San Francisco: Jossey-Bass.
Wenzel, A., Brown, G. K., & Beck, A. T. (in press). Cognitive therapy for suicidal patients: Scientific and clinical applications. Washington, DC: APA Books.
Wilcox, H. C., Conner, K. R., & Caine, E. D. (2004). Association of alcohol and drug use disorders and completed suicide: an empirical review of cohort studies. Drug and Alcohol Dependence, 76, S11–S19.15555812
Zayas, L. H., Lester, R. J., Cabassa, L. J., & Fortuna, L. R. (2005). Why do so many Latina teens attempt suicide? A conceptual model for research. American Journal of Orthopsychiatry, 75, 275–287.