# Chapter 1

## Introduction

This Treatment Improvement Protocol (TIP) is designed to assist not only substance abuse counselors in working with clients who are experiencing depressive symptoms (see Figure. 1.1), but also clinical supervisors and administrators who support the work of the counselors. Depressive symptoms are common among clients in substance abuse treatment (Grant, Stinson, Dawson, Chou, Dufour, Compton, et al., 2007). When depressive symptoms occur, they can complicate substance abuse treatment and interfere with recovery.

Figure 1-1. Depressive Symptoms and Related Feelings and Behaviors

The term “depressive symptoms” refers to symptoms experienced by people who, although failing to meet DSM-IV-TR diagnostic criteria for a mood disorder, experience sadness, depressed mood, “the blues,” or other related feelings and behaviors:

• Loss of interest in most activities
• Significant unintentional change in weight or appetite
• Sleep disturbances
• Decreased energy, chronic fatigue or tiredness, feeling exhausted
• Feelings of excessive guilt
• Feelings of low self-esteem, low self-confidence, or worthlessness
• Feelings of despair or hopelessness (pervasive pessimism about the future)
• Avoidance of normal familial and social contacts
• Frequent agitation, restlessness
• Psychologically or emotionally detached
• Feelings of irritability or frustration
• Decrease in activity, effectiveness, or productivity
• Difficulty in thinking (poor concentration, poor memory, or indecisiveness)
• Excessive or inappropriate worries
• Being easily moved to tears
• Anticipation of the worst
• Thoughts of suicide

The methods and techniques presented in this TIP are appropriate for clients in all stages of recovery. However, the focus of this TIP is on early recovery—that is, the first few months of treatment, when depressive symptoms are particularly common.

This TIP is not about treating any mood disorder that is defined in the Diagnostic and Statistical Manual of Mental Disorders, 4th edition, Text Revision (DSM-IV-TR; APA, 2000). Clients with diagnosed mood disorders (e.g., major depression, dysthymia, cyclothymia, bipolar disorder) need specialized treatment from a trained and licensed mental health professional. However, when treating the substance abuse issues of clients who have mood disorders, the substance abuse counselors' role is to (1) address how the depressive symptoms of the mood disorder interact with the substance abuse recovery treatment, and (2) develop a collaborative treatment relationship with the trained and licensed mental health professional who is directing the treatment for the mood disorders.

## Why SAMHSA Created an Implementation Guide as Part of This TIP

Managing Depressive Symptoms in Substance Abuse Clients During Early Recovery, Part 1, provides the tools your counselors need to address depressive symptoms with clients. However, an extensive literature review suggests that without specific attention to implementation issues, these tools are likely to go unused or to be used ineffectively (Fixsen, Naoom, Blase, Friedman, & Wallace, 2005). This Guide will help you ensure that the ideas in Part 1 are put into practice in your program or agency. Implementation will require the active support of executive administration and the expertise of clinical supervisors.

## Consensus Panel Recommendations for Administrators

Substance abuse counselors should be prepared to help clients manage their depressive symptoms because these symptoms can complicate treatment and recovery from substance use disorders. Administrators play an important role in ensuring that their programs incorporate this aspect of treatment. In particular, the Consensus Panel recommends the following:

• All substance abuse treatment programs should integrate screening and management of depressive symptoms into existing substance abuse treatment.
• Programs need to develop the capacity to differentiate clients with depressive symptoms from those with depressive illness and have resources in place to address the needs of both groups.
• Programs have a responsibility to develop a referral network that is capable of evaluating clients with depressive symptoms and receiving clients whose depressive symptoms cannot be managed in the substance abuse treatment setting.
• Adequate policies and procedures should be in place to serve clients with suicidal thoughts or behaviors.
• In clinical supervision, an emphasis should be placed on improving counselors' ability to recognize and manage clients' depressive symptoms.

## Why Address Depressive Symptoms?

### The Effects of Depressive Symptoms on Recovery

Clients with depressive symptoms may experience challenges to successful treatment above and beyond those experienced by clients who are not depressed (Conner, Sorensen, & Leonard, 2005; Curran, Flynn, Kirchner, & Booth, 2000; Dodge, Sindelar, & Sinha, 2005; Greenfield, Weiss, Muenz, Vagge, Kelly, Bello, et al., 1998; Strowig, 2000).

The client with depressive symptoms may have difficulty in any or all of the following areas:

• Ability to learn program rules or to follow instructions.
• Ability to keep appointments.
• Energy to participate in or maintain interest in program activities.
• Motivation for change.
• Ability to make appropriate decisions about treatment needs and goals.
• Belief that he or she can be helped.
• Responsiveness to reinforcements.
• Ability to handle feelings.
• Ability to handle relations with other clients.
• Ability to attend to (and not disrupt) group activities.
• Ability to stay substance-free after treatment is completed.

In summary, depressive symptoms may pose significant impediments to recovery. Addressing these symptoms is a necessary part of treating the whole person and may be a concern for meeting the client's recovery goals.

Depressive symptoms may easily be mistaken for resistance to treatment. It is essential that staff be able to discriminate between depression and treatment resistance. Depressed clients may well wish to be in recovery but lack the motivation and energy to take on the challenging tasks posed by participation in recovery programs.

### The Benefits to Your Program of Addressing Depressive Symptoms

Research clearly demonstrates that depressive symptoms can be reduced through treatment. Addressing these symptoms may improve substance abuse treatment outcomes and long-term abstinence outcomes (Brown, Evans, Miller, Burgess, & Mueller, 1997; Ramsey, Brown, Stuart, Burgess, & Miller, 2002).

Treating the symptoms of depression:

• Enhances the treatment experience for both the person with depressive symptoms and those around him or her.
• Increases retention rates.
• Leads to greater reductions in substance use.
• Reduces the probability of relapse.
• Increases engagement rates in aftercare services.

In addition to these benefits for the client, addressing depressive symptoms as part of your agency or program may lead to:

• Increased clinical competence of staff.
• Increase in appropriate referrals for psychological and psychiatric evaluations for depression and depressive symptoms.
• Increased staff retention, higher levels of staff satisfaction, reduced risk of burnout, decreased staff stress, and reduced turnover.
• Improved risk management (e.g., less suicidal ideation and suicidal behavior) and reduced liability.
• Access to new revenue streams.

Addressing co-occurring substance use and mental disorders is a key priority for the Federal government, State governments, insurance companies, credentialing boards, and accrediting organizations. By starting now to address depressive symptoms in your agency or programs, you will be better positioned in the future to compete in the substance abuse treatment marketplace.

Ideally, your agency can become part of the larger community of research-practitioners who seek the best ways to help clients more quickly experience a higher quality of recovery. By joining with other agencies in your network, you can coordinate treatment practices and perhaps collaboratively obtain research grants. Some of the best practices are unresearched because agencies do not appreciate the value of their unique treatment approach.

## Thinking About Organizational Change

If you have decided to implement some or all of the recommendations in Managing Depressive Symptoms in Substance Abuse Clients During Early Recovery, Part 1, you, your staff, your clients, and the other agencies and organizations with which you interact may require the development of new treatment protocols and policies, as well as new clinical knowledge, attitudes, and skills. These changes can be rewarding and/or frustrating, but will be beneficial to client well-being in the long run.

Every organization is a social system with its own unique culture. There are actually two cultures to each organization—the formal and the informal—that involve separate communication channels. The ideal is to have these cultures as congruent as possible. They affect decisions, relationships, and common (or conflicting) values and beliefs. Any change in services or approaches to clients will call for a significant change in the organization's culture.

Change in the corporate culture calls for leadership. Management at all levels and in all departments—not just clinical services—must be involved. Ancillary and support personnel also will be affected and need to be part of the process.

The similarities between recovery in an individual and change in an organization are rather striking. In fact, the organizational change process is highly analogous to the clinical processes of assessment, client-centered treatment planning, treatment delivery, and continuing care.

As with recovery, careful assessment is central to organizational change. About half of Part 2, chapter 2 of this TIP concerns assessment issues. As you will see in that discussion, the current status of the organization relative to targeted change goals needs to be assessed. Current practices, staff and administrator competencies, policies and procedures, facilities, and so on will need to be evaluated (see the section “Maximizing the Fit,” p. 106). These are similar to client assessments that determine the nature and scope of a client's issues and challenges as well as their strengths and assets.

A program's readiness for change needs to be examined. Sometimes, the best decision is to delay attempting any change and work only on organizational climate and readiness. Introducing change before the groundwork has been laid can foreclose or impede later change opportunities when the climate improves. An excellent resource for organizational assessment for change is the Program Change Model (Simpson, 2002) and its accompanying survey, the Organizational Readiness for Change (Texas Christian University, Institute of Behavioral

Research, 2002). This model addresses strategies and tools for assessing institutional and personal readiness and outlines the stages of the transfer process that administrators may find helpful.

The four stages are:

1. Exposure through training
2. Adoption through leadership decision making
3. Implementation through exploratory use
4. Practice through routine use.

In addition, your assessment should consider your organization's past experiences with change initiatives (i.e., whether they were positive or negative). Just as a bad experience in a previous treatment program may color a client's perception of a new program, old experiences with organizational change may affect attitudes toward new efforts. Thus, a thorough review of organizational history of change is critical to planning new organizational change. The response to change of staff members is equally important to predicting successful outcome of implementation.

As in treatment, assessment is not a one-time activity. Rather, it is an ongoing process that includes regular feedback and adjustment of your plans for organizational change and your approaches to facilitating change. A plan for organizational change is similar to a client-centered treatment plan. First, your plan must be tailored to the specific needs of your organization. Your assessment information helps you determine where your organization needs to go, how to get there, and the pace at which change can occur. Simply following the plan used by another organization makes no more sense than having the identical treatment plan for all of your clients. The choice to implement a component on depressive symptoms presumably is part of a larger mission and vision to provide treatment for a wider range of affective symptoms (such as anger, anxiety, shame, guilt) that undermine progress toward personal and social well-being.

In as many ways as possible, the change plan should be linked to your best understanding of what key stakeholders (e.g., boards, staff, funders, clients, communities, 12-Step groups) want and value. If, for example, your staff desires professional growth opportunities, change aimed at addressing the needs of clients with depressive symptoms can be linked to expanding staff capabilities in mental health issues. Similarly, your board's concern with expansion might be tied to the need for increased capacity if the organization is to address the depressive symptoms of its clients.

The development of the change plan should involve as many clients, stakeholders, and community resources as possible. There are a number of reasons this is the case. First and obviously, clients, staff, and other stakeholders function best when they feel involved in shaping their worlds. They feel that they have a measure of control and understand what is going to happen and what is expected of them. Equally important, stakeholders (especially staff) have a key role in determining how to make the recommendations in Managing Depressive Symptoms in Substance Abuse Clients During Early Recovery, Part 1 work best in your agency or program.

Finally, no stakeholder is more important than the clinical supervisor who is commissioned to implement the clinical mission and vision of the administrators. The clinical supervisor is challenged to help counselors maintain a high level of best-practices, to oversee the application of these practices, and to conduct process and program evaluation for quality control. Below is a discussion of how clinical supervisors serve as the critical link between direct service staff and administration, and the role of clinical supervisors in implementing organizational change.

Principles for implementing the change plan are directly analogous to principles of treatment and recovery in that both are achieved in steps, making it a process rather than an outcome. The following principles of managing change are directly adapted from principles of care presented in chapter 1 of Managing Depressive Symptoms in Substance Abuse Clients During Early Recovery, Part 1:

1. There is no single model or approach to implementing a program of organizational change. A preconception about how change should occur or inflexibility during the change process is all but certain to be counterproductive, if not fatal, to meeting a client's treatment goals or a program's change goals. Constant vigilance and course corrections will be needed. Corrections should be made in consultation with the same stakeholders who developed the original change plan.
2. A belief in your organization's ability to accomplish the change plan is fundamental. As with counselors, an administrator's belief that change can happen (and the ability to communicate that belief) is a central component of the change process.
3. The change program should be individualized to accommodate the specific needs, goals, culture, and readiness to change of your organization.It is critical to adapt and “personalize” the plan to fit specific organizational needs and culture.

At least in the first few years after the implementation of an organizational change plan, maintenance of these changes cannot be assumed. Continuing care of your organization's new accomplishments is critical to their long-term survival. Like treatment and recovery, this is often neglected and can lead to relapse.

Continuing care is needed for several reasons. First, newly learned practices and procedures are fragile and will tend to drift. Organizational change almost always brings about some degree of personnel change. Planning for the selection and integration of new employees, the factors that need to be considered, and the method by which integration will be accomplished all need to be part of the developmental process. Equally important, new and unforeseen barriers may arise that need to be addressed. As time passes, more and more of these challenges will have been encountered and overcome. In the early stages, however, there will be some unanticipated challenges. Regular supervision and training boosters are the best insurance that behavior change will last over time.

Eventually, the changes you implement will become a regular feature of your agency's operation. This process is called institutionalization; it will have occurred when no one seems to really remember what things were like before the change took place. Rather, the new practices you introduced have become the everyday practices of your agency. Even when institutionalization occurs, however, a commitment to continuous quality improvement will help ensure your program's ability to respond to ongoing changes in the needs of your client population and community.

### The Challenge of Implementing New Clinical Practices

It is sometimes assumed that good ideas are self-implementing. After all, you may pride yourself on being a rational person who does not need to be persuaded to adopt a good idea when you see one. This is all the more true in your role as a helping professional. You want the best for your clients and actively seek new ideas that will help you help them. However, recognizing a good idea and implementing it in practice are two very different things. In fact, many good ideas for practice improvement are never widely implemented (e.g., Woolf, DiGuiseppi, Atkins, & Kamerow, 1996).

Some of the usual challenges you may hear are:

• “This is not what worked for me.”
• “This is not how I was taught to do it.”
• “Depression is part of withdrawal; it will go away on its own after a while.”
• “We need to stick to basics.”
• “I'm doing it just fine, thank you very much.”
• “You keep adding things to do. What are you going to take away?”
• “You're the expert: tell me what to do.”
• “This won't work for this client.”
• “I couldn't make supervision because I had to see a client.”

As a general rule, failure to implement new clinical practices has little to do with resistance to change on the part of counselors or administrators. Failure to implement can be a result of issues such as inadequate modeling from administration, lack of follow-through, inadequate training, and many others. Even the best counselors and administrators are highly constrained by the contexts in which they work.

Accordingly, implementation success requires administrators to:

• Be proactive in making the new practice fit the context.
• Create an organizational climate that encourages and supports implementation.

These two tasks are related, and accomplishing one requires accomplishing the other. For example, fitting new practices to your context requires a thorough review of your agency's current operations. Such self-examination, in turn, helps create an organizational climate of openness to new ideas and experimentation. Before implementation begins, it is important to create positive expectations among staff. Investing the time to educate and express support for the specific implementations can go a long way in staff acceptance of change, especially in the early stages.

So often, executive staff face more immediate resistance or ambivalence because the initial groundwork was not done. Moreover, administrators have likely considered the change ideas for some time and expect staff to be at a similar level of enthusiasm and commitment to the proposal.

Change is easier to make when those involved:

• Understand why the change is needed and the benefits they will realize.
• See how the new ways will integrate into and honor what has been done previously.
• Are given motivation strategies for providing ideas and offers of assistance in implementation.

### Maximizing the Fit

For a clinical innovation to take hold, it must fit with: (1) key characteristics of your target population and community (e.g., values, expectations); (2) the skills, licensures, certifications, and team structures of your staff; (3) your program or agency's facilities and resources; (4) your policies and practices; (5) local, State, and Federal regulations; (6) available interagency networks (e.g., needed outside resources, memoranda of understanding); and (7) your reimbursement procedures. Certain kinds of mismatches will be fatal to implementing change. For example, no one would expect successful implementation of an innovation when staff lack the skills to perform it. However, a lack of appropriate space or needed audiovisual equipment can stall an innovation in its tracks. As with many endeavors, the details are critical.

It is likely that adjustments will be needed both in your agency's or program's context and in the ways that the recommendations presented in Part 1 are implemented. Part 2, chapter 2 of this TIP provides procedures, checklists, and other tools for assessing the fit between the recommendations provided in Part 1 and your program or agency's current context, procedures, and so on. Useful though these materials are, your ultimate success in “maximizing the fit” will depend on your creativity, problem solving skills, and patience in applying them.

In the early stages of implementing the recommendations in Part 1, organizations will profit from a climate that promotes:

• A willingness to take risks and try unconventional approaches.
• A willingness to tolerate some ambiguity as the fit between new practices and context evolves.
• An ability to recognize false starts and to abandon approaches that are not working.
• Appreciation and reward for ideas and implementation.

As noted earlier, the later stages of implementation will be facilitated by:

• A commitment to continuous quality improvement.
• The development of structures that support and reinforce the change (e.g., standardized training for new staff, regular boosters, and supervision for all staff).
• Expressions of organizational pride in accomplishment.
• Institutionalization (in which new practices become everyday practices).

Clinical supervision is the keystone of implementation of new clinical procedures and processes. Supervision should be more instructive and less crisis driven—more proactive and less reactive—by using such strategies and resources as:

• Innovative supervision methods, including live, insession supervision, role playing, taping, and group and peer supervision.
• Regularly scheduled, ongoing clinical supervision
• Checklists and fidelity scales.
• Quality skills training.
• Counselor mentoring.

## The Role of the Administrator in Introducing and Supporting New Clinical Practices

Chapter 2 of this Guide presents the tasks you will need to accomplish in order to implement the changes elaborated in Managing Depressive Symptoms in Substance Abuse Clients During Early Recovery, Part 1. Important as these tasks are, they cannot themselves ensure the successful implementation of the Part 1 recommendations. Rather, successful implementation will ultimately depend on the leadership you provide.

Leadership is critical for implementing an organizational change. First and foremost, leadership means commitment. If you and your administrative colleagues are not fully committed to improving services for clients with depressive symptoms, meaningful and lasting change is unlikely to take hold. In many ways, attempting change without the commitment of organizational leaders can be worse than no attempt to change at all. The perception that leaders are only giving lip-service to a new idea will eventually become clear to staff. This perception will undermine the current attempts at innovation and may lead to a staff that is reluctant to try new ideas.

Second, leadership means having a vision of how the organization will change. This vision should include explicit goals and a clear statement of how conflicts with other organizational goals will be resolved. However, a vision is more than a list of goals. It is a picture of how the organization will look when change has been accomplished—a picture you must paint with words in vivid detail for your staff. Developing this vision and the means to communicate it throughout the organization requires considerable effort.

Leadership should include highly skilled and competent clinicians trained in mental health and substance use disorder treatment who can direct and supervise services for clients with co-occurring depressive symptoms and substance use disorders. These clinicians should know and appreciate the specific roles that can be played by licensed or certified addiction counselors, licensed social workers, psychologists, physicians, and other mental health and substance abuse professionals. They should also have an appreciation for the role depressive symptoms can play in interfering with substance abuse treatment. When such resources are not available on staff, a clinician should be available on a consultant basis.

Since working with clients with depressive symptoms means that programs must be prepared to address the needs of clients with co-occurring disorders, staff have a right to expect that program leadership will be knowledgeable and conversant on the impact of addressing co-occurring disorders and offer a vision of what this means to the program.

Third, leadership means inspiring your organization. Inspirational leaders communicate confidence in the organization's ability to change, enthusiasm for change, optimism about the change process, and an unwillingness to accept failure. This needs to be communicated to all stakeholders including current and potential clients, funders, board members, staff, community leaders, community 12-Step participants and programs, and sister agencies. Inspiration not only is a process of oral and written communication, but also involves modeling the attitudes and values you want staff and other stakeholders to adopt, including those discussed earlier (e.g., risk taking, tolerance of ambiguity, and willingness to start over when approaches are not working). Inspiration also involves getting your hands dirty. Nothing inspires staff members more than seeing their leaders struggle alongside them in the day-to-day tasks of making new ideas work.

Finally, leadership means an ongoing and honest appraisal of progress. As noted in Managing Depressive Symptoms: A Review of the Literature, Part 3 (http://store.samhsa.gov) and discussed further below, implementing the recommendations from Part 1 will require ongoing assessments of progress, including regular formative evaluation of process and outcomes. Periodic reports on how the organization is doing can and should be developed from the assessments and evaluations. These reports should be shared with staff as should plans for corrective action when needed. The most effective leaders frame both good and bad news in a positive light. One way to do this is to emphasize the learning value of challenges and setbacks and to remind staff that it is the organization as a whole, rather than any individual, that is responsible for making change happen. This means that “we succeeded” or “we still have room to improve” is always the preferred way to communicate successes and failures.