# Expert Advisory Board

Note: The information given indicates each participant's affiliation during the time the board was convened and may no longer reflect the individual's current affiliation.

Richard N. Rosenthal, M.D., Chair
Professor of Clinical Psychiatry
Columbia University College of Physicians and Surgeons
Chairman, Department of Psychiatry
St. Luke's Roosevelt Hospital Center
New York, New York

Patricia A. Burke, M.S.W., LCSW, BCD, C-CATODSW
Private Practice
West Baldwin, Maine

Dennis C. Daley, LCSW, BCD
Associate Professor of Psychiatry
Western Psychiatric Institute and Clinic
University of Pittsburgh Medical Center
Pittsburgh, Pennsylvania

William Mock, Ph.D., LISW, LICDC, SAP
Director
The Center for Interpersonal Development
Lakewood, Ohio

Paul Nagy, LPC, CCAS, CCS
Program Director, Duke Addictions Program and Clinical Associate
Duke University Department of Psychiatry and Behavioral Sciences Durham
North Carolina

Bette Ann Weinstein, Ph.D., LCSW
Private Practice
Delray Beach, Florida