# Consensus Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

## Chair, Part 1 and Part 2 Consensus Panels

Rose M. Urban, M.S.W., J.D., LCSW, LCAS
KAP Project Co-Director
The CDM Group, Inc.
Bethesda, Maryland

## Part 1 Consensus Panel Members

Bruce Carruth, Ph.D.
KAP Expert Content Director
The CDM Group, Inc.
Bethesda, Maryland

Jennifer Frey, Ph.D.
KAP Expert Content Director
The CDM Group, Inc.
Bethesda, Maryland

Michael Klitzner, Ph.D.
KAP Expert Content Director
The CDM Group, Inc.
Bethesda, Maryland

Sheldon R. Weinberg, Ph.D.
Senior Research/Applied Psychologist
The CDM Group, Inc.
Bethesda, Maryland

## Part 2 Consensus Panel Members

Jennifer Frey, Ph.D.
KAP Expert Content Director
The CDM Group, Inc.
Bethesda, Maryland

Nancy VanDeMark, Ph.D.
Director, Research and Program Evaluation
Arapahoe House, Inc.
Thornton, Colorado