# Appendix G—Acknowledgments

Numerous people contributed to the development of this Treatment Improvement Protocol (TIP), including the TIP Consensus Panel (see page v), the TIP Expert Advisory Board (see page vi), the TIP Meeting Advisory Panel (see Appendix E), and TIP Field Reviewers (see Appendix F).

This publication was produced by The CDM Group, Inc. (CDM), and JBS International, Inc. (JBS), under the Knowledge Application Program (KAP) contract number 270-04-7049 with the Substance Abuse and Mental Health Services Administration (SAMHSA), U.S. Department of Health and Human Services (HHS).

Rose M. Urban, M.S.W., J.D., LCSW, LCAS, served as the KAP Project Co-Director. Elizabeth Marsh Cupino formerly served as CDM KAP Managing Co-Director. Sheldon Weinberg, Ph.D., served as KAP Senior Researcher/Applied Psychologist. Other KAP personnel included Susan Kimner, KAP Deputy Project Director/Editorial Director and TIP Editor; Janet Humphrey, M.A., KAP Writer/Editor; Michelle Myers, former Quality Assurance Editor; Amy Conklin, former Quality Assurance Editor; Virgie Paul, Librarian; Jonathan Max Gilbert, M.A., Writer; and Radell Heintze, former KAP Project Coordinator.