# Appendix F—Field Reviewers

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

Karen Allen, Ph.D., R.N.
Professor & Chairperson, Dept. of Nursing
Andrews University
Berrien Springs, Michigan

Gloria Baciewicz, M.D.
Senior Medical Director, Ambulatory Services
Strong Behavioral Health, University of Rochester Medical Center
Rochester, New York

Kathryn Bedard, M.A., LCADC, CMS
New Jersey Division of Mental Health Services
Trenton, New Jersey

Claudia A. Blackburn, M.S., Psy.D.
Consultant/Licensed Psychologist
Lancaster, Pennsylvania

Mimmie Byrne, LICSW, CAC
Associate Professor
West Virginia University
Dept. of Behavioral Medicine & Psychiatry
Morgantown, West Virginia

Catherine S. Chichester, APRN, BC
Executive Director
Co-Occurring Collaborative of Southern Maine
Portland, Maine

Barbara Davis, LCSW
Psychotherapist
South Orange, New Jersey

James F. Emmert, FACATA
Principal
JFE Associates
Deerfield Beach, Florida

Joyce Fowler, Ph.D.
Licensed Psychologist
Fowler Institute
Little Rock, Arkansas

Scarlett Harris, LCSW
Private Practice Social Worker
Adjunct Faculty, University of Arkansas at Little Rock
Little Rock, Arkansas

Denise A. Horton, Ph.D., LPC, CEAP
Alcohol/Drug Control Officer/Employee Assistance
Professional Army Substance Abuse Program
Fort Dix, New Jersey

John K. Kriger, M.S.W., LCADC
President
Kriger Consulting, Inc.
Burlington, New Jersey

Michael Dale Loos, Ph.D., LPC/S, LADAC
President
Michael Dale Loos
Fayetteville, Arkansas

Edna Meziere, M.S., R.N.
Healthcare Administrator (Retired)
Tulsa, Oklahoma

Geri Miller, Ph.D.
Professor
Appalachian State University
Fleetwood, North Carolina

Craig Nakken, LCSW
Clinical Social Worker
St. Paul, Minnesota

David S. Olsen, M.A.
Outpatient Alcohol & Drug Counselor
Central Kansas Foundation
Salina, Kansas

Jack M. Schibik, Ph.D., LCADC, LPC, LMHC
Kairos Counseling, Coaching, & Consulting
Naples, Florida

Cynthia Zubritsky, Ph.D.
Senior Research Faculty
University of Pennsylvania Department of Psychiatry
Philadelphia, Pennsylvania