# Appendix A—Bibliography

Addiction Technology Transfer Center (2004). The Change Book: A Blueprint for Technology Transfer. (2nd ed.) Kansas City, MO: Addiction Technology Transfer Center.
American Psychiatric Association (2000). Diagnostic and Statistical Manual of Mental Disorders. (4th Text Revision ed.) Washington, DC: American Psychiatric Association.
American Society of Addiction Medicine (2001). Patient Placement Criteria for the Treatment of Substance-Related Disorders: ASAM PPC-2R. (2nd–Rev. ed.) Chevy Chase, MD: American Society of Addiction Medicine.
Bardwell, W. A., & Dimsdale, J. E. (2001). The impact of ethnicity and response bias on the self-report of negative affect. Journal of Applied Biobehavioral Research, 6, pp. 27–38.
Beck, A. T., Rush, A. J., Shaw, B. F., & Emery, G. (1979). Cognitive Therapy of Depression. New York: Guilford Press.
Brown, R. A., Evans, D. M., Miller, I. W., Burgess, E. S., & Mueller, T. I. (1997). Cognitive-behavioral treatment for depression in alcoholism. Journal of Consulting and Clinical Psychology, 65, 715–726.9337490
Carroll, K. M. (1998). A cognitive–behavioral approach: treating cocaine addiction. Therapy Manuals for Drug Addiction (Manual 2). Rockville, MD: National Institute on Drug Abuse.
Center for Substance Abuse Treatment (1999). Enhancing Motivation for Change in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 35 (Rep. No. HHS Publication No. (SMA) 99-3354). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2005a). Substance Abuse Relapse Prevention for Older Adults: A Group Treatment Approach. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2005b). Substance Abuse Treatment for Persons With Co-Occurring Disorders. Treatment Improvement Protocol (TIP) Series 42 (Rep. No. HHS Publication No. (SMA) 05-3992). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2006a). Definitions and Terms Relating to Co-Occurring Disorders. COCE Overview Paper 1. HHS Publication No. (SMA) 06-4163. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2006b). Screening, Assessment, and Treatment Planning for Persons With Co-Occurring Disorders. COCE Overview Paper 2. HHS Publication No. (SMA) 06-4164. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (2007). Competencies for Substance Abuse Treatment Clinical Supervisors. Technical Assistance Publication (TAP) Series 21-A (Rep. No. HHS Publication No. (SMA) 07-4243). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment (in development a). Addressing Suicidal Thoughts and Behaviors With Clients in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series XX (Rep. No. HHS Publication No. (SMA) XX-XXXX). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (in development b). Supervision and the Professional Development of the Substance Abuse Counselor. Treatment Improvement Protocol (TIP) Series XX (Rep. No. HHS Publication No. (SMA) XX-XXXX). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Compton, W. M., Conway, K. P., Stinson, F. S., & Grant, B. F. (2006). Changes in the prevalence of major depression and comorbid substance use disorders in the United States between 1991–1992 and 2001–2002. American Journal of Psychiatry, 163, 2141–2147.
Cole, S. R., Kawachi, I., Maller, S. J., & Berkman, L. F. (2000). Test of item-response bias in the CES-D scale: Experience from the New Haven EPESE study. Journal of Clinical Epidemiology, 53, 285–289.10760639
Conner, K. R., Sorensen, S., & Leonard, K. E. (2005). Initial depression and subsequent drinking during alcoholism treatment. Journal of Studies on Alcohol, 66, 401–406.16047530
Cuijpers, P., Smit, F., & van Straten, A. (2007). Psychological treatments of subthreshold depression: A meta-analytic review. Acta Psychiatrica Scandinavica, 115, 434–441.17498154
Cuijpers, P., van Straten, A., & Warmerdam, L. (2007). Behavioral activation treatments of depression: A meta-analysis. Clinical Psychology Review, 27, 318–326.17184887
Curran, G. M., Flynn, H. A., Kirchner, J., & Booth, B. M. (2000). Depression after alcohol treatment as a risk factor for relapse among male veterans. Journal of Substance Abuse Treatment, 19, 259–265.11027896
Dobson, K.S. (1989). A meta-analysis of the efficacy of cognitive therapy for depression. Journal of Consulting and Clinical Psychology, 57, 414–419.2738214
Dodge, R., Sindelar, J., & Sinha, R. (2005). The role of depression symptoms in predicting drug abstinence in outpatient substance abuse treatment. Journal of Substance Abuse Treatment, 28, 189–196.15780549
Fixsen, D. L., Naoom, S. F., Blase, K. A., Friedman, R. M., & Wallace, F. (2005). Implementation Research: A Synthesis of the Literature. Tampa, FL: University of South Florida, Louis de la Parte Florida Mental Health Institute, The National Implementation Research Network.
Gilbert, P. (2000). Counseling for Depression. (2nd ed.) Thousand Oaks, CA: Sage Publications, Inc.
Gliatto, M. F., & Rai, A. K. (1999). Evaluation and treatment of patients with suicidal ideation. American Family Physician, 59, 61500–61506.
Grant, B. F., Stinson, F. S., Dawson, D. A., Chou, S. P., Dufour, M. C., Compton, W., (2004). Prevalence and co-occurrence of substance use disorders and independent mood and anxiety disorders: Results from the National Epidemiologic Survey on Alcohol and Related Conditions. Archives of General Psychiatry, 61, 807–816.15289279
Greenfield, S. F., Weiss, R. D., Muenz, L. R., Vagge, L. M., Kelly, J. F., Bello, L. R., et al. (1998). Effect of depression on return to drinking: A prospective study. Archives of General Psychiatry, 55, 259–265.9510220
Hubble, M. A., Duncan, B. L., & Miller, S. D. (Eds.) The Heart and Soul of Change: What Works in Therapy (1999). Washington, DC: American Psychological Association.
Husband, S. D., Marlowe, D. B., Lamb, R. J., Iguchi, M. Y., Bux, D. A., Kirby, K. C., et al. (1996). Decline in self-reported dysphoria after treatment entry in inner-city cocaine addicts. Journal of Consulting & Clinical Psychology, 64, 221–224.8907102
Hyde, P. S., Falls, K., Morris, J. A., & Schoenwald, S. K. (2003). Turning Knowledge Into Practice: A Manual for Behavioral Health Administrators and Practitioners About Understanding and Implementing Evidence-Based Practices. Boston, MA: The Technical Assistance Collaborative, Inc.
Jackson, L. C., & Greene, B. (Eds.) Psychotherapy With African American Women: Innovations in Psychodynamic Perspectives and Practice (2000). New York: Guilford Press.
Jacobson, N.S., Martell, C. R., & Dimidjian, S. (2001). Behavioral activation therapy for depression: Returning to contextual roots. Clinical Psychology: Science and Practice, 8, 255–270.
Kessler, R. C., Berglund, P., Borges, G., Nock, M., & Wang, P. S. (2005). Trends in suicide ideation, plans, gestures, and attempts in the United States, 1990–1992 to 2001–2003. Journal of the American Medical Association, 293, 2487–2495.15914749
Lazarus, J. (2000). Stress Relief and Relaxation Techniques. Los Angeles: Keats Publishing.
Leyden-Rubenstein, L.A. (1999). The Stress Management Handbook: Strategies for Health and Inner Peace. New Canaan, CT: Keats Publishing.
Miller, W. R., & Rollnick, S. (2002). Motivational Interviewing: Preparing People for Change. (2nd ed.) New York: Guilford Press.
Nunes, E. V., & Levin, F. R. (2004). Treatment of depression in patients with alcohol or other drug dependence: A meta-analysis. JAMA: Journal of the American Medical Association, 291, 1887–1896.15100209
Nunes, E., Rubin, E., Carpenter, K., & Hasin, D. (2006). Mood disorders and substance use. In D. J. Stein, D. J. Kupfer, & A. F. Schatzberg (Eds.), The American Psychiatric Publishing Textbook of Mood Disorders. (pp. 653–671). Washington, DC: American Psychiatric Publishing, Inc..
Nunes, E. V., Selzer, J., Levounis, P., & Davies, C. (in press). Substance Dependence and Co-Occurring Psychiatric Disorders: Best Practices for Diagnosis and Treatment. New York: Civic Research Institute Press.
Nunes, E. V., Sullivan, M. A., & Levin, F. R. (2004). Treatment of depression in patients with opiate dependence. Biological Psychiatry, 56, 793–802.15556125
Prochaska, J. O., & DiClemente, C. C. (1984). The stages of change. In The Transtheoretical Approach: Crossing Traditional Boundaries of Therapy. (pp. 21–32). Homewood, IL: Dow Jones-Irwin.
Ramsey, S. E., Brown, R. A., Stuart, G. L., Burgess, E. S., & Miller, I. W. (2002). Cognitive variables in alcohol dependent patients with elevated depressive symptoms: Changes and predictive utility as a function of treatment modality. Substance Abuse, 23, 171–182.12444350
Reilly, P.M. & Shopshire, M.S. (2002). Anger Management for Substance Abuse and Mental Health Clients: A Cognitive Behavioral Therapy Manual. HHS Pub. No. (SMA) 02-3661. Rockville, MD: Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services Administration.
Rogers, C. R. (1992). The necessary and sufficient conditions of therapeutic personality change. Journal of Consulting and Clinical Psychology, 60, 827–832.1460145
Rogers, E. M. (2003). Diffusion of Innovations. (5th ed.) New York: Free Press.
Rosenthal, R.N. (2008). Techniques of individual supportive psychotherapy. In G. O. Gabbard (Ed.), Textbook of Psychotherapeutic Treatments. Washington, DC: American Psychiatric Publishing, Inc.
Rosenthal, R. N. & Westreich, L. (1999). Treatment of persons with dual diagnoses of substance use disorder and other psychological problems. In B. S. McCrady & E. E. Epstein (Eds.), Addictions: A Comprehensive Guidebook (pp. 439–476). New York: Oxford University Press.
Rudd, M. D. (2006). The Assessment and Management of Suicidality. Sarasota, FL: Professional Resource Press.
Rudd, M. D., Joiner, T., & Rajab, M. H. (2001). Treating Suicidal Behavior: An Effective, Time-Limited Approach. New York: The Guilford Press.
Simpson, D. D. (2002). A conceptual framework for transferring research to practice. Journal of Substance Abuse Treatment, 22, 171–182.12072162
Schuckit, M. A. (1986). Primary men alcoholics with histories of suicide attempts. Journal of Studies on Alcohol, 47, 78–81.3959563
Smith, C. & Erford, B. T. (2001). Test Review: Beck Depression Inventory-II. Greensboro, NC: Association for Assessment in Counseling.
State of Nevada Board of Examiners for Alcohol, Drug and Gambling Counselors (2003). Nevada Administrative Code-Chapter 641 C-Alcohol, Drug and Gambling Counselors General Provisions. Dayton, NV: State of Nevada Board of Examiners for Alcohol, Drug and Gambling Counselors.
Strain, E. C., Stitzer, M. L., & Bigelow, G. E. (1991). Early treatment time course of depressive symptoms in opiate addicts. Journal of Nervous and Mental Disease, 179, 215–221.
Strowig, A. B. (2000). Relapse determinants reported by men treated for alcohol addiction: The prominence of depressed mood. Journal of Substance Abuse Treatment, 19, 469–474.11166511
Styron, W. (1992). Darkness Visible: A Memoir of Madness. New York: Vintage Books.
Sue, D. W., & Sue, D. (2003). Counseling the Culturally Diverse: Theory and Practice. (4th ed.) New York: John Wiley and Sons.
Texas Christian University Institute of Behavioral Research. (2002). Organizational Readiness for Change (TCU ORC) Treatment Staff Version (TCU ORC-S). Fort Worth, TX: Texas Christian University.
Texas Department of State Health Services. (2004). Licensed Chemical Dependency Counselor Handbook: Counselor Licensure Rules, Counselor Intern Handbook of Helpful Information, Forms and Examination Information. Austin, TX: Texas Department of State Health Services.
U.S. Department of Health and Human Services. (2003). Developing Cultural Competence in Disaster Mental Health Programs: Guiding Principles and Recommendations. (HHS Pub. No. (SMA) 3828). Rockville, MD: Center for Mental Health Services, Substance Abuse and Mental Health Services Administration.
Winston, A., Rosenthal, R. N., & Pinsker, H. (2004). Introduction to Supportive Psychotherapy. Washington, DC: American Psychiatric Publishing Inc.
Woolf, S. H., DiGuiseppi, C. G., Atkins, D., & Kamerow, D. B. (1996). Developing evidence-based clinical practice guidelines: Lessons learned by the U.S. Preventive Services Task Force. Annual Review of Public Health, 17, 511–538.