# Appendix E: Field Reviewers

Note: The information given indicates each participant's affiliation during the time the review was conducted and may no longer reflect the individual's current affiliation.

Karen C.O. Batia, M.A., Ph.D.
Senior Director
Mental Health and Addiction Services
Heartland Health Outreach
Chicago, Illinois

Thomas P. Beresford, M.D.
Professor
Department of Psychiatry
University of Colorado School of Medicine
Denver, Colorado

Barry Blood, LCPC
Addiction Counselor
Family Service Foundation
Columbia, Maryland

Patricia T. Bowman
Probation Counselor
Fairfax Alcohol Safety Action Program
Fairfax, Virginia

Barry S. Brown, M.S., Ph.D.
Adjunct Professor
University of North Carolina at Wilmington
Carolina Beach, North Carolina

David A. Chiriboga, Ph.D.
Professor
Department of Aging and Mental Health
Florida Mental Health Institute
University of South Florida
Tampa, Florida

Carol J. Colleran, CAP, ICADC
Director of Primary Programs
Center of Recovery for Older Adults
Hanley-Hazelden Center
West Palm Beach, Florida

Joy Davidoff
Coordinator of Addiction Medicine
New York State Office of Alcoholism and Substance Abuse Services
Albany, New York

John P. de Miranda, Ed.M.
Executive Director
National Association on Alcohol, Drugs and Disability, Inc.
San Mateo, California

B.J. Dean
Executive Director
Island Grove Regional Treatment Center, Inc.
Greeley, Colorado

Ralph W. Edwards, M.P.H., M.P.A.
Director
Office of Citizen Leadership
Massachusetts Department of Mental Health and Retardation
Boston, Massachusetts

Michael I. Fingerhood, M.D.
Associate Professor of Medicine
Johns Hopkins Bayview Medical Center
Baltimore, Maryland

Michael M. Galer, D.B.A.
Chair
Graduate School of Business
University of Phoenix Greater Boston Campus
Braintree, Massachusetts

Robert Holden, M.A.
Program Director
Partners in Drug Abuse Rehabilitation Counseling
Washington, DC

Kyle M. Kampman, M.D.
Associate Professor of Psychiatry
Medical Director
Treatment Research Center
University of Pennsylvania
Philadelphia, Pennsylvania

Michael Warren Kirby, Jr., M.A., Ph.D.
Chief Executive Officer
Arapahoe House, Inc.
Thornton, Colorado

James J. Manlandro, D.O., FAOAAM, FACOFP
Medical Director
Family Addiction Treatment Services, Inc.
Somers Point, New Jersey

Ethan Nebelkopf, Ph.D., MFCC
Director
Family and Child Guidance Clinic
Native American Health Center
Oakland, California

Robert E. Olson, M.S.
Project Director
California Alcohol, Drug and Disability Technical Assistance Project
National Association on Alcohol, Drugs and Disability, Inc.
Belmont, California

Christopher Pond
Director of Adult Services
Arapahoe House, Inc.
Thornton, Colorado

Anthony B. Radcliffe, M.D.
Chief of Addiction Medicine
Fontana SCPMG
Kaiser Permanente/CDRP
Fontana, California

Jay Renaud
Member/Editor
J & M Reports
Guidepoints: Acupuncture in Recovery
Vancouver, Washington

Joseph P. Reoux, M.D.
Assistant Professor
Department of Psychiatry and Behavioral Sciences
VA Puget Sound Health Care System
University of Washington School of Medicine
Seattle, Washington

Timothy M. Scanlan, M.D.
Medical Director
Addiction Specialists of Kansas
Wichita, Kansas

Lawrence Schonfeld, Ph.D.
Professor
Louis de la Parte Florida Mental Health Institute
Department of Aging and Mental Health
University of South Florida
Tampa, Florida

Steven Shevlin
Executive Director
Signs of Sobriety, Inc.
Ewing, New Jersey

Carla Shird, M.A., CSC-AD
Counselor
Mental Health Center
Gallaudet University Kellogg Conference Center
Washington, DC

Mickey J.W. Smith, M.S.W.
Senior Policy Associate, Behavioral Health Program, Policy & Practice Unit
Division of Professional Development & Advocacy
National Association of Social Workers
Washington, DC

Leslie R. Steve, M.A.
Native American Coordinator
Center for the Application of Substance Abuse Technologies
University of Nevada
Reno, Nevada

Richard T. Suchinsky, M.D.
Associate Chief for Addictive Disorders and Psychiatric Rehabilitation
Mental Health and Behavioral Sciences Services
Department of Veterans Affairs
Washington, DC

Nancy R. VanDeMark, M.S.W.
Director
Research and Program Evaluation
Arapahoe House, Inc.
Thornton, Colorado

Melvin H. Wilson, M.B.A., LCSW-C
Baltimore HIDTA Coordinator
Maryland Department of Parole and Probation
Clinton, Maryland

Ann S. Yabusaki, M.Ed., M.A., Ph.D.
Substance Abuse Director
Psychologist
Substance Abuse Programs and Training
Coalition for a Drug-Free Hawaii
Kaneohe, Hawaii