# Appendix D: Resource Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

Brad Austin
Public Health Advisor
Division of State and Community Assistance PPG Program Branch
Center for Substance Abuse Treatment
Rockville, Maryland

Christina Currier
Public Health Analyst
Practice Improvement Branch
Division of Services Improvement
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Herman Diesenhaus
Public Health Analyst
Scientific Analysis Branch
Office of Evaluation, Scientific Analysis and Synthesis
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Hendree E. Jones, M.A., Ph.D.
Assistant Professor
CAP Research Director
Department of Psychiatry and Behavioral Sciences
Johns Hopkins University Center
Baltimore, Maryland

Robert Lubran, M.S., M.P.A.
Director
Division of Pharmacologic Therapies
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

James J. Manlandro, D.O., FAOAAM, FACOFP
Medical Director
Family Addiction Treatment Services, Inc.
Somers Point, New Jersey

Carol Rest-Mincberg
State Project Officer
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Dennis Scurry, M.D.
Chief Medical Officer
Addiction of Prevention and Recovery Administration
Government of the District of Columbia
Department of Health
Washington, DC

Alan Trachtenberg, M.D., M.P.H.
Medical Officer
Division of Pharmacologic Therapies
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland