# Appendix B: Common Drug Intoxication Signs and Withdrawal Symptoms

| Cocaine | Alcohol | Heroin | Cannabis (marijuana)
Intoxication
Action | Stimulant | Sedative | Sedative, euphoriant, analgesic | Euphoriant, at high doses may induce hallucinations
Characteristics of intoxication | □ BP, HR, temp,; □ energy,; □ paranoia,; □ fatigue,; ↓ appetite, move bowels/urinate | • Sedation, ↓respiration,; • Depresses CNS system, can result in coma, death | Drowsiness, “nodding,” euphoria (happy giddiness) | ↓BP, □HR, ↓intraocular pressure (pressure in the eyes) conjunctival injection (reddening of the eyes)
Withdrawal
Onset | Depends upon type of cocaine used: for crack will begin within hours of last use | 24–48 hours after blood alcohol level drops | Within 24 hours of last use | Some debate about this, may be a few days
Duration | 3–4 days | 5–7 days | 4–7 days | May last up to several weeks
Characteristics | Sleeplessness or excessive restless sleep, appetite increase, depression, paranoia, decreased energy | □BP, □HR, □temp, nausea/vomiting/diarrhea, seizures, delirium, death | Nausea, vomiting, diarrhea, goose bumps, runny nose, teary eyes, yawning | Irritability, appetite disturbance, sleep disturbance, nausea, concentration problems, nystagmus, diarrhea
Medical/psychiatric issues | Stroke, cardiovascular collapse, myocardial and other organ infarction, paranoia, violence, severe depression, suicide | Virtually every organ system is affected (e.g., cardiomyopathy, liver disease, esophageal and rectal varices); fetal alcohol syndrome and other problems with fetus | During withdrawal individual may become dehydrated