# Consensus Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

## Chair

Norman S. Miller, M.D., FASAM
Professor and Director of Addiction Medicine
Department of Psychiatry
Michigan State University
East Lansing, Michigan

## Co-Chair

Steven S. Kipnis, M.D., FACP
Medical Director
Russell E. Blaisdell Addiction Treatment Center
New York State Office of Alcoholism and Substance Abuse Services
Orangeburg, New York

## Workgroup Managers and Co-Managers

Anne M. Herron, M.S.
Director
Division of State and Community Assistance
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Ronald J. Hunsicker, D.Min., FACATA
President/Chief Executive Officer
National Association of Addiction Treatment Providers
Lancaster, Pennsylvania

Robert J. Malcolm, Jr., M.D.
Professor of Psychiatry, Family Medicine, and Pediatrics
Associate Dean for Continuing Medical Education
Center for Drug and Alcohol Programs
Institute of Psychiatry
Medical University of South Carolina
Charleston, South Carolina

Anthony Radcliffe, M.D., FASAM
Chief of Addiction Medicine
Kaiser Permanente
Southern California Permanente Medical Group
Fontana, California

Carl Rollynn Sullivan, III, M.D.
Professor
Director of Addiction Program
Department of Behavioral Medicine and Psychiatry
School of Medicine
West Virginia University
Morgantown, West Virginia

Nancy R. VanDeMark, M.S.W.
Director of Colorado Social Research Associates
Arapahoe House, Inc.
Thornton, Colorado

## Panelists

Louis E. Baxter, Sr., M.D., FASAM
Executive Director
Physicians Health Program
Medical Society of New Jersey
Lawrenceville, New Jersey

Kenneth O. Carter, M.D., M.P.H., Dipl.Ac.
Psychiatrist
Acupuncture Detoxification Specialist
Carolinas Medical Center
Charlotte, North Carolina

Jean Lau Chin, M.A., Ed.D., ABPP
President
CEO Services
Alameda, California

Charles A. Dackis, M.D.
Assistant Professor
Department of Psychiatry
University of Pennsylvania School of Medicine
Philadelphia, Pennsylvania

Sylvia J. Dennison, M.D.
Chief/Medical Director
Division of Addiction Services
Department of Psychiatry
University of Illinois
Chicago, Illinois

Patricia L. Mabry, Ph.D.
Health Scientist Administrator/Behavioral Scientist
Office of Behavioral and Social Sciences Research
Office of the Director
National Institutes of Health
Bethesda, Maryland

Hendree E. Jones, M.A., Ph.D.
Assistant Professor
CAP Research Director
Department of Psychiatry and Behavioral Sciences
Johns Hopkins University Center
Baltimore, Maryland

Frances J. Joy, R.N., CD, CASAC
Manager
Alcohol and Drug Abuse Unit
State of Missouri Department of Mental Health
Fulton State Hospital
Fulton, Missouri