# KAP Expert Panel and Federal Government Participants

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

Barry S. Brown, Ph.D.
Adjunct Professor University of North Carolina at Wilmington Carolina Beach, North Carolina

Jacqueline Butler, M.S.W., LISW, LPCC, CCDC III, CJS
Professor of Clinical Psychiatry College of Medicine University of Cincinnati Cincinnati, Ohio

Deion Cash
Executive Director Community Treatment and Correction Center, Inc. Canton, Ohio

Debra A. Claymore, M.Ed.Adm.
Owner/Chief Executive Officer WC Consulting, LLC Loveland, Colorado

Carlo C. DiClemente, Ph.D.
Chair Department of Psychology University of Maryland Baltimore County Baltimore, Maryland

Catherine E. Dube, Ed.D.
Independent Consultant Brown University Providence, Rhode Island

Jerry P. Flanzer, D.S.W., LCSW, CAC
Chief, Services Division of Clinical and Services Research National Institute on Drug Abuse Bethesda, Maryland

Michael Galer, D.B.A.
Chairman of the Graduate School of Business University of Phoenix—Greater Boston Campus Braintree, Massachusetts

Renata J. Henry, M.Ed.
Director Division of Alcoholism, Drug Abuse, and Mental Health Delaware Department of Health and Social Services New Castle, Delaware

Joel Hochberg, M.A.
President Asher & Partners Los Angeles, California

Jack Hollis, Ph.D.
Associate Director Center for Health Research Kaiser Permanente Portland, Oregon

Mary Beth Johnson, M.S.W.
Director Addiction Technology Transfer Center University of Missouri—Kansas City Kansas City, Missouri

Eduardo Lopez, B.S.
Executive Producer EVS Communications Washington, DC

Holly A. Massett, Ph.D.
Academy for Educational Development Washington, DC

Diane Miller
Chief Scientific Communications Branch National Institute on Alcohol Abuse and Alcoholism Bethesda, Maryland

Harry B. Montoya, M.A.
President/Chief Executive Officer Hands Across Cultures Espanola, New Mexico

Richard K. Ries, M.D.
Director/Professor Outpatient Mental Health Services Dual Disorder Programs Seattle, Washington

Gloria M. Rodriguez, D.S.W.
Research Scientist Division of Addiction Services NJ Department of Health and Senior Services Trenton, New Jersey

Everett Rogers, Ph.D.
Center for Communications Programs Johns Hopkins University Baltimore, Maryland

Jean R. Slutsky, P.A., M.S.P.H.
Senior Health Policy Analyst Agency for Healthcare Research & Quality Rockville, Maryland

Nedra Klein Weinreich, M.S.
President Weinreich Communications Canoga Park, California

Clarissa Wittenberg
Director Office of Communications and Public Liaison National Institute of Mental Health Kensington, Maryland

## Consulting Members

Paul Purnell, M.A.
Social Solutions, L.L.C. Potomac, Maryland

Scott Ratzan, M.D., M.P.A., M.A.
Academy for Educational Development Washington, DC

Thomas W. Valente, Ph.D.
Director, Master of Public Health Program Department of Preventive Medicine School of Medicine University of Southern California Alhambra, California

Patricia A. Wright, Ed.D.
Independent Consultant Baltimore, Maryland