# Consensus Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

## Co-Chair

Roger H. Peters, Ph.D.
Professor Department of Law and Mental Health Florida Mental Health Institute University of South Florida Tampa, Florida

## Co-Chair

Harry K. Wexler, Ph.D.
Senior Principal Investigator National Development and Research Institute, Inc. New York, New York

## Workgroup Leaders

Steven R. Belenko, Ph.D.
National Center on Addiction and Substance Abuse Columbia University New York, New York

Nahama Broner, Ph.D.
Senior Research Psychologist Center for Crime, Violence and Justice Research New York, New York

Christopher J. Geiger
Vice President/Director of Criminal Justice Programs Walden House, Inc. San Francisco, California

Kevin Knight, Ph.D.
Research Scientist Texas Christian University Fort Worth, Texas

Michael D. Link, M.C.J.
Chief Division of Treatment and Planning Ohio Department of Alcohol and Drug Addiction Services Columbus, Ohio

Henry Jay Richards, Ph.D.
Associate Professor University of Washington Seattle, Washington

Sally J. Stevens, Ph.D.
Research Professor Social and Behavioral Sciences Southwest Institute for Research on Women University of Arizona Tucson, Arizona

## Panelists

Elaine Abraham
Program Developer/Consultant National Development and Research, Inc. Chula Vista, California

E. Bernard Anderson, Jr., M.S., M.A., NCAC, ICADC, CCS
Regional Administrator Correctional Treatment Florida Addictions and Correctional Treatment Services, Inc. Tallahassee, Florida

Annabelle Casas-Mendoza, M.A.
Family Treatment Drug Court 65th District Court El Paso, Texas

Deion Cash
Executive Director Community Treatment & Correction Center, Inc. Canton, Ohio

Kimberly S. Hee, M.A.
Grants Program Specialist Office of the Mayor Criminal Justice Planning Los Angeles, California

Mack Jenkins, B.A.
Division Director Adult Court Services Orange County Probation Department Santa Ana, California

Carl G. Leukefeld, D.S.W.
Director Center on Drug and Alcohol Research University of Kentucky Lexington, Kentucky

Erik J. Roskes, M.D.
Director Forensic Treatment and Correctional Services School of Medicine Springfield Hospital Center Sykesville, Maryland