# 1 Introduction

In This Chapter…

The Purpose of This TIP

Key Definitions

Audience for This TIP

Contents of This TIP

When the prison gates slam behind an inmate, he does not lose his human quality; his mind does not become closed to ideas; his intellect does not cease to feed on a free and open interchange of opinions; his yearning for self-respect does not end; nor is his quest for self-realization concluded. If anything, the needs for identity and self-respect are more compelling in the dehumanizing prison environment.

—Thurgood Marshall (Procunier v. Martinez, 416 U.S. 396 [1974])

## Overview

Research consistently demonstrates a strong connection between criminal activity and substance abuse (Chaiken 1986; Inciardi 1979; Johnson et al. 1985). Eighty-four percent of State prison inmates who expected to be released in 1999 were involved with alcohol or illicit drugs at the time of their offense; 45 percent reported that they were under the influence when they committed their crime; and 21 percent indicated that they committed their offense for money to buy drugs (Office of National Drug Control Policy [ONDCP] 2003). Data from the Arrestee Drug Abuse Monitoring program indicate that in 2000, 64 percent of male arrestees tested positive for at least one of five illicit drugs (cocaine, opioids, marijuana, methamphetamines, and PCP). Additionally, 57 percent reported binge drinking in the 30 days prior to arrest, and 36 percent reported heavy drinking (Taylor et al. 2001).

The consequences of crime related to substance abuse are substantial. The Bureau of Justice Statistics reports that in 1999 alone, 12,658 homicides—4.5 percent of all homicides for that year—were drug related (Dorsey et al. 1999). The emotional costs to people with substance use disorders, their families, and the victims of their crimes are immeasurable. The ONDCP estimates that the total crime-related costs of drug abuse were more than $100 billion in 2000 (ONDCP 2001).

The devastating emotional and financial costs of drug-related crimes have led to a number of strategies to break the link between drugs and crime, including stricter drug laws, “three strikes and you're out” legislation, increased surveillance, mandatory sentencing laws, and severe penalties for drunk drivers, to name just a few. These approaches have had mixed results, and opinions vary on their usefulness.

One consistent research finding is that involvement in substance abuse treatment reduces recidivism (a tendency to return to criminal habits) for offenders who use drugs (Anglin and Hser 1990; Harwood et al. 1988; Hubbard et al. 1984, 1989; Knight et al. 1999a; Martin et al. 1999; McLellan et al. 1983; Wexler et al. 1988, 1999a; Wisdom 1999). For example, when researchers conducted followup studies of clients treated through comprehensive treatment demonstration programs funded by the Center for Substance Abuse Treatment (CSAT), they found substantial reductions in criminal activity, including a 64-percent decrease in arrests (Wisdom 1999). In part because of the reduced criminal activity associated with substance abuse treatment for offenders, treatment has also been found to be cost-effective. According to the California Drug and Alcohol Treatment Assessment study (Gerstein et al. 1994), for example, every dollar invested in treatment saved approximately $7 in future costs.

In response to research demonstrating the success of treatment in reducing criminal activity as well as the cost benefits of such treatment, policymakers over the past two decades have implemented a wide variety of strategies at the Federal, State, and local levels. These initiatives are aimed at improving the availability and quality of treatment for offenders. Drug Courts—courts with special unified dockets for individuals charged with crimes who are drug or alcohol involved—serve to divert offenders with substance use disorders away from the criminal justice system into a supervised treatment plan or to incorporate a coerced treatment plan as part of a judicial sentence. Other programs have been established for people with special needs, including individuals with co-occurring mental disorders. At the same time, other initiatives have increased funding for people already in prisons and jails. Examples of such initiatives include

• Project REFORM and later Project RECOVERY. These programs, funded in the late 1980s by the Bureau of Justice Assistance (BJA) and in the early 1990s by CSAT, provided technical assistance to 20 States in planning and developing substance abuse programming for prisoners with substance abuse problems (Wexler 1995).
• Residential Substance Abuse Treatment for State Prisoners Formula Grant Program. This program funds States seeking to develop comprehensive approaches to treatment for offenders who abuse substances, including intensive programs for inmates and relapse prevention training. Further information is available at http://www.cfda.gov.
• The National Drug Control Strategy, prepared annually by the Office of National Drug Control Policy (1997, 1998, 1999, 2000, 2001). This program has encouraged the development of treatment and rehabilitation services for offenders who use drugs (e.g., Treatment Accountability for Safer Communities, formerly Treatment Alternatives to Street Crime; drug court programs; prison treatment programs). For further information, go to http://www.whitehouse.gov/ondcp.
• The BJA, Office of Justice Programs, U.S. Department of Justice. Formerly known as the Drug Courts Program Office, established to administer the drug court grant program, the BJA provides financial and technical assistance, training, and programmatic guidance for drug courts throughout the country. BJA offers grants that enable communities to develop, implement, or improve drug courts. Information is available at http://www.bja.gov
• The Serious and Violent Offender Reentry Initiative. In conjunction with several Federal partners, the U.S. Department of Justice is spearheading this initiative to provide funding to promote successful reintegration of serious, high-risk offenders into the community. The Initiative seeks to address all obstacles to successful reentry, including substance abuse. Information is available online at http://www.crimesolutions.gov/ProgramDetails.aspx?ID=167.

In part because of initiatives such as these, the availability of substance abuse treatment for criminal offenders is on the rise. After 3 years of decline in the mid-1990s, the number of inmates in drug treatment programs began rising again in 1997 and 1998 (Corrections Yearbook 1998). A report based on a 1997 nationwide survey of Federal and State correctional facilities (Office of Applied Studies 2000) indicates that 93.8 percent of Federal prisons and 56.3 percent of State prisons provide some form of substance abuse treatment.

Although an increasing number of prisons offer some form of treatment, the actual number of programs and slots remains limited (National Center on Addiction and Substance Abuse at Columbia University 1998; Peters and Matthews 2002). For example, although more than half of prison inmates have a lifetime prevalence of drug use disorders (Peters et al. 1998), fewer than 15 percent of inmates receive substance abuse treatment services while in prison (Mumola 1999; Simpson et al. 1999b). Moreover, while the number of substance abuse programs for offenders is on the rise, so too is the number of offenders in need of services. Substance abuse treatment services for offenders have not kept pace with the growing need for these services (Belenko and Peugh 1998; Simpson et al. 1999b).

This TIP highlights some of the best practices and innovative programs created to treat offenders. It describes the unique needs of offenders with substance abuse and dependence disorders. Finally, it addresses the challenges counselors and criminal justice personnel are likely to face at every stage of the criminal justice continuum.

## The Purpose of This TIP

This TIP updates and combines three TIPs originally published in 1994 and 1995: TIP 7, Screening and Assessment for Alcohol and Other Drug Abuse Among Adults in the Criminal Justice System (CSAT 1994d); TIP 12, Combining Substance Abuse Treatment With Intermediate Sanctions for Adults in the Criminal Justice System (CSAT 1994a); and TIP 17, Planning for Alcohol and Other Drug Abuse Treatment for Adults in the Criminal Justice System (CSAT 1995b).

One consistent research finding is that involvement in substance abuse treatment reduces recidivism for offenders who use drugs.

The new TIP presents clinical guidelines to assist counselors in dealing with problems that routinely arise because of their clients' status in the criminal justice system. These clients have multiple needs; they often have poor health, have histories of trauma, lack job and communication skills, and have educational deficits. A special feature throughout the TIP—“Advice to the Counselor”—provides the TIP's most direct and accessible guidance for the counselor. Readers with basic backgrounds, such as addiction counselors or other practitioners, can study these boxes first for the most immediate practical guidance. In particular, the Advice to the Counselor boxes provide a distillation of what the counselor needs to know and what steps to take, which can be followed by a more detailed reading of the relevant material in the section or chapter.

The events of September 11, 2001, dramatically altered the political climate of our Nation and caused a shift in focus from the “tough on drugs” policies previously in place to the war on terrorism. These changes have impacted both the sanctions against people in the criminal justice system and the availability of substance abuse treatment for those populations. While it is beyond the scope of this TIP to address the implications of these shifts or to predict their ultimate outcomes, the core content of this document reflects the current best practices for providing substance abuse treatment for adults in the criminal justice system.

This TIP aims to provide tools and resources to increase the availability and improve the quality of substance abuse treatment to criminal justice clients. It should assist the criminal justice system in meeting the challenges of working with offenders with substance use disorders and encourage the implementation of evidence-based clinical approaches to treatment.

Other guiding principles of this publication are to

• Provide the relevant information that will inform and enable treatment providers to feel more confident in their approach to offender and ex-offender populations.
• Help people in community treatment understand the criminal justice system and how it works in step with their treatment services.
• Encourage collaboration between the criminal justice and treatment communities.
• Help readers understand the multiple perspectives that often lead to confusion and misunderstandings—public safety versus public health, treatment versus corrections, differing client needs, issues of culture and society, and local characteristics of the criminal justice system.
• Provide practical solutions and approaches to complex problems.

## Key Definitions

In this TIP, the term “substance abuse” is used to denote both substance abuse and substance dependence as they are defined by the Diagnostic and Statistical Manual of Mental Disorders, Fourth Edition, Text Revision (DSM-IV-TR) (American Psychiatric Association 2000). This term was chosen partly because substance abuse treatment professionals commonly use the term “substance abuse” to describe any excessive use of addictive substances. Readers should attend to the context in which the term occurs to determine the possible range of meanings it covers; in most cases, however, the term will refer to all varieties of substance use disorders described by DSM-IV-TR.

According to DSM-IV-TR, substance abuse is a maladaptive pattern of substance use marked by recurrent and significant negative consequences related to the repeated use of substances. Substance dependence is defined as a cluster of cognitive, behavioral, and physiological symptoms indicating that the individual is continuing use of the substance despite significant substance-related problems. A person experiencing substance dependence shows “a pattern of repeated self-administration that usually results in tolerance, withdrawal, and compulsive drug-taking behavior” (p. 192). A diagnosis of substance dependence can be applied to every class of substances except caffeine.

Treatment is defined according to the Institute of Medicine (IOM 1990), as cited in CSAT's National Treatment Plan Initiative (CSAT 2000a, b):

Treatment refers to the broad range of [primary and supportive] services—including identification, brief intervention, assessment, diagnosis, counseling, medical services, psychiatric services, psychological services, social services, and followup—provided for people with alcohol [and/or drug] problems. The overall goal of treatment is to reduce or eliminate the use of alcohol [and/or drugs] as a contributing factor to physical, psychological, and social dysfunction and to arrest, retard, or reverse the progress of any associated problems (CSAT 2000a, p. 7).

The criminal justice system, as discussed in this TIP, includes four subsystems: pretrial and diversion settings, jails and detention centers, prisons (State and Federal), and community supervision settings. Definitions of other terms relevant to criminal justice and substance abuse treatment are given in appendix B, Glossary.

For the purposes of this TIP, an offender is a person who has been arrested, charged with a crime, or convicted of a crime and under the supervision of the criminal justice system.

## Audience for This TIP

This TIP is written primarily for substance abuse counselors and clinicians who treat clients involved in the criminal justice system or who are under full or partial supervision and for administrators whose programs serve clients under criminal justice supervision. It also will be useful for counselors who work in correctional institutions and those in community agencies with clients on probation, parole, or pretrial release.

Others who work in the criminal justice system may also find this TIP helpful. This includes judges and prosecutors; probation and parole officers, case managers, public defenders and other criminal defense attorneys; jail, detention center, and prison personnel; and people working in pretrial/diversion and in probation and parole settings.

Program developers and grant writers will find that this TIP provides information about a variety of programs and resources. Finally, this TIP is of value to anyone concerned with reducing overcrowding in correctional facilities, addressing the crimes committed by untreated drug-involved offenders, and meeting the challenges that these offenders face on their journey toward recovery.

## Contents of This TIP

The chapters that follow will focus on the following areas:

• Chapter 2 focuses on screening and assessment of criminal justice clients in the relevant domains. It includes a discussion of special concerns (e.g., gender and sexual orientation, literacy, a client's primary language, and learning disabilities) and specific populations. See also appendix C, which contains more information on screening and assessment instruments.
• Although it is recognized that treatment can be effective, it is also clear that different treatment approaches may work better with some clients than with others. Chapter 3 discusses triage and placement in treatment services and reviews the complex area of treatment matching.
• Chapter 4 discusses the available treatment options in the criminal justice system. It also presents guidelines for developing treatment plans.
• Chapter 5 addresses the major treatment issues for offenders who use substances. These include a wide range of themes, including engagement and retention, stigma and shame, the client–counselor relationship, and major treatment levels (e.g., residential, nonresidential, outpatient, community supervised, and self-help and other ancillary services).
• Chapter 6 describes treatment issues and approaches for special populations for whom modifications in treatment may be appropriate: people of ethnic and racial minorities, women, violent offenders, people with disabilities, older inmates, people with co-occurring substance use and mental disorders, and sex offenders, among others.
• Chapters 7 through 10 describe the specific treatment needs and strategies for individuals in particular criminal justice settings. Chapter 7 addresses treatment provided in diversion and other pretrial settings. Chapter 8 provides a detailed discussion of treatment for offenders in jails and detention centers, while Chapter 9 focuses on offenders in prison. Chapter 10 outlines treatment for people under community supervision.
• Finally, Chapter 11 discusses the issues related to program development.

This TIP aims to provide tools and resources to increase the availability and improve the quality of substance abuse treatment to criminal justice clients.