# Appendix H—Acknowledgments

Numerous people contributed to the development of this TIP, including the TIP Consensus Panel (see page xi), the Knowledge Application Program (KAP) Expert Panel and Federal Government Participants (see page xiii), the SAMHSA Resource Panel Meeting attendees, (see Appendix D), the KAP Cultural Competency and Diversity Network participants (see Appendix E), Special Consultants (see Appendix F), and TIP Field Reviewers (see Appendix G).

This publication was produced under KAP, a Joint Venture of The CDM Group, Inc. (CDM), and JBS International, Inc. (JBS), for the Substance Abuse and Mental Health Services Administration, Center for Substance Abuse Treatment.

CDM KAP personnel included Rose M. Urban, M.S.W., J.D., LCSW, LCAS, KAP Executive Deputy Project Director; Susan Kimner, Managing Project Co-Director; Elizabeth Marsh, former KAP Deputy Project Director; Sheldon Weinberg, KAP Senior research/Applied Psychologist; Raquel Witkin, former Deputy Project Manager; Deborah Steinbach, former Editor/Writer; Janet Humphrey, former Editor/Writer; Michelle Myers, former Quality Assurance Editor; Elizabeth Plevyak, former Editorial Assistant; and Virgie D. Paul, M.L.S., Librarian.