# Appendix G: Field Reviewers

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

Robert B. Auckerman, M.S.W.
Program Services Consultant Littleton, Colorado

Joanne Barnett, M.Ed., LPC, LADC, CCS, CDP, MAC, CCJS
Addiction Services Coordinator Community Partners in Action Hartford, Connecticut

Sonya Brown
State TASC Director Division of Mental Health Developmental Disabilities and Substance Abuse Services, HHS Raleigh, North Carolina

Barry S. Brown, Ph.D.
Adjunct Professor University of North Carolina at Wilmington Carolina Beach, North Carolina

Eddie Canterbury, LCSW, BCSAC
Social Worker Specialist—LCSW Rapides Adult Drug Treatment Court Alexandria, Louisiana

Redonna Chandler, Ph.D.
Health Scientist Administrator Services Research Branch National Institute on Drug Abuse Bethesda, Maryland

Laura Choate
Manager Office of Drug Court Programs California Department of Alcohol and Drug Programs Sacramento, California

Richard Craig, Ph.D.
Director of Research Patuxent Institution Jessup, Maryland

George De Leon, Ph.D.
Director Center for Therapeutic Community Research National Development and Research Institutes, Inc. New York, New York

David Farabee
Research Psychologist UCLA Integrated Substance Abuse Programs Los Angeles, California

Kathleen J. Farkas, Ph.D., LISW
Mandel School of Applied Social Sciences Case Western Reserve University Cleveland, Ohio

Jerry P. Flanzer, D.S.W., LCSW, CAC
Chief Services Research Branch National Institute on Drug Abuse Bethesda, Maryland

Richard S. Gebelein
Judge Superior Court of Delaware Wilmington, Delaware

Bobby G. Greer, Ph.D., LPC, CCRC
Memphis, Tennessee

Hendree E. Jones, Ph.D.
Assistant Professor CAP Research Director Department of Psychiatry and Behavioral Sciences Johns Hopkins University Center Baltimore, Maryland

Margaret Williams Kherlopian
Coordinator of Criminal Justice Programs South Carolina Department of Alcohol and Other Drug Abuse Services Columbia, South Carolina

Kevin Knight, Ph.D.
Research Scientist Texas Christian University Fort Worth, Texas

Jeffrey N. Kushner, M.A., M.H.R.A.
Drug Court Administrator Municipal Court of Saint Louis Saint Louis, Missouri

Gerald Melnick, Ph.D.
Senior Principal Investigator National Development and Research Institutes, Inc. New York, New York

Ethan Nebelkopf, Ph.D., MFCC
Clinic Director Family and Child Guidance Center Native American Health Center Oakland, California

Michael L. Prendergast, Ph.D.
Director Criminal Justice Research Group UCLA Integrated Substance Abuse Programs Los Angeles, California

JoAnn Y. Sacks, Ph.D.
Principal Investigator National Development and Research Institutes New York, New York

Robert Philip Schwartz, M.D.
Medical Director Friends Research Institute Baltimore, Maryland

Elizabeth Simoni, J.P.
Executive Director Maine Pretrial Services, Inc. Portland, Maine

Elizabeth Stanley-Salazar
Vice President Director of Public Policy Phoenix Houses of California Lake View Terrace, California

Richard E. Steinberg, M.S.
President/Chief Executive Officer WestCare Foundation, Inc. Las Vegas, Nevada

Pamela D. Stokes, M.S.M.
Program Analyst National Association of State Alcohol and Drug Abuse Directors, Inc. Washington, DC

Richard T. Suchinsky, M.D.
Associate Director for Addictive Disorders and Psychiatric Rehabilitation Mental Health and Behavioral Sciences Services Department of Veterans Affairs Washington, DC

Anne Swern
Counsel to the District Attorney of Kings County Kings County District Attorney, Charles J. Hynes Brooklyn, New York

Faye S. Taxman, Ph.D.
Director Bureau of Governmental Research University of Maryland College Park, Maryland

Angel Velez, CASAC
Addiction Program Specialist-II New York State Office of Alcohol and Substance Abuse Services New York, New York

Pogos H. Voskanian, M.D.
Huntingdon Valley, Pennsylvania

Robert Walker, M.S.W., LCSW
Assistant Professor Center on Drug and Alcohol Research University of Kentucky Lexington, Kentucky

Suzanne L. Wenzel, Ph.D.
Behavioral Scientist RAND Santa Monica, California

Karen M. Wheeler
Program and Policy Development Specialist Office of Mental Health and Addiction Services Salem, Oregon

Dorian L. Wingard, B.A., CCDC
Education Coordinator Chair Education Committee Education Resource Center Steven's House Residential Treatment Center for Adolescents A House of Hope, Inc. Program Columbus, Ohio

Edie Wooldridge, B.A., CADC II
Program Manager InterChange Treatment Program Multnomah County Department of Community Justice Hillsboro, Oregon

Buck Zeller
RCE Director, TASC Region IV Blue Ridge Center Asheville, North Carolina