# Appendix F: Special Consultants

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

Gary Field, Ph.D.
Administrator Counseling and Treatment Services Correctional Programs Oregon Department of Corrections Salem, Oregon

Thomas J. Tobin, Ph.D.
Chief Executive Officer/Co-Founder The SHARP Program Orinda, California