# Appendix E: Cultural Competency and Diversity Network Participants

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

Elmore T. Briggs, CCDC, NCAC II
Program Manager Adolescent Recovery Center Vanguard Services Unlimited Arlington, Virginia African American Workgroup

Deion Cash
Executive Director Community Treatment & Correction Center, Inc. Canton, Ohio African American Workgroup

E. Bernard Anderson, Jr., M.S., M.A., NCAC, ICADC, CCS
Regional Administrator Correctional Treatment Florida Addictions and Correctional Treatment Services, Inc. Tallahassee, Florida LGBT Workgroup

Richard T. Suchinsky, M.D.
Associate Director for Addictive Disorders and Psychiatric Rehabilitation Mental Health and Behavioral Sciences Services Department of Veterans Affairs Washington, DC Disabilities Workgroup