# Appendix D: Resource Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

Linell P. Broecker, M.S.W.
Senior Prevention Programs Manager Demand Reduction Section Drug Enforcement Administration Washington, DC

Patrick Coleman
Deputy Director Bureau of Justice Assistance Washington, DC

Cathi Coridan, M.A.
Senior Director for Substance Abuse Programs and Policy National Mental Health Association Alexandria, Virginia

Gloria Danzinger
Staff Director Standing Committee on Substance Abuse American Bar Association Washington, DC

Peter J. Delany, D.S.W.
Deputy Director Division of Epidemiology, Services and Prevention Research National Institute on Drug Abuse Bethesda, Maryland

Jennifer Kay Edwards, M.A.
Assistant to the Deputy Director Corrections Program Office U.S. Department of Justice Washington, DC

Jerry P. Flanzer, D.S.W., LCSW, CAC Chief
Services Research Branch National Institute on Drug Abuse Bethesda, Maryland

Irene Gainer
Executive Director Treatment Accountability for Safer Communities Arlington, Virginia

R.J. Gregrich, M.S. Chief
Treatment Branch Office of Demand Reduction Office of National Drug Control Policy Washington, DC

Stephen J. Ingley
Executive Director American Jail Association Hagerstown, Maryland

Jane E. Kennedy, M.P.A., CDP
Executive Director Treatment Alternatives to Street Crime Seattle, Washington

Bruce R. Lorenz, B.S., CADC, NCAC II
Director Thresholds, Inc. Georgetown, Delaware

Cranston Mitchell
Correctional Program Specialist Community Corrections Division National Institute of Corrections Washington, DC

Stacia Murphy
President National Council on Alcoholism and Drug Dependence New York, New York

Madeline Ortiz
Corrections Program Specialist Prisons Division National Institute of Corrections Washington, DC

Marjorie A. Rock, Dr.P.H.
Associate Professor Ehrenkranz School of Social Work New York University New York, New York

Erik J. Roskes, M.D.
Director Forensic Treatment and Correctional Services School of Medicine Springfield Hospital Center Sykesville, Maryland

Susan E. Salasin
Director Mental Health and Criminal Justice Program Center for Mental Health Services Rockville, Maryland

Mary K. Shilton
Executive Director National Treatment Accountability for Safer Communities Washington, DC

Audrey Wright Spolarich
Health Policy Analysts, Inc. Washington, DC

Patrick H. Tarr, Ph.D.
Senior Policy Advisor Office of Policy Development U.S. Department of Justice Washington, DC

Jennifer Taussig, M.P.H.
Health Scientist Centers for Disease Control and Prevention Atlanta, Georgia

Vicky Verdeyen
Psychology Administrator Bureau of Prisons Department of Justice Washington, DC

Beth A. Weinman, M.A.
National Drug Abuse Treatment Coordinator Federal Bureau of Prisons Department of Justice Washington, DC

Steve Wing
Senior Advisor for Drug Policy Office of Policy and Program Coordination Substance Abuse and Mental Health Services Administration Rockville, Maryland