# Appendix A: Bibliography

Acoca, L. Defusing the time bomb: Understanding and meeting the growing health care needs of incarcerated women in America. Crime and Delinquency 44(1):49–69, 1998.
Acoca, L., and Austin, J. The Crisis: Women in Prison. Oakland, CA: National Council on Crime and Delinquency, 1996.
Addiction Technology Transfer Center. Criminal Justice/Substance Abuse Cross Training: Working Together for Change. Virginia; Maryland; North Carolina: Mid-Atlantic Addiction Technology Transfer Center, 1998a.
Addiction Technology Transfer Center. Training for Professionals Working With MICA Offenders: Cross Training for Staff in Law Enforcement, Mental Health & Substance Abuse Settings. Albany, NY: Northeastern States Addiction Technology Transfer Center, 1998b.
Addiction Technology Transfer Center. Working With Criminal Justice Clients. Albany, NY: Northeastern States Addiction Technology Transfer Center, 1998c.
Addiction Technology Transfer Center. Orientation to Therapeutic Community. Item #M08. Missouri; Kansas; Minnesota: Mid-America Addiction Technology Transfer Center, 1999a.
Addiction Technology Transfer Center. Therapeutic Community Experiential Training. Albany, NY: Mid-Atlantic Technology Transfer Center, 1999.
Addiction Technology Transfer Center. Corrections and Substance Abuse Treatment: Putting the Two Systems Together. California; Arizona; New Mexico: Pacific Southwest Addiction Technology Transfer Center, 2000.
Alarid, L.F. Sexual orientation perspectives of incarcerated bisexual and gay men: The county jail protective custody experience. Prison Journal 80(1):80–95, 2000.
Alterman, A.I., McDermott, P.A., Cook, T.G., Metzger, D., Rutherford, M.J., Cacciola, J.S., and Brown, L.S. New scales to assess change in the Addiction Severity Index for the opioid, cocaine, and alcohol dependent. Psychology of Addictive Behaviors 12(4):233–246, 1998.
American Civil Liberties Union. ACLU Applauds Supreme Court Ruling Protecting Disabled Prisoners. Press release, June 15, 1998. New York: American Civil Liberties Union.
American Correctional Association. Standards for Adult Correctional Institutions. 3d ed. Lanham, MD: American Correctional Association, 1990.
American Educational Research Association, American Psychological Association, and National Council on Measurement in Education. Standards for Educational and Psychological Testing. Washington, DC: American Educational Research Association, 1999.
American Psychiatric Association. Diagnostic and Statistical Manual of Mental Disorders. 4th ed. Washington, DC: American Psychiatric Association, 1994.
American Psychiatric Association. Diagnostic and Statistical Manual of Mental Disorders. 4th ed. Text Revision. Washington, DC: American Psychiatric Association, 2000.
American Society of Addiction Medicine. Patient Placement Criteria for the Treatment of Substance-Related Disorders: ASAM PPC-2R. 2d - Revised ed. Chevy Chase, MD: American Society of Addiction Medicine, 2001.
Anderson, S.W., Bechara, A., Damasio, H., Tranel, D., and Damasio, A.R. Impairment of social and moral behavior related to early damage in human prefrontal cortex. Nature Neuroscience 2(11):1032–1037, 1999.10526345
Andrews, D.A., and Bonta, J. Level of Service Inventory–Revised User's Manual. Toronto, ON: Multi Health Systems, 1995.
Andrews, D.A., and Bonta, J. The Psychology of Criminal Conduct. 2d ed. Cincinnati, OH: Anderson Publishing Co., 1998.
Andrews, D.A., Zinger, I., and Hoge, R.D. Does correctional treatment work?: A clinically relevant and psychologically informed meta-analysis. Criminology 28(3):369–404, 1990.
Anglin, M.D., and Hser, Y.I. Treatment of drug abuse. In: Tonry, M., and Wilson, J.Q., eds. Drugs and Crime. Chicago: University of Chicago Press, 1990. pp. 393–460.
Anglin, M.D., Longshore, D., and Turner, S. Treatment Alternatives to Street Crime: An evaluation of five programs. Criminal Justice & Behavior 26(2):168–195, 1999.
Anglin, M.D., Prendergast, M., and Farabee, D. “The effectiveness of coerced treatment for drug-abusing offenders.” Paper presented at the Office of National Drug Control Policy's Conference of Scholars and Policy Makers, Washington, DC, March 23–25, 1998.
Antonowicz, D.H., and Ross, R.R. Essential components of successful rehabilitation programs for offenders. International Journal of Offender Therapy and Comparative Criminology 38(2):97–104, 1994.
Argyris, C. Intervention Theory and Method: A Behavioral Science View. Reading, MA: Addison-Wesley, 1970.
Aspler, R., and Harding, W.M. Cost-effectiveness Analysis of Drug Abuse Treatment: Current Status and Recommendations for Future Research. NIDA Drug Abuse Services Research Series. HHS Publication No. (ADM) 91–1777. Rockville, MD: National Institute on Drug Abuse, 1991. pp. 58–81.
Association for the Treatment of Sexual Abusers. Practice Standards and Guidelines for the Members of the Association for the Treatment of Sexual Abusers (revised 2001). Beaverton, OR: Association for the Treatment of Sexual Abusers, 2001.
Barbaree, H.E., Peacock, E.J., Cortoni, F., Marshall, W.L., and Seto, M. Ontario penitentiaries program. In: Marshall, W.L., and Fernandez, Y.M., eds. Sourcebook of Treatment Programs for Sexual Offenders. New York: Plenum Press, 1998. pp. 59–77.
Beck, A.J. Prison and Jail Inmates at Midyear 1999. Washington, DC: Bureau of Justice Statistics, 2000a.
Beck, A.J. Prisoners in 1999. Washington DC: Bureau of Justice Statistics, 2000b.
Beck, A.J. State and Federal Prisoners Returning to the Community: Findings From the Bureau of Justice Statistics. Washington, DC: Bureau of Justice Statistics, 2000c.
Beck, A.J., and Karberg, J.C. Prison and Jail Inmates at Midyear 2000. Washington, DC: Bureau of Justice Statistics, 2001.
Beck, A.J., Karberg, J.C., and Harrison, P.M. Prison and Jail Inmates at Midyear 2001. Bureau of Justice Statistics Bulletin. Washington, DC: Bureau of Justice Statistics, 2002.
Beck, A.J., and Maruschak, L.M. Mental Health Treatment in State Prisons, 2000. Washington, DC: Bureau of Justice Statistics, 2001.
Beck, A.T., Steer, R.A., and Brown, G.K. Beck Depression Inventory—II Manual. San Antonio, TX: The Psychological Corporation, 1996.
Belenko, S. The impact of drug offenders on the criminal justice system. In: Weisheit, R., ed. Drugs, Crime, and the Criminal Justice System. Cincinnati, OH: Anderson Publishing Co., 1990.
Belenko, S. The challenges of integrating drug treatment into the criminal justice system. Albany Law Review 63(3):833–876, 2000.
Belenko, S. Research on Drug Courts: A Critical Review. 2001 Update. New York: National Center on Addiction and Substance Abuse, 2001.
Belenko, S., Mara-Drita, I., and McElroy, J. Drug tests and the prediction of pretrial misconduct: Findings and policy issues. Crime & Delinquency 38(4):557–582, 1992.
Belenko, S., and Peugh, J. Fighting Crime by Treating Substance Abuse. Issues in Science and Technology Online. Washington, DC: National Academy Press, 1998.
Bell, D.C. Connection in therapeutic communities. International Journal of the Addictions 29(4):525–543, 1994.
Bernstein, E.M., and Putnam, F.W. Dissociative Experiences Scale. Journal of Nervous and Mental Disease 174(12):727–735, 1986.
Bien, T.H., Miller, W.R., and Tonigan, J.S. Brief interventions for alcohol problems: A review. Addiction 88(3):315–335, 1993.8461850
Blake, D.D., Weathers, F.W., and Kaloupek, D.G. Clinician-administered PTSD scale for DSM-IV. In: Turner, S., and Deborah Lee, eds. Measures in Post Traumatic Stress Disorder: A Practitioner's Guide. London: NFER-Nelson, 1998.
Bloom, B., Chesney-Lind, M., and Owen, B. Women in California Prisons: Hidden Victims of the War on Drugs. San Francisco: Center on Juvenile and Criminal Justice, 1994.
Bonczar, T.P., and Glaze, L.E. Probation and Parole in the United States, 1998. Bureau of Justice Statistics Bulletin. NCJ 178234. Washington, DC: Office of Justice Programs, 1999.
Bonta, J. Offender Rehabilitation: From Research to Practice. Canada: Ministry of the Solicitor General of Canada, 1997.
Borum, R. Improving the clinical practice of violence risk assessment. Technology, guidelines, and training. American Psychologist 51(9):945–956, 1996.
Borum, R., Swanson, J., Swartz, M., and Hiday, V. Substance abuse, violent behavior, and police encounters among persons with severe mental disorder. Journal of Contemporary Criminal Justice 13(3):236–250, 1997.
Botvin, G.J., Baker, E., Renick, N.L., Filazzola, A.D., and Botvin, E.M. A cognitive-behavioral approach to substance abuse prevention. Addictive Behaviors 9(2):137–147, 1984.6611026
Boulet J., and Boss M.W. Reliability and validity of the Brief Symptom Inventory. Psychological Assessment 3:433–437, 1991.
Bradley, K.A., Boyd-Wickizer, J., Powell, S.H., and Burman, M.L. Alcohol screening questionnaires in women: A critical review. Journal of the American Medical Association 280(2):166–171, 1998.9669791
Brady, D. Radical treatment. Maclean's 106(17):38–41, 1993.
Briere, J. Trauma Symptom Inventory: Professional Manual. Odessa, FL: Psychological Assessment Resources, 1995.
Briere, J., and Runtz, M. The Trauma Symptom Checklist (TSC-33): Early data on a new scale. Journal of Interpersonal Violence 4(2):151–163, 1989.
Brinkley, C.A., Schmitt, W.A., Smith, S.S., and Newman, J.P. Construct validation of a self-report psychopathy scale: Does Levenson's Self-report Psychopathy Scale measure the same constructs as Hare's Psychopathy Checklist-Revised? Personality & Individual Differences 31(7):1021–1038, 2001.
Broner, N., Borum, R., Gawley, K., and Whitmire, L. A review of screening instruments for co-occurring mental illness and substance use in criminal justice programs. In: Landsberg, G., Rock, M., and Berg, L., eds. Serving Mentally Ill Offenders: Challenges and Opportunities for Mental Health Professionals. New York: Springer Publishing, 2002a. pp. 289–337.
Broner, N., Franczak, M., Dye, C., and McAllister, W. Knowledge transfer, policy-making and community empowerment: A consensus model approach for providing public mental health and substance abuse services. Psychiatric Quarterly 72(1):79–102, 2001b.
Broome, K.M., Knight, K., Hiller, M.L., and Simpson, D.D. Drug treatment process indicators for probationers and prediction of recidivism. Journal of Substance Abuse Treatment 13(6):487–491, 1996a.9219146
Broome, K.M., Knight, K., Joe, G.W., and Simpson, D.D. Evaluating the drug-abusing probationer: Clinical interview versus self-administered assessment. Criminal Justice and Behavior 23(4):593–606, 1996b.
Brown, J.M., Langan, P.A., and Levin, D.J. Felony Sentences in State Courts, 1996. Washington, DC: Bureau of Justice Statistics, 1999.
Brown, K.A. Assertive Community Treatment: A Reentry Model for Seriously Mentally Ill Offenders. Columbus, OH: The Supreme Court of Ohio, 2003.
Brown, S. Treating the Alcoholic: A Developmental Model of Recovery. New York: John Wiley and Sons, 1985.
Budman, S.H. Computer-mediated addiction services: Tomorrow won't look like today. Behavioral Healthcare Tomorrow 11(2):14–21, 2002.
Burdon, W.M., Kilian, T.C., Koutsenok, I., and Prendergast, M.L. Treating substance abusing sex offenders in a correctional environment: Lessons from the California experience. Offender Substance Abuse Report (January/February):3, 4, 11, 12, 2001.
Bureau of Justice Assistance. Integrating Drug Testing Into a Pretrial Services System: 1999 Update. NCJ 176340. Washington, DC: Bureau of Justice Assistance, 1999.
Bureau of Justice Assistance. Creating a New Criminal Justice System for the 21st Century: Findings and Results From State and Local Program Evaluations. NCJ 178936. Washington, DC: Bureau of Justice Assistance, 2000.
Burton, D., and Smith-Darden, J. North American Survey of Sexual Abuser Treatment and Models: Summary Data – 2000. Brandon, VT: The Safer Society Press, 2001.
Bush, J., Glick, B., and Taymans, J. Thinking for a Change: Integrated Cognitive Behavior Change Program. Longmont, CO: National Institute of Corrections, 2000. nicic.org/Library/016672 [Accessed March 28, 2005].
Butcher, J.N., Graham, J.R., Ben-Porath, Y.S., Tellegen, A., Dahlstrom, W.G., and Kaemmer, B. Minnesota Multiphasic Personality Inventory-2 (MMPI-2): Manual for Administration, Scoring and Interpretation (Revised Edition). Minneapolis, MN: University of Minnesota Press, 2001.
Butler, S.F., Budman, S., Goldman, R., Newman, F., Beckley, K., Trottier, D., and Cacciola, J.S. Initial validation of a computer-administered Addiction Severity Index: The ASI-MV. Psychology of Addictive Behavior 15(1):4–12, 2001.
Butler, S.F., Cacciola, J.S., Budman, S.H., Ford, S., Gastfriend, D., Salloum, I.M., and Newman, F.L. Predicting Addiction Severity Index (ASI) ratings for a computer-administered ASI. Psychological Assessment 10(4):399–407, 1998.
Carise, D., Wicks, K., McLellan, A.T., and Olton, P. Addiction Severity Index, 5th Edition: North Dakota State Adaptation for Use with Native Americans. Rockville, MD: Center for Substance Abuse Treatment, 1998.
Carnes, P. Out of the Shadows: Understanding Sexual Addiction. 3d ed. Minneapolis, MN: Hazelden, 2001.
Carroll, J.F.X., and McGinley, J.J. A screening form for identifying mental health problems in alcohol/other drug dependent persons. Alcoholism Treatment Quarterly 19(4):33–47, 2001.
Center for Sex Offender Management. The Collaborative Approach to Sex Offender Management. Silver Spring, MD: Center for Sex Offender Management, 2000a.
Center for Sex Offender Management. Myths and Facts About Sex Offenders. Silver Spring, MD: Center for Sex Offender Management, 2000b.
Center for Sex Offender Management. Community Notification and Education. Silver Spring, MD: Center for Sex Offender Management, 2001a.
Center for Sex Offender Management. Recidivism of Sex Offenders. Silver Spring, MD: Center for Sex Offender Management, 2001b.
Center for Substance Abuse Research. Washington county explores a structure for success. CESAR Reports 2(2):1, 5, 1992.
Center for Substance Abuse Treatment. Combining Substance Abuse Treatment With Intermediate Sanctions for Adults in the Criminal Justice System. Treatment Improvement Protocol (TIP) Series 12. HHS Publication No. (SMA) 94–3004. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1994a.
Center for Substance Abuse Treatment. Criminal Justice Treatment Planning Chart. In: Center for Substance Abuse Treatment, ed. Planning for Alcohol and Other Drug Abuse Treatment for Adults in the Criminal Justice System. Treatment Improvement Protocol (TIP) Series 17. HHS Publication No. (SMA) 95–3039. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1994b. Appendix B.
Center for Substance Abuse Treatment. Intensive Outpatient Treatment for Alcohol and Other Drug Abuse. Treatment Improvement Protocol (TIP) Series 8. HHS Publication No. (SMA) 99–3306. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1994c.
Center for Substance Abuse Treatment. Practical Approaches in the Treatment of Women who Abuse Alcohol and Other Drugs. HHS Publication No. (SMA) 94–3006. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1994d.
Center for Substance Abuse Treatment. Screening and Assessment for Alcohol and Other Drug Abuse Among Adults in the Criminal Justice System. Treatment Improvement Protocol (TIP) Series 7. HHS Publication No. (SMA) 00–3477. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1994e.
Center for Substance Abuse Treatment. Simple Screening Instruments for Outreach for Alcohol and Other Drug Abuse and Infectious Diseases. Treatment Improvement Protocol (TIP) Series 11. HHS Publication No. (SMA) 94–2094. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1994f.
Center for Substance Abuse Treatment. Detoxification From Alcohol and Other Drugs. Treatment Improvement Protocol (TIP) Series 19. HHS Publication No. (SMA) 95–3046. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1995a.
Center for Substance Abuse Treatment. Planning for Alcohol and Other Drug Abuse Treatment for Adults in the Criminal Justice System. Treatment Improvement Protocol (TIP) Series 17. HHS Publication No. (SMA) 95–3039. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1995b.
Center for Substance Abuse Treatment. Treatment Drug Courts: Integrating Substance Abuse Treatment With Legal Case Processing. Treatment Improvement Protocol (TIP) Series 23. HHS Publication No. (SMA) 96–3113. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1996.
Center for Substance Abuse Treatment. A Guide to Substance Abuse Services for Primary Care Clinicians. Treatment Improvement Protocol (TIP) Series 24. HHS Publication No. (SMA) 97–3139. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1997a.
Center for Substance Abuse Treatment. Substance Abuse Treatment and Domestic Violence. Treatment Improvement Protocol (TIP) Series 25. HHS Publication No. (SMA) 97–3163. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1997b.
Center for Substance Abuse Treatment. Supplementary Administration Manual for the Expanded Female Version of the Addiction Severity Index (ASI) Instrument. HHS Publication No. (SMA) 96–8056. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1997c.
Center for Substance Abuse Treatment. Comprehensive Case Management for Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 27. HHS Publication No. (SMA) 98–3222. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1998a.
Center for Substance Abuse Treatment. Continuity of Offender Treatment for Substance Use Disorders From Institution to Community. Treatment Improvement Protocol (TIP) Series 30. HHS Publication No. (SMA) 98–3245. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1998b.
Center for Substance Abuse Treatment. Substance Abuse Among Older Adults. Treatment Improvement Protocol (TIP) Series 26. HHS Publication No. (SMA) 98–3179. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1998c.
Center for Substance Abuse Treatment. Substance Use Disorder Treatment for People With Physical and Cognitive Disabilities. Treatment Improvement Protocol (TIP) Series 29. HHS Publication No. (SMA) 98–3249. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1998d.
Center for Substance Abuse Treatment. Brief Interventions and Brief Therapies for Substance Abuse. Treatment Improvement Protocol (TIP) Series 34. HHS Publication No. (SMA) 99–3353. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1999a.
Center for Substance Abuse Treatment. Enhancing Motivation for Change in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 35. HHS Publication No. (SMA) 99–3354. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1999b.
Center for Substance Abuse Treatment. Screening and Assessing Adolescents for Substance Use Disorders. Treatment Improvement Protocol (TIP) Series 31. HHS Publication No. (SMA) 99–3282. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1999c.
Center for Substance Abuse Treatment. Treatment of Adolescents With Substance Use Disorders. Treatment Improvement Protocol (TIP) Series 32. HHS Publication No. (SMA) 99–3283. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1999d.
Center for Substance Abuse Treatment. Changing the Conversation: Improving Substance Abuse Treatment. The National Treatment Improvement Plan. Panel Reports, Public Hearings, and Participant Acknowledgments. HHS Publication No. (SMA) 00–3479. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2000a.
Center for Substance Abuse Treatment. Changing the Conversation: Improving Substance Abuse Treatment. The National Treatment Improvement Plan. HHS Publication No. (SMA) 00–3480. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2000b.
Center for Substance Abuse Treatment. Integrating Substance Abuse Treatment and Vocational Services. Treatment Improvement Protocol (TIP) Series 38. HHS Publication No. (SMA) 00–3470. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2000c.
Center for Substance Abuse Treatment. Substance Abuse Treatment for Persons With Child Abuse and Neglect Issues. Treatment Improvement Protocol (TIP) Series 36. HHS Publication No. (SMA) 00–3357. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2000d.
Center for Substance Abuse Treatment. Substance Abuse Treatment for Persons With HIV/AIDS. Treatment Improvement Protocol (TIP) Series 37. HHS Publication No. (SMA) 00–3459. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2000e.
Center for Substance Abuse Treatment. A Provider's Introduction to Substance Abuse Treatment for Lesbian, Gay, Bisexual, and Transgender Individuals. HHS Publication No. (SMA) 01–3498. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2001.
Center for Substance Abuse Treatment. The Confidentiality of Alcohol and Drug Abuse Patient Records Regulation and the HIPAA Privacy Rule: Implications for Alcohol and Substance Abuse Programs. HHS Publication No. SMA 04-3947 Rockville, MD: Substance Abuse and Mental Health Services Administration, 2004.
Center for Substance Abuse Treatment. Medication-Assisted Treatment for Opioid Addiction in Opioid Treatment Programs. Treatment Improvement Protocol (TIP) Series 43. HHS Publication No. (SMA) 05–4048. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2005a.
Center for Substance Abuse Treatment. Substance Abuse Treatment: Group Therapy. Treatment Improvement Protocol (TIP) Series 41. HHS Publication No. (SMA) 05–4056. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2005b.
Center for Substance Abuse Treatment. Substance Abuse Treatment for Persons with Co-Occurring Disorders. Treatment Improvement Protocol (TIP) Series 42. HHS Publication No. (SMA) 05–3992. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2005c.
Center for Substance Abuse Treatment. Detoxification and Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development a.
Center for Substance Abuse Treatment. Improving Cultural Competence in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development b.
Center for Substance Abuse Treatment. Substance Abuse: Administrative Issues in Intensive Outpatient Treatment. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development c.
Center for Substance Abuse Treatment. Substance Abuse: Clinical Issues in Intensive Outpatient Treatment. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development d.
Center for Substance Abuse Treatment. Substance Abuse Treatment and Men's Issues. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development e.
Center for Substance Abuse Treatment. Substance Abuse and Trauma. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development f.
Center for Substance Abuse Treatment. Substance Abuse Treatment: Addressing the Specific Needs of Women. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development g.
Centers for Disease Control and Prevention. HIV/AIDS Surveillance Report, 2003 (Volume 15). Atlanta, GA: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, 2004a.
Centers for Disease Control and Prevention. Reported Tuberculosis in the United States, 2003. Atlanta, GA: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, September 2004b.
Chadwick, K. The Sister Project: Providing Options to Women. The Walden House Journal. San Francisco: Walden House, 2001.
Chaiken, M.R. Crime rates and substance abuse among types of offenders. In: Johnson, B.D., and Wish, E.D., eds. Crime Rates Among Drug-Abusing Offenders: Final Report to the National Institute of Justice. New York: Narcotic and Drug Research, 1986.
Chaiklin, H. The elderly disturbed prisoner. Clinical Gerontologist 20(1):47–62, 1998.
Cherpitel, C.J. Brief screening instruments for alcoholism. Alcohol Health and Research World 21(4):348–351, 1997.15706747
City of New York. Preliminary Fiscal 2001 Volume II – Agency and Citywide Indicators. Mayor's Management Report. New York: New York City Government, 2001.
Coalition for Federal Sentencing Reform. Executive Summary. Alexandria, VA: National Center on Institutions and Alternatives, 1998.
Cockram, J., Jackson, R., and Underwood, R. People with an intellectual disability and the criminal justice system: The family perspective. Journal of Intellectual & Developmental Disability 23(1):41–56, 1998.
Cohen, F. The Mentally Disordered Inmate and the Law. Kingston, NJ: Civic Research Institute, 2000.
Cohen, R.L. Survey of State Prison Inmates: Probation and Parole Violators in State Prison, 1991. Washington, DC: Bureau of Justice Statistics, 1995.
Compton, W.M., III, Cottler, L.B., Ben Abdallah, A., Phelps, D.L., Spitznagel, E.L., and Horton, J.C. Substance dependence and other psychiatric disorders among drug dependent subjects: Race and gender correlates. American Journal on Addictions 9(2):113–125, 2000.
Cooke, D.J., and Michie, C. Psychopathy across cultures: North America and Scotland compared. Journal of Abnormal Psychology 108(1):58–68, 1999.10066993
Cooper, C.S. Drug Court Management Information System Developed by the Buffalo and Jacksonville Drug Courts Using Microsoft Access. Washington, DC: American University, 2002.
Cornelius, J.R., Jarrett, P.J., Thase, M.E., Fabrega, H., Jr., Haas, G.L., Jones-Barlock, A., Mezzich, J.E., and Ulrich, R.F. Gender effects on the clinical presentation of alcoholics at a psychiatric hospital. Comprehensive Psychiatry 36(6):435–440, 1995.8565448
Corrections Yearbook. Middletown, CT: Criminal Justice Institute, Inc., 1998.
Covington, S.S. Women in prison: Approaches in the treatment of our most invisible population. Women & Therapy 21(1):141–155, 1998.
Cross, T.L., Bazron, B.J., Dennis, K.W., and Isaacs, M.R. Towards a Culturally Competent System of Care: A Monograph on Effective Services for Minority Children Who are Severely Emotionally Disturbed. Vol. 1. Washington, DC: Georgetown University Child Development Center, 1989.
Cullen, F.T., and Gendreau, P. The effectiveness of correctional rehabilitation: Reconsidering the “nothing works” debate. In: Goodstein, L., and MacKenzie, D.L., eds. The American Prison: Issues in Research and Policy. New York: Plenum Press, 1989. pp. 23–44.
Curtis, C., Hoctor, D., and Pennell, S. Intensive supervision for drug-involved probationers. In: Fields, C.B., ed. Innovative Trends and Specialized Strategies in Community-Based Corrections. New York: Garland, 1994. pp. 87–119.
Dees, S.M., Dansereau, D.F., and Bartholomew, N.G. Treatment Readiness Interventions. Research Summary. Fort Worth, TX: Institute of Behavioral Research, Texas Christian University, 2000.
Deitch, D.A. “Correctional treatment: Current issues and future concerns.” Paper presented at the World Federation of Therapeutic Communities Conference, San Francisco, CA, September 2000.
De Leon, G. Legal pressure in therapeutic communities. In: Leukefeld, C.G., and Tims, F.M., eds. Compulsory Treatment of Drug Abuse: Research and Clinical Practice. NIDA Research Monograph 86. HHS Publication No. ADM. 88–1578. Rockville, MD: National Institute on Drug Abuse, 1988. pp. 160–177.
De Leon, G. Therapeutic communities for addictions: A theoretical framework. International Journal of the Addictions 30(12):1603–1645, 1995.
De Leon, G. Integrative recovery: A stage paradigm. Substance Abuse 17(1):51–63, 1996.
De Leon, G. Community as Method: Therapeutic Communities for Special Populations and Special Settings. Westport, CT: Praeger, 1997.
De Leon, G. Therapeutic communities. In: Galanter, M., and Kleber, H.D., eds. Textbook of Substance Abuse Treatment. 2d ed. Washington, DC: American Psychiatric Press, 1999. pp. 447–462.
De Leon, G. The Therapeutic Community: Theory, Model, and Method. New York: Springer Publishers, 2000.
De Leon, G., and Jainchill, N. Male and female drug abusers: Social and psychological status after treatment in a therapeutic community. American Journal of Drug and Alcohol Abuse 8(4):465–497, 1982.
De Leon, G., and Jainchill, N. Circumstance, motivation, readiness and suitability as correlates of treatment tenure. Journal of Psychoactive Drugs 18(3):203–208, 1986.3772644
De Leon, G., Melnick, G., and Hawke, J. The motivation-readiness factor in drug treatment: Implications for research and policy. In: Levy, J.A., Stephens, R.C., and McBride, D.C., eds. Emergent Issues in the Field of Drug Abuse. Stamford, CT: JAI Press, 2000. pp. 103–129.
De Leon, G., Melnick, G., Kressel, D., and Jainchill, N. Circumstances, motivation, readiness, and suitability (the CMRS Scales): Predicting retention in therapeutic community treatment. American Journal of Drug and Alcohol Abuse 20(4):495–515, 1994.
De Leon, G., Melnick, G., Thomas, G., Kressel, D., and Wexler, H. Motivation for treatment in a prison-based therapeutic community. American Journal of Drug and Alcohol Abuse 26(1):33–46, 2000.
De Leon, G., and Rosenthal, M.S. Treatment in residential communities. In: Karasu, T.B., ed. Treatments of Psychiatric Disorders, Vol. 2. Washington, DC: American Psychiatric Press, 1989. pp. 1379–1396.
De Leon, G., Sacks, S., Staines, G.L., and McKendrick, K. Modified therapeutic community for homeless mentally ill chemical abusers: Treatment outcomes. American Journal of Drug and Alcohol Abuse 26(3):461–480, 2000.
De Leon, G., Wexler, H.K., and Jainchill, N. The therapeutic community: Success and improvement rates 5 years after treatment. International Journal of the Addictions 17(4):703–747, 1982.
De Leon, G., and Ziegenfuss, J.T., eds. Therapeutic Communities for Addictions: Readings in Theory, Research and Practice. Springfield, IL: Charles C. Thomas, 1986.
Depue, R.A., and Klein, D.N. Identification of unipolar and bipolar affective conditions in non-clinical populations by the General Behavior Inventory. In: Dunner, D.L., Gershon, E.S., and Barrett, J.E., eds. Relatives at Risk for Mental Disorders. New York: Raven Press, 1988. pp. 179–202.
Derogatis, L.R. Brief Symptom Inventory. Baltimore, MD: Clinical Psychometric Research, 1975a.
Derogatis, L.R. Symptom Checklist-90-Revised (SCL-90-R). Minneapolis, MN: NCS Assessments, 1975.
Derosia, V.R. Living Inside Prison Walls: Adjustment Behavior. Westport, CT: Praeger Publishers, 1998.
Deschenes, E.P., Anglin, M.D., and Speckart, G. Narcotics addiction: Related criminal careers, social and economic costs. Journal of Drug Issues 21(2):383–411, 1991.
Diaz, F.G. Traumatic brain injury and criminal behaviour. Medicine and Law 14(1–2):131–140, 1995.7666742
DiClemente, C.C., and Hughes, S.O. Stages of change profiles in outpatient alcoholism treatment. Journal of Substance Abuse 2:217–235, 1990.2136111
DiClemente, C.C., and Prochaska, J.D. Toward a comprehensive, theoretical model of change: Stages of change and addictive behavior. In: Miller, W.R., and Heather, N., eds. Treating Addictive Behaviors. 2d ed. New York: Plenum Press, 1998. pp. 3–24.
Ditton, P.M. Mental Health and Treatment of Inmates and Probationers. Washington, DC: Bureau of Justice Statistics, 1999.
Donaldson, S. Prison, jails, and reformatories. In: Dynes, W.R., ed. Encyclopedia of Homosexuality. New York: Garland Publications, 1990.
Dorsey, T.L., and Zawitz, M.W. Drugs and Crime Facts. Washington, DC: Bureau of Justice Statistics, 1999.
Douglas, K.S., and Webster, C.D. Predicting violence in mentally and personality disordered individuals. In: Roesch, R., and Hart, S.D., eds. Psychology and Law: The State of the Discipline. New York: Kluwer Academic/Plenum Publishers, 1999. pp. 175–239.
Drake, R.E., Antosca, L.M., Noordsy, D.L., Bartels, S.J., and Osher, F.C. New Hampshire's specialized services for the dually diagnosed. New Directions for Mental Health Services 50:57–67, 1991.
Drake, R.E., Bartels, S.J., Teague, G.B., Noordsy, D.L., and Clark, R.E. Treatment of substance abuse in severely mentally ill patients. Journal of Nervous and Mental Disease 181(10):606–611, 1993.
Drake, R.E., Essock, S.M., Shaner, A., Carey, K.B., Minkoff, K., Kola, L., Lynde, D., Osher, F.C., Clark, R.E., and Rickards, L. Implementing dual diagnosis services for clients with severe mental illness. Psychiatric Services 52(4):469–476, 2001.11274491
Drake, R.E., McHugo, G.J., Clark, R.E., Teague, G.B., Xie, H., Miles, K., and Ackerson, T.H. Assertive community treatment for patients with co-occurring severe mental illness and substance use disorder: A clinical trial. American Journal of Orthopsychiatry 68(2):201–215, 1998a.
Drake, R.E., Mercer-McFadden, C., Mueser, K.T., McHugo, G.J., and Bond, G.R. Review of integrated mental health and substance abuse treatment for patients with dual disorders. Schizophrenia Bulletin 24(4):589–608, 1998b.9853791
Drake, R.E., and Mueser, K.T. Psychosocial approaches to dual diagnosis. Schizophrenia Bulletin 26(1):105–118, 2000.10755672
Duffee, D.E., and Carlson, B.E. Competing value premises for the provision of drug treatment to probationers. Crime and Delinquency 42(4):574–592, 1996.
Dumond, R.W. Inmate sexual assault: The plague that persists. Prison Journal 80(4):407–414, 2000.
Eamon, K.C., Munchua, M.M., and Reddon, J.R. Effectiveness of an anger management program for women inmates. Journal of Offender Rehabilitation 34(1):45–60, 2001.
Edens, J.F., Peters, R.H., and Hills, H.A. Treating prison inmates with co-occurring disorders: An integrative review of existing programs. Behavioral Sciences and the Law 15(4):439–457, 1997.9433747
Edens, J.F., Poythress, N.G., and Watkins, M.M. Further validation of the Psychopathic Personality Inventory among offenders: Personality and behavioral correlates. Journal of Personality Disorders 15(5):403–415, 2001.11723875
Eisenberg, M., and Fabelo, T. Evaluation of the Texas correctional substance abuse treatment initiative: The impact of policy research. Crime & Delinquency 42(2):296–309, 1996.
el Bassel, N., Gilbert, L., Schilling, R.F., and Ivanoff, A. Correlates of crack abuse among drug-using incarcerated women: Psychological trauma, social support, and coping behavior. American Journal of Drug and Alcohol Abuse 22(1):41–56, 1996.
el Bassel, N., Schilling, R.F., Ivanoff, A., and Chen, D.R. Stages of change profiles among incarcerated drug-using women. Addictive Behaviors 23(3):389–394, 1998.9668936
English, K., Jones, L., Pasini-Hill, D., Patrick, D., and Cooley-Towell, S. The Value of Polygraph Testing in Sex Offender Management: Research Report Submitted to the National Institute of Justice. Denver, CO: ORS, 2000.
Etheridge, R.M., Hubbard, R.L., Anderson, J., Craddock, S.G., and Flynn, P.M. Treatment structure and program services in the Drug Abuse Treatment Outcome Study (DATOS). Psychology of Addictive Behavior 11(4):244–260, 1997.
Falkin, G.P., Strauss, S., and Bohen, T. Matching drug-involved probationers to appropriate drug interventions: A strategy for reducing recidivism. Federal Probation 63(1):3–8, 1999.
Farabee, D., Hser, Y., Anglin, M.D., and Huang, D. Recidivism among early cohort of California's Proposition 36 offenders. Criminology & Public Policy 3(4):563–584, 2004.
Farabee, D., Prendergast, M., and Anglin. The effectiveness of coerced treatment for drug-abusing offenders. Federal Probation 62(1):3–10, 1998.
Farabee, D., Prendergast, M., Cartier, J., Wexler, H., Knight, K., and Anglin, M.D. Barriers to implementing effective correctional drug treatment programs. Prison Journal 79(2):150–162, 1999.
Federal Bureau of Investigation. Crime in the United States 1999. Uniform Crime Reports. Washington, DC: Federal Bureau of Investigation, 2000.
Federal Bureau of Investigation. Crime in the United States 2000. Uniform Crime Reports. Washington, DC: Federal Bureau of Investigation, 2001.
Federal Bureau of Investigation. Crime in the United States: 2003 Uniform Crime Reports. Uniform Crime Reports. Washington, DC: Federal Bureau of Investigation, 2004.
Federal Bureau of Prisons. Federal Bureau of Prisons Clinical Practice Guidelines: Detoxification of Chemically Dependent Inmates, December, 2000. Washington, DC: U.S. Bureau of Prisons, 2000.
Field, G. Psychological deficits and treatment needs of chronic criminality. Federal Probation 50(4):60–66, 1986.
Flynn, P.M., Craddock, S.G., Hubbard, R.L., Anderson, J., and Etheridge, R.M. Methodological overview and research design for the Drug Abuse Treatment Outcome Study (DATOS). Psychology of Addictive Behavior 11(4):230–243, 1997.
Foa, E.B., Riggs, D.S., Dancu, C.V., and Rothbaum, B.O. Reliability and validity of a brief instrument for assessing post-traumatic stress disorder. Journal of Traumatic Stress 6(4):459–473, 1993.
Franey, C., and Ashton, M. The grand design: Lessons for DATOS. Drug & Alcohol Findings (7):4–19, 2002.
Friedman, A.S. Substance use/abuse as a predictor to illegal and violent behavior: A review of the relevant literature. Aggression & Violent Behavior 3(4):339–355, 1998.
Fullilove, M.T., Fullilove, R.E., Smith, M., and Winkler, K. Violence, trauma, and post-traumatic stress disorder among women drug users. Journal of Traumatic Stress 6(4):533–543, 1993.
Galbraith, I.G. Minimal interventions with problem drinkers: A pilot study of the effect of two interview styles on perceived self-efficacy. Health Bulletin 47(6):311–314, 1989.2592199
Galen, L.W., Brower, K.J., Gillespie, B.W., and Zucker, R.A. Sociopathy, gender, and treatment outcome among outpatient substance abusers. Drug and Alcohol Dependence 61(1):23–33, 2000.11064181
Gartner, A., and Riessman, F. Self-Help in the Human Services. San Francisco: Jossey-Bass, 1977.
Gendreau, P. What works in community corrections: Promising approaches in reducing criminal behavior. IARCA Journal on Community Corrections 6:5–12, 1995.
Gendreau, P. The principles of effective intervention with offenders. In: Harland, A.T., ed. Choosing Correctional Options That Work: Defining the Demand and Evaluating the Supply. Thousand Oaks, CA: Sage Publications, 1996. pp. 117–130.
Gendreau, P., and Goggin, C. Correctional treatment: Accomplishments and realities. In: Van Voorhis, P., Braswell, M., and Lester, D., eds. Correctional Counseling and Rehabilitation. 3d ed. Cincinnati, OH: Anderson Publishing Co., 1997.
Gendreau, P., Smith, P., and Goggin, C. Treatment programs in corrections. In: Winterdyk, J., ed. Corrections in Canada: Social Reaction to Crime. Scarborough, ON: Prentice-Hall, 2000.
Genty, P.M. Permanency planning in the context of parental incarceration: Legal issues and recommendations. Child Welfare 77(5):543–559, 1998.9744073
Gerstein, D.R., and Harwood, H.J., eds. Treating Drug Problems: Vol. 1. A Study of the Evolution, Effectiveness, and Financing of Public and Private Drug Treatment Systems. Washington, DC: National Academy Press, 1990.
Gerstein, D.R., Johnson, R.A., Harwood, H., Fountain, D., Suter, N., and Malloy, K. Evaluating Recovery Services: The California Drug and Alcohol Treatment Assessment (CALDATA). Sacramento, CA: Department of Alcohol and Drug Programs, 1994.
Gibson, L., Holt, J., Fondacaro, K., Tang, T., Powell, T., and Turbitt, E. An examination of antecedent traumas and psychiatric comorbidity among male inmates with PTSD. Journal of Traumatic Stress 12(3):473–484, 1999.10467556
Gil-Rivas, V., Fiorentine, R., Anglin, M.D., and Taylor, E. Sexual and physical abuse: Do they compromise drug treatment outcomes? Journal of Substance Abuse Treatment 14(4):351–358, 1997.9368211
Glass, M.H., and Bieber, S.L. The effects of acculturative stress on incarcerated Alaska Native and non-Native men. Cultural Diversity and Mental Health 3(3):175–191, 1997.9277019
Glaze, L.E. Probation and Parole in the United States, 2002. Washington, DC: Bureau of Justice Statistics, 2003.
Glaze, L.E. Probation and Parole in the United States, 2001. Washington, DC: Bureau of Justice Statistics, 2002.
Glaze, L.E., and Palla, S. Probation and Parole in the United States, 2003. NCJ 205336. Washington, DC: Bureau of Justice Statistics, 2004.
Goffman, E. Asylums: Essays on the Social Situations of Mental Patients and Other Inmates. Garden City, NY: Doubleday, 1961.
Gornik, M. Moving from correctional program to correctional strategy: Using proven practices to change criminal behavior. Offender Substance Abuse Report (July/August):60–64, 2001.
Gorski, T.T. Passages Through Recovery: An Action Plan for Preventing Relapse. Center City, MN: Hazelden, 1989.
Gorski, T.T., and Kelley, J.M. Counselor's Manual for Relapse Prevention With Chemically Dependent Criminal Offenders. Technical Assistance Publication Series 19. HHS Publication No. (SMA) 96–3115. Rockville, MD: Center for Substance Abuse Treatment, 1996.
Graham, G. A Framework for Recovery. Bellevue, WA: Gordon Graham and Company, Inc., 1999.
Graham, W.F., and Wexler, H.K. The Amity Therapeutic Community program at Donovan Prison: Program description and approach. In: De Leon, G., ed. Community as Method: Therapeutic Communities for Special Populations and Special Settings. Westport, CT: Praeger Publishers, 1997. pp. 69–86.
Greenfeld, L.A. Alcohol and Crime: An Analysis of National Data on the Prevalence of Alcohol Involvement in Crime. Washington, DC: Bureau of Justice Statistics, 1998.
Greenfeld, L.A., and Snell, T.L. Women Offenders. NCJ 175688. Washington, DC: Bureau of Justice Statistics, 1999.
Griffin v. Coughlin. 88 N.Y.2d 674, 1996.
Griffith, J.D., Hiller, M.L., Knight, K., and Simpson, D.D. A cost-effectiveness analysis of in-prison therapeutic community treatment and risk classification. The Prison Journal 79(3):352–368, 1999.
Grilo, C.M., Becker, D.F., Walker, M.L., Edell, W.S., and McGlashan, T.H. Gender differences in personality disorders in psychiatrically hospitalized young adults. Journal of Nervous and Mental Disease 184(12):754–757, 1996.
Hamilton, M. Rating scale for depression. Journal of Neurology, Neurosurgery, and Psychiatry 23:56–61, 1960.
Hammett, T.M. Public Health/Corrections Collaborations: Prevention and Treatment of HIV/AIDS, STDs, and TB. Washington, DC: U.S. Department of Justice, 1998.
Hammett, T.M., Harmon, P., and Maruschak, L.M. HIV/AIDS, STDs, and TB in Correctional Facilities: 1996–1997 Update. Issues and Practices in Criminal Justice. NCJ 176344. Washington, DC: National Institute of Justice, 1999.
Hanson, R.K., and Harris, A.J.R. A structured approach to evaluating change among sexual offenders. Sexual Abuse: A Journal of Research and Treatment 13(2):105–122, 2001.11294122
Hare, R.D. Psychopaths and their nature: Implications for the mental health and criminal justice systems. In: Millon, T., Simonsen, E., Birket-Smith, M., and Davis, R., eds. Psychopathy: Antisocial, Criminal, and Violent Behavior. New York: Guilford Press, 1998a. pp. 188–212.
Hare, R.D. The Hare PCL-R: Some issues concerning its use and misuse. Legal and Criminological Psychology 3(Part 1):99–119, 1998b.
Hare, R.D. A research scale for the assessment of psychopathy in criminal populations. Personality and Individual Differences 1:111–119, 1980.
Hare, R.D. Psychopathy: Theory, research and implications for society. An introduction. Issues in Criminological & Legal Psychology (24):4–5, 1995.
Hare, R.D. Psychopathy: A clinical construct whose time has come. Criminal Justice & Behavior 23(1):25–54, 1996.
Hare, R.D., Hart, S., and Harpur, T. Psychopathy and the DSM-IV criteria for antisocial personality disorder. Journal of Abnormal Psychology 100(3):391–398, 1991.1918618
Harer, M.D. Recidivism Among Federal Prisoners Released in 1987. Washington, DC: Federal Bureau of Prisons, August 4, 1994.
Harlow, C.W. Profile of Jail Inmates 1996. Bureau of Justice Statistics Special Report. NCJ 164620. Washington, DC: Bureau of Justice Statistics, 1998.
Harlow, C.W. Prior Abuse Reported by Inmates and Probationers. Bureau of Justice Statistics Selected Findings. Washington, DC: Bureau of Justice Statistics, 1999.
Harris, G.T., Rice, M.E., and Insey, V.L. Violent recidivism of mentally disordered offenders: The development of a statistical prediction instrument. Criminal Justice & Behavior 20(4):315–335, 1993.
Harris, M. Treating sexual abuse trauma with dually diagnosed women. Community Mental Health Journal 32(4):371–385, 1996.8840080
Harris, M., and Community Connections Trauma Work Group. Trauma Recovery and Empowerment: A Clinician's Guide for Working With Women in Groups. New York: Simon & Schuster, 1998.
Harrison, P.M., and Beck, A.J. Prisoners in 2002. Bureau of Justice Statistics Bulletin. Washington, DC: Bureau of Justice Statistics, 2003.
Harrison, P.M., and Beck, A.J. Prisoners in 2003. Bureau of Justice Statistics Bulletin. NCJ 205335. Washington, DC: Bureau of Justice Statistics, 2004.
Harrison, P.M., and Karberg, J.C. Prison and Jail Inmates at Midyear 2002. Washington, DC: Bureau of Justice Statistics, 2003.
Harrison, P.M., and Karberg, J.C. Prison and Jail Inmates at Midyear 2003. Bureau of Justice Statistics Bulletin. Washington, DC: Bureau of Justice Statistics, 2004.
Hart, S.D., Cox, D.N., and Hare, R.D. Manual for the Psychopathy Checklist: Screening Version (PCL:SV). Toronto, ON: MultiHealth Systems, 1995.
Hart, S.D., Hare, R.D., and Forth, A.E. Psychopathy as a risk marker for violence: Development and validation of a screening version of the revised Psychopathy Checklist. In: Monahan, J., and Steadman, H.J., eds. Violence and Mental Disorder: Developments in Risk Assessment. Chicago: University of Chicago Press, 1994. pp. 81–98.
Harwood, H.J., Hubbard, R.L., Collins, J.J., and Rachal, J.V. The cost of crime and the benefits of drug abuse treatment: A cost-benefit analysis using TOPS data. In: Leukefeld, C.G., and Tims, F.M., eds. Compulsory Treatment of Drug Abuse: Research and Clinical Practice. NIDA Monograph Series 86. Rockville, MD: National Institute on Drug Abuse, 1988. pp. 209–234.
Hathaway, S.R., and McKinley, J.C. Mnnesota Multiphasic Personality Inventory-2. Minneapolis, MN: National Computer Systems, 1989.
Hathaway, S.R., McKinley, J.C., and Butcher, J.N. MMPI-2, Minnesota Multiphasic Personality Inventory-2: User's Guide. Minneapolis, MN: National Computer Systems, 1989.
Haywood, T.W., Kravitz, H.M., Goldman, L.B., and Freeman, A. Characteristics of women in jail and treatment orientations: A review. Behavior Modification 24(3):307–324, 2000.10881379
Healey, K.M. Case Management in the Criminal Justice System. National Institute of Justice Research in Action. Washington, DC: National Institute of Justice, 1999.
Hemphill, J.R., Hare, R.D., and Wong, S. Psychopathy and recidivism: A review. Legal and Criminological Psychology 3:139–170, 1998.
Henderson, D.J. Drug abuse and incarcerated women: A research review. Journal of Substance Abuse Treatment 15(6):579–587, 1998.9845871
Henry, D.A., and Clark, J. Pretrial Drug Testing: An Overview of Issues and Practices. Bureau of Justice Assistance Bulletin. NCJ 176341. Washington, DC: Bureau of Justice Assistance, 1999.
Herz, D.C. Drugs in the Heartland: Methamphetamine Use in Rural Nebraska. National Institute of Justice Research in Brief. Washington, DC: National Institute of Justice, 2000.
Hiller, M.L., Knight, K., and Simpson, D.D. Prison-based substance abuse treatment, residential aftercare and recidivism. Addiction 94(6):833–842, 1999a.10665073
Hiller, M.L., Knight, K., and Simpson, D.D. Risk factors that predict dropout from correction-based treatment for drug abuse. Prison Journal 79(4):411–431, 1999b.
Hobson, J., Shine, J., and Roberts, R. How do psychopaths behave in a prison therapeutic community? Psychology, Crime & Law 6:139–154, 2000.
Hodgins, D.C., el Guebaly, N., and Addington, J. Treatment of substance abusers: Single or mixed gender programs? Addiction 92(7):805–812, 1997.9293039
Holbrook, M.I. Anger management training in prison inmates. Psychological Reports 81(2):623–626, 1997.9354116
Hollin, C.R. Treatment programs for offenders: Meta-analysis, “what works,” and beyond. International Journal of Law and Psychiatry 22(3–4):361–372, 1999.10457930
Holt, N., and Miller, D. Exploration in Inmate-Family Relationships. California Department of Corrections, 1972.
Hora, P.F., Schma, W.G., and Rosenthal, J.T.A. Therapeutic jurisprudence and the drug treatment court movement: Revolutionizing the criminal justice system's response to drug abuse and crime in America. Notre Dame Law Review 74(2):439–537, 1999.
Hser, Y., Teruya, C., Evans, E.A., Longshore, D., Grella, C., and Farabee, D. Treating drug-abusing offenders: Initial findings from a five county study on the impact of California's Proposition 36 on the treatment system and patient outcomes. Evaluation Review 27(5):479–505, 2003.14531316
Hubbard, R.L., Collins, J.J., Rachal, J.V., and Cavanaugh, E.R. The criminal justice client in drug abuse treatment. In: Compulsory Treatment of Drug Abuse: Research and Clinical Practice. NIDA Research Monograph 86. Rockville, MD: National Institute on Drug Abuse, 1988. pp. 57–80.
Hubbard, R.L., Craddock, S.G., Flynn, P.M., Anderson, J., and Etheridge, R.M. Overview of 1-year follow-up outcomes in the Drug Abuse Treatment Outcome Study (DATOS). Psychology of Addictive Behaviors 11(4):261–278, 1997.
Hubbard, R.L., Marsden, M.E., Cavanaugh, E., Rachal, J.V., and Ginzburg, H.M. Role of drug-abuse treatment in limiting the spread of AIDS. Reviews of Infectious Diseases 10(2):377–384, 1988.3259712
Hubbard, R.L., Marsden, M.E., Rachal, J.V., Harwood, H.J., Cavanaugh, E.R., and Ginzburg, H.M. Drug Abuse Treatment: A National Study of Effectiveness. Chapel Hill, NC: University of North Carolina Press, 1989.
Hubbard, R.L., Rachal, J.V., Craddock, S.G., and Cavanaugh, E.R. Treatment Outcome Prospective Study (TOPS): Client characteristics and behaviors before, during, and after treatment. In: Tims, F.M., and Ludford, P.J., eds. Drug Abuse Treatment Evaluation: Strategies, Progress, and Prospects. NIDA Research Monograph 51. HHS Publication No. (ADM) 86–1329. Rockville, MD: National Institute on Drug Abuse, 1984. pp. 42–68.
Huddleston, C.W. Drug courts and jail-based treatment. Corrections Today 60(6):98–101, 1998.
Hughes, T.A., Wilson, D.J., and Beck, A.J. Trends in State Parole, 1990–2000. Bureau of Justice Statistics Special Report. Washington, DC: Bureau of Justice Statistics, 2001.
Hughey, R., and Klemke, L.W. Evaluation of a jail-based substance abuse treatment program. Federal Probation 60(4):40–44, 1996.
Inciardi, J.A. A Corrections-Based Continuum of Effective Drug Abuse Treatment. National Institute of Justice Research Preview. Washington, DC: National Institute of Justice, 1996.
Inciardi, J.A. Heroin use and street crime. Crime and Delinquency 25:335–346, 1979.
Inciardi, J.A., Martin, S.S., Butzin, C.A., Hooper, R.M., and Harrison, L.D. An effective model of prison-based treatment for drug-involved offenders. Journal of Drug Issues 27(2):261–278, 1997.
Inciardi, J.A., and McBride, D.C. Treatment Alternatives to Street Crime. HHS Publication No. (ADM) 91-1749. Bethesda, MD: U.S. Department of Health and Human Services, National Institute on Drug Abuse, Institute of Medicine. Broadening the Base of Treatment for Alcohol Problems. Washington, DC: National Academy Press, 1990.
Izzo, R.L., and Ross, R.R. Meta-analysis of rehabilitation programs for juvenile delinquents: A Brief Report. Criminal Justice and Behavior 17(1):134–142, 1990.
Jacobson, A., and Herald, C. The relevance of childhood sexual abuse to adult psychiatric inpatient care. Hospital and Community Psychiatry 41(2):154–158, 1990.2303215
Jeffries, J.M., Menghraj, S., and Hairston, C.F. Serving Incarcerated and Ex-Offender Fathers and Their Families: A Review of the Field. New York: Vera Institute of Justice, 2001.
Jemelka, R.P., Rahman, S., and Trupin, E.W. Prison mental health: An overview. In: Steadman, H.J., and Cocozza, J.J., eds. Mental Illness in America's Prisons. Washington, DC: The National Coalition for the Mentally Ill in the Criminal Justice System, 1993.
Jenkins, P. Moral Panic: Changing Concepts of the Child Molester in Modern America. New Haven, CT: Yale University Press, 1998.
Johnson, B.D., Goldstein, P.J., Preble, E., Schmeidler, J., Lipton, D.S., Spunt, B., and Miller, T. Taking Care of Business: The Economics of Crime by Heroin Abusers. Lexington, MA: Lexington Books, 1985.
Jordan, B.K., Schlenger, W.E., Fairbank, J.A., and Caddell, J.M. Prevalence of psychiatric disorders among incarcerated women: II. Convicted felons entering prison. Archives of General Psychiatry 53(6):513–519, 1996.8639034
Kassebaum, P.A. Substance Abuse Treatment for Women Offenders: Guide to Promising Practices. Technical Assistance Publication Series 23. HHS Publication No. (SMA) 99–3303. Rockville, MD: Center for Substance Abuse Treatment, 1999.
Kauffman, E., Dore, M.M., and Nelson-Zlupko, L. The role of women's therapy groups in the treatment of chemical dependence. American Journal of Orthopsychiatry 65(3):355–363, 1995.
Kerr v. Farrey. 95 F.3d 472, (7th Cir. 1996), 2001.
Kings County District Attorney's Office. Drug Treatment Alternative-to-Prison Program. Brooklyn, NY: Kings County District Attorney's Office, 2002.
Knight, K. “The TCU Drug Screen.” Paper presented at the annual meeting of the Academy of Criminal Justice Sciences. Washington, DC, April 2001. Greenbelt, MD: Academy of Criminal Justice Sciences, 2001.
Knight, K., and Hiller, M.L. Community-based substance abuse treatment: A 1-year outcome evaluation of the Dallas County Judicial Treatment Center. Federal Probation 61(2):61–68, 1997.
Knight, K., and Hiller, M.L. The validity of self-reported cocaine use in a criminal justice treatment sample. American Journal of Drug and Alcohol Abuse 24(4):647–661, 1998.
Knight, K., Hiller, M.L., Broome, K.M., and Simpson, D.D. Legal pressure, treatment readiness, and engagement in long-term residential programs. Journal of Offender Rehabilitation 31(1/2):101–115, 2000.
Knight, K., Hiller, M.L., and Simpson, D.D. Evaluating corrections-based treatment for the drug-abusing criminal offender. Journal of Psychoactive Drugs 31(3):299–304, 1999a.10533977
Knight, J.R., Hiller, M.L., Simpson, D., and Broome, K.M. The validity of self-reported cocaine use in a criminal justice treatment sample. American Journal of Drug and Alcohol Abuse 24(4):647–660, 1998.
Knight, K., Simpson, D.D., Chatham, L.R., and Camacho, L.M. Assessment of prison-based drug treatment: Texas' in-prison therapeutic community program. Journal of Offender Rehabilitation 24(3/4):75–100, 1997.
Knight, K., Simpson, D.D., and Hiller, M.L. Screening and referral for substance abuse treatment in the criminal justice system. In: Leukefeld, C.G., Tims, F.M., and Farabee, D., eds. Treatment of Drug Offenders: Policies and Issues. New York: Springer Publishing Company, Inc., 2002. pp. 259–272.
Knight, K., Simpson, D.D., and Hiller, M.L. Three-year reincarceration outcomes for in-prison therapeutic community treatment in Texas. The Prison Journal 79(3):337–351, 1999b.
Knop, J., Jensen, P., and Mortensen, E.L. Comorbidity of alcoholism and psychopathy. In: Millon, T., Simonsen, E., and Davis, R., eds. Psychopathy: Antisocial, Criminal, and Violent Behavior. New York: The Guilford Press, 1998. pp. 321–331.
Kofoed, L. Assessment of comorbid psychiatric illness and substance disorders. New Directions for Mental Health Services 50:43–55, 1991.
Kooyman, M. The psychodynamic of therapeutic communities for treatment of heroin addicts. In: De Leon, G., and Ziegenfuss, J.T., eds. Therapeutic Communities for Addictions: Readings in Theory, Research and Practice. Springfield, IL: Charles C. Thomas, 1986. pp. 29–41.
Kressel, D., De Leon, G., Palij, M., and Rubin, G. Measuring client clinical progress in therapeutic community treatment: The therapeutic community Client Assessment Inventory, Client Assessment Summary, and Staff Assessment Summary. Journal of Substance Abuse Treatment 19(3):267–272, 2000.11027897
Kressel, D., Zompa, D., and De Leon, G. A statewide integrated quality assurance model for correctional-based therapeutic community programs. Offender Substance Abuse Report 2(4):49–64, 2002.
Kruh, I.P., Arnaut, G.Y., Manley, J., Whittemore, K.E., Gage, B., and Gagliardi, G. “The Psychopathic Personality Inventory: A validation study with insanity acquittees.” Paper presented at the Biennial Conference of the American Psychology-Law Society, New Orleans, 2000.
Laakso, M.P., Vaurio, O., Koivisto, E., Savolainen, L., Eronen, M., Aronen, H.J., Hakola, P., Repo, E., Soininen, H., and Tiihonen, J. Psychopathy and the posterior hippocampus. Behavioural Brain Research 118(2):187–193, 2001.11164516
LaMere, S., Smyer, T., and Gragert, M. The aging inmate. Journal of Psychosocial Nursing and Mental Health Services 34(4):25–29, 1996.
Lamon, S.S., Cohen, N.L., and Broner, N. New York City's system of criminal justice mental health services. In: Landsberg, G., Rock, M., Berg, L., and Smiley, A., eds. Serving Mentally Ill Offenders and Their Victims: Challenges and Opportunities for Mental Health Professionals. New York: Springer Publishing, 2002. pp. 144–156.
Landreth, G.L., and Lobaugh, A.F. Filial therapy with incarcerated fathers: Effects on parental acceptance of child, parental stress, and child adjustment. Journal of Counseling & Development 76(2):157–165, 1998.
Lang, M.A., and Belenko, S. Predicting retention in a residential drug treatment alternative to prison program. Journal of Substance Abuse Treatment 19(2):145–160, 2000.10963926
Lavine R. Psychopharmacological treatment of aggression and violence in the substance using population. Journal of Psychoactive Drugs 29(4):321–329, 1997.9460025
Laws, D.R. Relapse Prevention With Sex Offenders. New York: Guilford Press, 1989.
Laws, D.R., Hudson, S.M., and Ward, T., eds. Remaking Relapse Prevention With Sex Offenders: A Sourcebook. Thousand Oaks, CA: Sage Publications, 2000.
Lehman, A.F. Heterogeneity of person and place: Assessing co-occurring addictive and mental disorders. American Journal of Orthopsychiatry 66(1):32–41, 1996.
Leshner, A.I. Introduction to the special issue: The National Institute on Drug Abuse's (NIDA's) Drug Abuse Treatment Outcome Study (DATOS). Psychology of Addictive Behaviors 11(4):211–215, 1997.
Leukefeld, C.G., and Tims, F.M., eds. Compulsory Treatment of Drug Abuse: Research and Clinical Practice. NIDA Research Monograph Series No. 86. Rockville, MD: National Institute on Drug Abuse, 1988.
Leukefeld, C.G., and Tims, F.M. Directions for practice and research. In: Leukefeld, C.G., and Tims, F.M., eds. Drug Abuse Treatment in Prisons and Jails. NIDA Research Monograph Series 118. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 279–293.
Levenson, M.R., Kiehl, K.A., and Kitzpatrick, C.M. Assessing psychopathic attributes in a noninstitutionalized population. Journal of Personality and Social Psychology 68:151–158, 1995.7861311
Lilienfeld, S.O., and Andrews, B.P. Development and preliminary validation of a self-report measure of psychopathic personality traits in noncriminal populations. Journal of Personality Assessment 66(3):488–524, 1996.8667144
Lindquist, C.H., and Lindquist, C.A. Gender differences in distress: Mental health consequences of environmental stress among jail inmates. Behavioral Sciences and the Law 15(4):503–523, 1997.9433751
Linehan, M.M. Cognitive-Behavioral Treatment of Borderline Personality Disorder. New York: Guilford Press, 1993.
Lipton, D.S. Correctional opportunity: Pathways to drug treatment for offenders. Journal of Drug Issues 24(1–2):331–348, 1994.
Lipton, D.S. The Effectiveness of Treatment for Drug Abusers Under Criminal Justice Supervision. NCJ 157642. Washington, DC: National Institute of Justice, 1995.
Lipton, D.S. Principles of Correctional Therapeutic Community Treatment Programming for Drug Abusers. New York: National Development and Research Institute, 1998.
Little, G.L., and Robinson, K.D. Treating drunk drivers with Moral Reconation Therapy: A one-year recidivism report. Psychological Reports 64(3 pt 1):960–962, 1989.2748784
Little, G.L., Robinson, K.D., and Burnette, K.D. Treating drug offenders with Moral Reconation Therapy: A three-year recidivism report. Psychological Reports 69(3 pt 2):1151–1154, 1991.1792284
Little, G.L., Robinson, K.D., and Burnette, K.D. Cognitive behavioral treatment of felony drug offenders: A five-year recidivism report. Psychological Reports 73(3 pt 2):1089–1090, 1993.8115559
Lo, C.C., and Stephens, R.C. Drugs and prisoners: Treatment needs on entering prison. American Journal of Drug and Alcohol Abuse 26(2):229–245, 2000.
Longshore, D., Grills, C., Anglin, M.D., and Annon, K. Treatment motivation among African American drug-using arrestees. Journal of Black Psychology 24(2):126–144, 1998.
Longshore, D., Urada, D., Evans, E., Hser, Y.I., Prendergast, M., Hawken, A., Bunch, T., and Ettner, S. Evaluation of the Substance Abuse and Crime Prevention Act: 2003 Report. Department of Alcohol and Drug Programs, California Health and Human Services Agency, September 2004.
Lurigio, A.J. Drug treatment availability and effectiveness: Studies of the general and criminal justice populations. Criminal Justice & Behavior 27(4):495–528, 2000a.
Lurigio, A.J. Persons with serious mental illness in the criminal justice system: Background, prevalence, and principles of care. Criminal Justice Policy Review 11(4):312–328, 2000b.
Maguire, K., and Pastore, A.L. Sourcebook of Criminal Justice Statistics [Online]. Albany, NY: University at Albany, 2001.
Magura, S., Rosenblum, A., and Herman, J. Evaluation of In-Jail Methadone Maintenance: Preliminary Results. New York: The Lindesmith Center-Drug Policy Foundation, 1992.
Maloney, D., Romig, D., and Armstrong, T. The balanced approach to juvenile probation. Juvenile and Family Court Journal 39(3):1–63, 1988.
Marlowe, D.B., and Kirby, K.C. Effective use of sanctions in drug courts: Lessons from behavioral research. National Drug Court Institute Review 2(1):1–32, 1999.
Marlowe, D.B., Kirby, K.C., Bonieskie, L.M., Glass, D.J., Doods, L.D., Husband, S.D., Platt, J.J., and Festinger, D.S. Assessment of coercive and noncoercive pressures to enter drug abuse treatment. Drug and Alcohol Dependence 42(2):77–84, 1996.8889406
Marshall, W., Fernandez, Y., Hudson, S., and Ward, T., eds. Sourcebook of Treatment Programs for Sexual Offenders. New York: Plenum Press, 1998.
Martin, S.S., Butzin, C.A., and Inciardi, J.A. Assessment of a multistage therapeutic community for drug-involved offenders. Journal of Psychoactive Drugs 27(1):109–116, 1995.7602434
Martin, S.S., Butzin, C.A., Saum, C.A., and Inciardi, J.A. Three-year outcomes of therapeutic community treatment for drug-involved offenders in Delaware: From prison to work release to aftercare. The Prison Journal 79(3):294–320, 1999.
Martinson, R. What works? Questions and answers about prison reform. The Public Interest 35:22–54, 1974.
Maruschak, L.M. DWI Offenders Under Correctional Supervision. NCJ 172212. Washington, DC: Bureau of Justice Statistics, 1999a.
Maruschak, L.M. HIV in Prisons 1997. Bureau of Justice Statistics Bulletin. Washington, DC: Bureau of Justice Statistics, 1999b.
Maruschak, L.M. HIV in Prisons 1998. Bureau of Justice Statistics Bulletin. Washington, DC: Bureau of Justice Statistics, 2000.
Maruschak, L.M. HIV in Prisons, 2000. Bureau of Justice Statistics Bulletin. NCJ 196023. Washington, DC: Bureau of Justice Statistics, 2002.
Maruschak, L.M. HIV in Prisons and Jails, 2002. Bureau of Justice Statistics Bulletin. NCJ 205333. Washington, DC: Bureau of Justice Statistics, 2004.
Maruschak, L.M., and Beck, A.J. Medical Problems of Inmates, 1997. Bureau of Justice Statistics Special Report. Washington, DC: Bureau of Justice Statistics, 2001.
McBride, D., and VanderWaal, C. Day reporting centers as an alternative for drug using offenders. Journal of Drug Issues 27(2):379–397, 1997.
McCollister, K.E., and French, M.T. The Economic Cost of Substance Abuse Treatment in Criminal Justice Settings. Miami, FL: University of Miami, 2001.
McConnaughy, E.A., Prochaska, J., and Velicer, W.F. Stages of change in psychotherapy: Measurement and sample profiles. In: Psychotherapy: Theory, Research, and Practice. Chicago: Psychologists Interested in the Advancement of Psychotherapy, 1983. pp. 368–734.
McGlothlin, W.H., and Anglin, M.D. Shutting off methadone: Costs and benefits. Archives of General Psychiatry 38:885–892, 1981.6789792
McHugo, G.J., Drake, R.E., Burton, H.L., and Ackerson, T.H. A scale for assessing the stage of substance abuse treatment in persons with severe mental illness. Journal of Nervous and Mental Disease 183:762–767, 1995.
McHugo, G.J., Drake, R.E., Teague, G.B., and Xie, H. Fidelity to Assertive Community Treatment and client outcomes in the New Hampshire Dual Disorders Study. Psychiatric Services 50(6):818–824, 1999.10375153
McKean, J. Race, ethnicity, and criminal justice. In: Hendricks, J.E., ed. Multicultural Perspectives in Criminal Justice and Criminology. Springfield, IL: Charles C. Thomas, 1994. pp. 85–134.
McLellan, A.T., Grissom, G.R., Zanis, D., Randall, M., Brill, P., and O'Brien, C.P. Problem-service “matching” in addiction treatment: A prospective study in 4 programs. Archives of General Psychiatry 54(8):730–735, 1997.9283508
McLellan, A.T., Hagan, T.A., Levine, M., Gould, F., Meyers, K., Bencivengo, M., and Durell, J. Supplemental social services improve outcomes in public addiction treatment. Addiction 93(10):1489–1499, 1998.9926553
McLellan, A.T., Kushner, H., Metzger, D., Peters, R., Smith, I., Grissom, G., Pettnati, H., and Argeriou, M. The fifth edition of the Addiction Severity Index. Journal of Substance Abuse Treatment 9(3):199–213, 1992.1334156
McLellan, A.T., Luborsky, L., Cacciola, J., Griffith, J., Evans, F., Barr, H.L., and O'Brien, C.P. New data from the Addiction Severity Index: Reliability and validity in three centers. Journal of Nervous and Mental Disease 173(7):412–423, 1985.
McLellan, A.T., Luborsky, L., Woody, G.E., and O'Brien, C.P. An improved diagnostic evaluation instrument for substance abuse patients: The Addiction Severity Index. Journal of Nervous and Mental Disease 168(1):26–33, 1980.
McLellan, A.T., Luborsky, L., Woody, G.E., O'Brien, C.P., and Druley, K.A. Increased effectiveness of substance abuse treatment: A prospective study of patient-treatment “matching.” Journal of Nervous and Mental Disease 171(10):597–605, 1983.
McPeek, S., and Tse, S. Bureau of Prisons Parenting Programs: Use, Costs, and Benefits. Washington, DC: Federal Office of Research and Evaluation, 1988.
Megargee, E.I., Bohn, M.J.J., Meyer, J.E., Jr., and Sink, F. Classifying Criminal Offenders: A New System Based on the MMPI. Beverly Hills, CA: Sage Publications, 1979.
Melnick, G., and De Leon, G. Clarifying the nature of therapeutic community treatment: The Survey of Essential Elements Questionnaire (SEEQ). Journal of Substance Abuse Treatment 16(4):307–313, 1999.10349603
Melnick, G., De Leon, G., Thomas, G., and Kressel, D. Client-treatment matching protocol for therapeutic communities: First report. Journal of Substance Abuse Treatment 21(3):119–128, 2001.11728785
Melnick, G., and Pearson, F. “Quality improvement/assurance.” Paper presented at 2d Annual NIDA/NDRI Research to Practice Meeting, Bethesda, MD. March 15–17, 2000.
Michaels, D., Zoloth, S., Alcabes, P., Braslow, C., and Safyer, S. Homelessness and indicators of mental illness among inmates in New York City's correctional system. Hospital and Community Psychiatry 43(2):150–155, 1992.1572611
Miller, N.S., and Flaherty, J.A. Effectiveness of coerced addiction treatment (alternative consequences): A review of the clinical research. Journal of Substance Abuse Treatment 18(1):9–16, 2000.10636601
Miller, W.R., and Rollnick, S. Motivational Interviewing: Preparing People to Change Addictive Behavior. New York: Guilford Press, 1991.
Miller, W.R., and Rollnick, S. Motivational Interviewing: Preparing People for Change. 2d ed. New York: Guilford Press, 2002.
Millon, T. Millon Clinical Multiaxial Inventory Manual (Third Edition). 3d ed. Minneapolis, MN: Interpretive Scoring Systems, 1983.
Millon, T., Simonsen, E., Birket-Smith, M., and Davis, R.D., eds. Psychopathy: Antisocial, Criminal, and Violent Behavior. New York: Guilford Press, 1998.
Millon, T., Millon, C., and Davis, R. MCMI-III Millon Clinical Multiaxial Inventory-III. Minneapolis, MN: National Computer Systems, 1994.
Millon, T., Millon, C., and Davis, R. MCMI-III Millon Clinical Multiaxial Inventory-III. NCS Assessments. Bloomington, MN: NCS Pearson, Inc., 2002.
Miron, J.A. Violence and the U.S. Prohibition of Alcohol and Drugs. NBER Working Paper No. W6950. Cambridge, MA: National Bureau of Economic Research, 1999.
Monohan, J., and Steadman, H.J. Violence and Mental Disorder: Developments in Risk Assessment. The John D. and Catherine T. MacArthur Foundation series on mental health and development. Chicago: University of Chicago Press, 1994.
Monroe, G. Drug Abuse Patterns and Trends in Monroe/Ouachita Parish. Baton Rouge, LA: Louisiana Office for Addictive Disorders, 1998.
Monti, P.M., Abrams, D.B., Kadden, R.M., and Cooney, N.L. Treating Alcohol Dependence: A Coping Skills Training Guide. New York: Guilford Press, 1989.
Morey, L.C. Personality Assessment Inventory. Odessa, FL: Psychological Assessment Resources, 1991.
Morey, L.C., and Lanier, V.W. Operating characteristics of six response distortion indicators for the personality assessment inventory. Assessment 5(3):203–214, 1998.9728028
Mueser, K.T., Drake, R.E., and Miles, K.M. The course and treatment of substance use disorder in persons with severe mental illness. In: Onken, L.S., Blaine, J.D., Genser, S., and Horton, A.M., eds. Treatment of Drug-Dependent Individuals With Comorbid Mental Disorders. NIDA Research Monograph 172. NIH Publication No. 97–4172. Rockville, MD: National Institute on Drug Abuse, 1997. pp. 86–109.
Mueser, K.T., Yarnold, P.R., Rosenberg, S.D., Swett, C., Jr., Miles, K.M., and Hill, D. Substance use disorder in hospitalized severely mentally ill psychiatric patients: Prevalence, correlates, and subgroups. Schizophrenia Bulletin 26(1):179–192, 2000.10755680
Mumola, C.J. Substance Abuse and Treatment, State and Federal Prisoners, 1997. Bureau of Justice Statistics Special Report. Washington, DC: Bureau of Justice Statistics, 1999.
Mumola, C.J. Incarcerated Parents and Their Children. Bureau of Justice Statistics Special Report. Washington, DC: Bureau of Justice Statistics, 2000.
Mumola, C.J., and Bonczar, T.P. Substance Abuse and Treatment of Adults on Probation, 1995. Bureau of Justice Statistics Special Report. Washington, DC: Bureau of Justice Statistics, 1998.
Najavits, L.M. Seeking Safety: A Treatment Manual for PTSD and Substance Abuse. New York: Guilford Press, 2002.
National Association of Drug Court Professionals. Defining Drug Courts: The Key Components. Alexandria, VA: National Association of Drug Court Professionals, 1997.
National Center on Addiction and Substance Abuse. Addiction Treatment in Prison Will Reduce Crime, Save Billions of Tax Dollars, Says CASA Report. News Briefs. 1998.
National Center on Addiction and Substance Abuse. Behind Bars: Substance Abuse and America's Prison Population. Funded by: Charles E. Culpeper Foundation, and The Robert Wood Johnson Foundation. New York: National Center on Addiction and Substance Abuse at Columbia University, 1998.
National Center on Addiction and Substance Abuse. Crossing the Bridge: An Evaluation of the Drug Treatment Alternative-to-Prison (DTAP) Program. A CASA White Paper. New York: National Center on Addiction and Substance Abuse, Columbia University, 2003.
National Center on Addiction and Substance Abuse. Dangerous Liaisons: Substance Abuse and Sex. New York: National Center on Addiction and Substance Abuse, 1999.
National Center on Addiction and Substance Abuse. No Place to Hide: Substance Abuse in Mid-Size Cities and Rural America. New York: National Center on Addiction and Substance Abuse, 2000.
National Drug Court Institute. DUI/Drug Courts: Defining a National Strategy. Alexandria, VA: National Drug Court Institute, 1999.
National GAINS Center. Drug Courts as a Partner in Mental Health and Co-Occurring Substance Use Disorder Diversion Programs. Delmar, NY: The National GAINS Center, 1999a.
National GAINS Center. Maintaining Medicaid Benefits for Jail Detainees With Co-Occurring Mental Health and Substance Use Disorders. Delmar, NY: The National GAINS Center, 1999b.
National GAINS Center. Using Management Information Systems to Locate People With Serious Mental Illnesses and Co-Occurring Substance Use Disorders in the Criminal Justice System for Diversion. Summer 1999. Delmar, NY: Policy Research Associates, 1999c.
National GAINS Center. Jail Diversion: Creating Alternatives for Persons With Mental Illnesses. Delmar, NY: The National GAINS Center, 2000.
The National GAINS Center. The Prevalence of Co-Occurring Mental and Substance Use Disorders in the Jails. Fact Sheet. Delmar, NY: The National GAINS Center, 2002.
National Institute of Justice. 2000 Arrestee Drug Abuse Monitoring: Annual Report. Washington, DC: U.S. Department of Justice, 2003.
National Institute of Justice. Case Management With Drug-Involved Arrestees. Washington, DC: U.S. Department of Justice, 1995.
National Institute of Justice. Breaking the Cycle. Washington, DC: National Institute of Justice, 2001.
National Institute on Drug Abuse. Principles of Drug Addiction Treatment. A Research-Based Guide. Bethesda, MD: National Institutes of Health, 1999.
Nerenberg, R., Wong, M., and De Groot, A.A. HCV in Corrections: Frontline or Backwater? HEPP News. Providence, RI: Brown Medical School, 2002.
New York State and Division of Criminal Justice Services. Willard Continuous Treatment: Program Abstract. Albany, NY: New York State, Division of Criminal Justice Services, 2001.
New York State Division of Parole. Willard Drug Treatment Campus. New York: New York State Division of Parole, 2002.
New York State Office of Alcoholism & Substance Abuse Services. Guidelines for Level of Care Determination: LOCADTR 2.0. Albany, NY: OASAS, 2001.
Nielsen, A.L., Scarpitti, F.R., and Inciardi, J.A. Integrating the therapeutic community and work release for drug-involved offenders: The CREST Program. Journal of Substance Abuse Treatment 13(4):349–358, 1996.9076653
North, C.S., Eyrich, K.M., Pollio, D.E., and Spitznagel, E.L. Are rates of psychiatric disorders in the homeless population changing? American Journal of Public Health 94(1):103–108, 2004.14713706
Office of Applied Studies. Substance Abuse Treatment in Adult and Juvenile Correctional Facilities: Findings from the Uniform Facility Data Set 1997 Survey of Correctional Facilities. Drug and Alcohol Services Information System Series: S-9. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2000.
Office of the Federal Register. The United States Government Manual 2004/2005. Washington, DC: National Archives and Records Administration, 2004, p. 274.
Office of Justice Programs. About the Drug Courts Program Office. Drug Courts Program Office. Washington, DC: U.S. Department of Justice, 2001.
Office of Justice Programs. Learn About Reentry. Going Home: Serious and Violent Offender Reentry Initiative. Washington, DC: U. S. Department of Justice, 2001.
Office of National Drug Control Policy. National Drug Control Strategy. Washington, DC: Office of National Drug Control Policy, Executive Office of the President, 1997.
Office of National Drug Control Policy. National Drug Control Strategy. Washington, DC: Office of National Drug Control Policy, Executive Office of the President, 1998.
Office of National Drug Control Policy. National Drug Control Strategy. Washington, DC: Office of National Drug Control Policy, Executive Office of the President, 1999a.
Office of National Drug Control Policy. Therapeutic Communities in Correctional Settings: The Prison Based TC Standards Development Project Final Report of Phase II. Washington, DC: Office of National Drug Control Policy, 1999b.
Office of National Drug Control Policy. National Drug Control Strategy: 2000 Annual Report. Washington, DC: Office of National Drug Control Policy, 2000.
Office of National Drug Control Policy. The Economic Costs of Drug Abuse in the United States, 1992–1998. NCJ-190636. Washington, DC: Executive Office of the President, 2001.
Office of National Drug Control Policy. National Drug Control Strategy. NCJ 192260. Washington, DC: Office of National Drug Control Policy, 2002.
Office of National Drug Control Policy. Drug Data Summary. Drug Policy Information Clearinghouse Fact Sheet. Washington, DC: Office of National Drug Control Policy, 2003.
Ogloff, J.R.P., Wong, S., and Greenwood, A. Treating criminal psychopaths in a therapeutic community program. Behavioral Sciences and the Law 8(2):181–190, 1990.
Ohio Department of Alcohol and Drug Addiction Services. OVPP: Safety, Healing, Justice, Liberation. Columbus, OH: Ohio Department of Alcohol and Drug Addiction Services, 2000.
O'Keefe, M.L. Overview of Substance Abuse Programs within the Colorado Department of Corrections. Denver: Colorado Department of Corrections, 2000.
Orange County Probation Department. Orange County Probation Department Business Plan 2002. Santa Ana, CA: Orange County Probation Department, 2002.
Osher, F.C., and Kofoed, L.L. Treatment of patients with psychiatric and psychoactive substance abuse disorders. Hospital & Community Psychiatry 40(10):1025–1030, 1989.2807202
Otto, R.K. Assessing and managing violence risk in outpatient settings. Journal of Clinical Psychology 56(10):1239–1262, 2000.11051058
Owen, B.A. In the Mix: Struggle and Survival in a Women's Prison. SUNY series in women, crime, and criminology. Albany: State University of New York Press, 1998.
People for Peace. The Violence Interruption Process. Chicago: Center for Violence Interruption, 1996.
Peters, R.H. Relapse prevention approaches in the criminal justice system. In: Gorski, T.T., Kelley, J.M., Havens, L., and Peters, R.H., eds. Relapse Prevention and the Substance Abusing Criminal Offender. Technical Assistance Publication Series 8. HHS Publication No. (SMA) 99–3284. Rockville, MD: Center for Substance Abuse Treatment, 1993. pp. 13–19.
Peters, R.H., and Bartoi, M.G. Screening and Assessment of Co-Occurring Disorders in the Justice System. Delmar, NY: The National GAINS Center, 1997.
Peters, R.H., Greenbaum, P.E., Edens, J.F., Carter, C.R., and Ortiz, M.M. Prevalence of DSM-IV substance abuse and dependence disorders among prison inmates. American Journal of Drug and Alcohol Abuse 24(4):573–587, 1998.
Peters, R.H., Greenbaum, P.E., Steinberg, M.L., and Carter, C.R. Effectiveness of screening instruments in detecting substance use disorders among prisoners. Journal of Substance Abuse Treatment 18(4):349–358, 2000.10812308
Peters, R.H., Haas, A.L., and Murrin, M.R. Predictors of retention and arrest in drug courts. National Drug Court Institute Review 2(1):33–60, 1999.
Peters, R.H., and Hills, H.A. Inmates with co-occurring substance abuse and mental health disorders. In: Steadman, H.J., and Cocozza, J.J., eds. Mental Illness in America's Prisons. Seattle, WA: National Coalition for the Mentally Ill in the Criminal Justice System, 1993. pp. 159–212.
Peters, R.H., and Hills, H.A. Intervention Strategies for Offenders with Co-Occurring Disorders: What Works? Delmar, NY: National GAINS Center, 1997.
Peters, R.H., and Hills, H.A. Community treatment and supervision strategies for offenders with co-occurring disorders: What works? In: Latessa, E., ed. Strategic Solutions: The International Community Corrections Association Examines Substance Abuse. Lanham, MD: American Correctional Association, 1999. pp. 81–135.
Peters, R.H., and Kearns, W.D. Drug abuse history and treatment needs of jail inmates. American Journal of Drug and Alcohol Abuse 18(3):355–366, 1992.
Peters, R.H., Kearns, W.D., Murrin, M.R., and Dolente, A.S. Psychopathology and mental health needs among drug-involved inmates. Journal of Prison and Jail Health 11(1):3–25, 1992.
Peters, R.H., Kearns, W.D., Murrin, M.R., Dolente, A.S., and May, R.L. Examining the effectiveness of in-jail substance abuse treatment. Journal of Offender Rehabilitation 19(3/4):1–39, 1993.
Peters, R.H., and Matthews, C.O. Jail Treatment for Drug Abusers. In: Leukefeld, C.G., Tims, F.M., and Farabee, D.F., eds. Treatment of Drug Offenders: Policies and Issues. New York: Springer Publishing Company, 2002. pp. 186–203.
Peters, R.H., and May, R.I. Drug treatment services in jails. In: Leukefeld, C.G., and Tims, F.M., eds. Drug Abuse Treatment in Prison and Jails. NIDA Research Monograph 118. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 38–50.
Peters, R.H., and Peyton, E. Guideline for Drug Courts on Screening and Assessment. Washington, DC: Office of Justice Programs, Drug Courts Program Office, 1998.
Peters, R.H., and Steinberg, M.L. Substance abuse treatment services in U.S. prisons. In: Shewan, D., and Davies, J., eds. Drug Use and Prisons. Singapore: Harwood Academic Publishers, 2000. pp. 89–116.
Peters, R.H., Strozier, A.L., Murrin, M.R., and Kearns, W.D. Treatment of substance-abusing jail inmates: Examination of gender differences. Journal of Substance Abuse Treatment 14(4):339–349, 1997.9368210
Petersen, M., Stephens, J., Dickey, R., and Lewis, W. Transsexuals within the prison system: An international survey of correctional services policies. Behavioral Sciences & the Law 14(2):219–229, 1996.
Petersilia, J. When prisoners return to the community: Political, economic, and social consequences. Sentencing & Corrections: Issues for the 21st Century (9):1–8, 2000.
Peugh, J., and Belenko, S. Substance-involved women inmates: Challenges to providing effective treatment. Prison Journal 79(1):23–44, 1999.
Peugh, J., and Belenko, S. Examining the substance abuse patterns and treatment needs of incarcerated sex offenders. Sexual Abuse: A Journal of Research and Treatment 13(3):179–195, 2001.11486712
Pima County Sheriff's Department. The Amity/Pima County Jail Project Booklet: Substance Abuse Treatment in a Correctional Setting. Hagerstown, MD: American Jail Association, 1988.
Poythress, N.G., Edens, J.F., and Lilienfeld, S.O. Criterion-related validity of the psychopathic personality inventory in a prison sample. Psychological Assessment 10(4):426–430, 1998.
Prendergast, M.L., Anglin, M.D., and Wellisch, J. Treatment for drug-abusing offenders under community supervision. Federal Probation 59(4):66–75, 1995.
Prochaska, J.O., and DiClemente, C.C. Stages of change in the modification of problem behavior. In: Hersen, M., Eisler, R., and Miller, P.M., eds. Progress in Behavior Modification. Sycamore, IL: Sycamore Publishing Company, 1992. pp. 184–214.
Prochaska, J.O., DiClemente, C.C., and Norcross, J.C. In search of how people change: Applications to addictive behaviors. American Psychologist 47(9):1102–1114, 1992.
Procunier v. Martinez. 416 U.S. 396 (1974), 1974.
RachBeisel, J., Scott, J., and Dixon, L. Co-occurring severe mental illness and substance use disorders: A review of recent research. Psychiatric Services 50(11):1427–1434, 1999.10543851
Ramirez, R.R., and de la Cruz, G.P. The Hispanic Population in the United States: March 2002. Current Population Reports, P20-545. Washington, DC: U.S. Census Bureau, 2002.
Raymond, N.C., Coleman, E., Ohlerking, F., Christenson, G.A., and Miner, M. Psychiatric comorbidity in pedophilic sex offenders. American Journal of Psychiatry 156(5):786–788, 1999.
Regional Drug Initiative. Drug Impact Index. The Case for Treatment Expansion. Portland, OR: Regional Drug Initiative, 2001.
Rehabilitation Research and Training Center on Drugs and Disability. Previous Epidemiological Research. Dayton, OH: Rehabilitation Research and Training Center on Drugs and Disability, Wright State University, 2001.
Reilly, P.M., and Shopshire, M.S. Anger Management for Substance Abuse and Mental Health Clients: A Cognitive Behavioral Therapy Manual. Rockville, MD: Center for Substance Abuse Treatment, 2002.
Reise, S.P., and Oliver, C.J. Development of a California Q-Set indicator of primary psychopathy. Journal of Personality Assessment 62:130–144, 1994.8138879
Reise, S.P., and Wink, P. Psychological implications of the Psychopathy Q-Sort. Journal of Personality Assessment 65:300–312, 1995.16367720
Reiss, D., Grubin, D., and Meux, C. Institutional performance of male “psychopaths” in a high-security hospital. Journal of Forensic Psychiatry 10(2):290–299, 1999.
Reiss, D., Meux, C., and Grubin, D. The effect of psychopathy on outcome in high security patients. Journal of the American Academy of Psychiatry and Law 28(3):309–314, 2000.
Rice, M.E., Harris, G.T., and Cormier, C.A. Evaluation of a maximum security therapeutic community for psychopaths and other mentally disordered offenders. Law and Human Behavior 16(4):399–412, 1992.
Richards, H.J., Casey, J.O., and Lucente, S.W. Psychopathy and treatment response in incarcerated female substance abusers. Criminal Justice and Behavior 30(2):251–276, 2003.
Richie, B.E., and Johnsen, C. Abuse histories among newly incarcerated women in a New York City jail. Journal of the American Women's Association 51(3):111–114, 117, 1996.
Ries, R.K., and Ellingson, T. A pilot assessment at one month of 17 dual diagnosis patients. Hospital and Community Psychiatry 41(11):1230–1233, 1990.2249802
Roberts, A.C., and Nishimoto, R.H. Predicting treatment retention of women dependent on cocaine. American Journal of Drug and Alcohol Abuse 22(3):313–333, 1996.
Robins, L.N., and Regier, D.A., eds. Psychiatric Disorders in America: The Epidemiologic Catchment Area Study. New York: Free Press, 1991.
Robinson, M., and Kelley, T. The identification of neurological correlates of brain dysfunction in offenders by probation officers. In: Fishbein, D.H., ed. The Science, Treatment, and Prevention of Antisocial Behaviors: Application to the Criminal Justice System. Kingston, NJ: Civic Research Institute, 2000. pp. 12–1–12–20.
Sacks, S. Co-occurring mental and substance abuse disorders: Promising approaches and research issues. Substance Use and Misuse 35(12–14):2061–2093, 2000.11138717
Sacks, S., Peters, J., Wexler, H., Roebuck, C., and De Leon, G. “Modified Therapeutic Community for MICA Offenders: Description and Interim Findings.” Unpublished manuscript, 2001.
Sacks, J.Y., and Wexler, H.K. Women's Prison TC: Outcome, Process, & Economic Analysis. New York: National Development and Research Institutes, Inc., 2000.
San Francisco County Sheriff's Office Department. SISTER Project Final Evaluation Report: Sisters in Sober Treatment Empowered in Recovery. San Francisco: The Clearinghouse for Drug Exposed Children, University of California, 1996.
Sandoval, A., Hancock, D., Poythress N., Edens, J., and Lilienfeld S. Construct validity of the Psychopathic Personality Inventory in a correctional sample. Journal of Personality Assessment 74(1):262–281, 2000.10879355
Saunders, B., Wilkinson, C., and Phillips, M. The impact of a brief motivational intervention with opiate users attending a methadone programme. Addiction 90(3):415–424, 1995.7735025
SENTAC: The Sentencing Accountability Commission of Delaware. Sentencing Trends and Correctional Treatment in Delaware. Delaware: Sentencing Accountability Commission of Delaware, April 10, 2002.
Shapiro, C. La Bodega de la Familia: Reaching out to the forgotten victims of substance abuse. NJC 170595. Washington, DC: U.S. Department of Justice, 1998.
Simpson, D. Drug Abuse Treatment Outcome Studies. Fort Worth, TX: Texas Christian University, 2002.
Simpson, D.D. National treatment system evaluation based on the Drug Abuse Reporting Program (DARP) follow-up research. In: Tims, F.M., and Ludford, P.J., eds. Drug Abuse Treatment Evaluation: Strategies, Progress & Prospects. NIDA Research Monograph Series 51. HHS Publication No. (ADM) 84–1329. Washington, DC: U.S. Government Printing Office, 1984. pp. 29–41.
Simpson, D.D., and Joe, G.W. Motivation as a predictor of early dropout from drug abuse treatment. Psychotherapy 30(2):357–368, 1993.
Simpson, D.D., Joe, G.W., Fletcher, B.W., Hubbard, R.L., and Anglin, M.D. A national evaluation of treatment outcomes for cocaine dependence. Archives of General Psychiatry 56(6):507–514, 1999a.10359464
Simpson, D.D., Joe, G.W., and Broome, K.M. A national 5-year follow-up of treatment outcomes for cocaine dependence. Archives of General Psychiatry 59(6):538–544, 2002.12044196
Simpson, D.D., and Knight, K. TCU Data Collection Forms for Correctional Residential Treatment. Fort Worth, TX: Texas Christian University, Institute of Behavioral Research, 1998.
Simpson, D.D., Knight, K., and Hiller, M.L. TCU/DCJTC Forms Manual: Intake and During Treatment Assessments. Fort Worth, TX: Texas Christian University, Institute of Behavioral Research, 1997.
Simpson, D., Wexler, H.K., and Inciardi, J.A. Drug Treatment Outcomes for Correctional Settings. Special Issue. Fort Worth, TX: Institute of Behavioral Research, Texas Christian University, 1999b.
Skinner, H.A., and Horn, J.L. Alcohol Dependence Scale (ADS) User's Guide. Toronto, ON: Addiction Research Foundation, 1984.
Slaght, E. Focusing on the family in the treatment of substance abusing criminal offenders. Journal of Drug Education 29(1):53–62, 1999.10349827
Smart Steps: Treating Baltimore's Drug Problem. Drug Strategies. Washington, DC: Drug Strategies, 2000.
Smith, R. Transgendered … and taken to jail. Journal of Psychosocial Nursing and Mental Health Services 33(9):44–46, 1995.
Smith, R. Walden House Scores with Services for Women! The Walden House Staff News. (March) 2001.
Snell, T.L. Women in Prison. Bureau of Justice Statistics Special Report. Washington, DC: U.S. Department of Justice, 1994.
Spielvogel, A.M., and Floyd, A.K. Assessment of trauma in women psychiatric patients. In: Harris, M.E., and Landis, C.L., eds. Sexual Abuse in the Lives of Women Diagnosed With Serious Mental Illness. Amsterdam: Harwood Academic Publishers, 1997. pp. 39–64.
Steadman, H.J. A SAMHSA research initiative assessing the effectiveness of jail diversion programs for mentally ill persons. Psychiatric Services 50(12):1620–1623, 1999.10577883
Steadman, H.J., Cocozza, J.J., and Veysey, B.M. Comparing outcomes for diverted and nondiverted jail detainees with mental illnesses. Law and Human Behavior 23(6):615–627, 1999.10633579
Steadman, H.J., Morris, S.M., and Dennis, D.L. The diversion of mentally ill persons from jails to community-based services: A profile of programs. American Journal of Public Health 85(12):1630–1635, 1995.7503336
Steadman, H.J., Mulvey, E.P., Monahan, J., Robbins, P.C., Appelbaum, P.S., Grisso, T., Roth, L.H., and Silver, E. Violence by people discharged from acute psychiatric inpatient facilities and by others in the same neighborhoods. Archives of General Psychiatry 55(5):393–401, 1998.9596041
Steadman, H.J., Stainbrook, K.A., Griffin, P., Draine, J., Dupont, R., and Horey, C. A specialized crisis response site as a core element of police-based diversion programs. Psychiatric Services 52(2):219–222, 2001.11157122
Stein, L.I., and Test, M.A. Alternative to mental hospital treatment: I. Conceptual model, treatment program, and clinical evaluation. Archives of General Psychiatry 37(4):392–397, 1980.7362425
Stephan, J.J. State Prison Expenditures, 1996. Bureau of Justice Statistics. Washington, DC: U.S. Department of Justice, 1999.
Stephan, J.J. Census of Jails, 1999. Washington, DC: Bureau of Justice Statistics, 2001.
Stevens, S.J., and Patton, T. Residential treatment for drug addicted women and their children: Effective treatment strategies. In: Stevens, S.J., and Wexler, H.K., eds. Women and Substance Abuse: Gender Transparency. New York: Haworth Press, 1998. pp. 235–249.
Stohr, M.K., Hemmens, C., Baune, D., Dayley, J., Gornik, M., Kjaer, K., and Noon, C. Residential Substance Abuse Treatment for State Prisoners (RSAT) Partnership Process Evaluation, Final Report. NCJ 187352. Rockville, MD: U.S. Department of Justice, 2001.
Strauss, S.M., and Falkin, G.P. The relationship between the quality of drug user treatment and program completion: Understanding the perceptions of women in a prison-based program. Substance Use and Misuse 35(12–14):2127–2159, 2000.11138719
Substance Abuse and Mental Health Services Administration. Critical Elements in Developing Effective Jail-Based Drug Treatment Programming. Rockville, MD: Substance Abuse and Mental Health Service Administration, 1996.
Sue, D.W., and Sue, D. Counseling the Culturally Different: Theory and Practice. 3d ed. New York: John Wiley and Sons, 1999.
Sugarman, H. Structure, variations, and context: A sociological view of the therapeutic community. In: De Leon, G., and Ziegenfuss, J.T., eds. Therapeutic Communities for Addictions: Readings in Theory, Research and Practice. Springfield, IL: Charles C. Thomas, 1986. pp. 65–82.
Swartz, J.A., and Lurigio, A.J. Psychiatric illness and comorbidity among adult male jail detainees in drug treatment. Psychiatric Services 50(12):1628–1630, 1999.10577885
Swartz, J.A., Lurigio, A.J., and Slomka, S.A. Impact of IMPACT: An assessment of the effectiveness of a jail-based treatment program. Crime and Delinquency 42(4):553–573, 1996.
TASC, I. About TASC. Chicago: Treatment Alternatives for Safe Communities, Inc., 2002.
Tauber, J., and Huddleston, C.W. Development and Implementation of Drug Courts Systems. Alexandria, VA: National Drug Court Institute, 1999.
Tauber, J., Weinstein, S.P., and Taube, D. Federal Confidentiality Laws and How They Affect Drug Court Practitioners. Alexandria, VA: National Drug Court Institute, 1999.
Taxman, F.S. Reducing Recidivism Through a Seamless System of Care: Components of Effective Treatment, Supervision, and Transition Services in the Community. Washington, DC: Office of National Drug Control Policy, 1998.
Taxman, F.S. Unraveling “what works” for offenders in substance abuse treatment services. National Drug Court Institute Review 2(2):93–134, 1999.
Taxman, F.S., and Bouffard, J.A. The importance of systems in improving offender outcomes: New frontiers in treatment integrity. Justice Policy Journal 2(2):37–58, 2000.
Taxman, F.S., and Sherman, S. What is the status of my client?: Automation in a seamless case management system for substance abusing offenders. Journal of Offender Monitoring 11(1):25–31, 1998.
Taxman, F., and Spinner, D. “Jail Addiction Services (JAS) Demonstration Project in Montgomery County, Maryland: Jail and community-based substance abuse treatment program model: Final report.” Unpublished report: U.S. Department of Health and Human Services, Center for Substance Abuse Treatment, Maryland Governor's Commission on Drugs and Alcohol Abuse, Montgomery County Government, 1997.
Taylor, B.G., Fitzgerald, N., Hunt, D., Reardon, J.A., and Brownstein, H.H. ADAM Preliminary 2000 Findings on Drug Use & Drug Markets: Adult Male Arrestees. Washington, DC: U.S. Department of Justice, Office of Justice Programs, National Institute of Justice, 2001.
TCU Drug Screen. Fort Worth, TX: Institute of Behavioral Research, Texas Christian University, 1997.
Teplin, L.A., Abram, K.M., and McClelland, G.M. Prevalence of psychiatric disorders among incarcerated women: I. Pretrial jail detainees. Archives of General Psychiatry 53(6):505–512, 1996.8639033
Teplin, L.A., and Swartz, J. Referral Decision Scale. Law and Human Behavior 13(1):1–18, 1989.
Thornton, C.C., Gottheil, E., Weinstein, S.P., and Kerachsky, R.S. Patient-treatment matching in substance abuse: Drug addiction severity. Journal of Substance Abuse Treatment 15(6):505–511, 1998.9845864
Tomasino, V., Swanson, A.J., Nolan, J., and Shuman, H.I. The Key Extended Entry Program (KEEP): A methadone treatment program for opiate-dependent inmates. Mount Sinai Journal of Medicine 68(1):14–20, 2001.11135501
Torrey, E.F., Stieber, J., Ezekiel, J., Wolfe, S.M., Sharfstein, J., Noble, J.H., and Flynn, L.M. Criminalizing the Seriously Mentally Ill: The Abuse of Jails as Mental Hospitals. Arlington, VA: National Alliance for the Mentally Ill, 1992.
Travis, J., Solomon, A.L., and Waul, M. From Prison to Home: The Dimensions and Consequences of Prisoner Reentry. Research for Safer Communities. Washington, DC: The Urban Institute, 2001.
Tucker, T.C. Outcome Evaluation of the Detroit Target Cities Jail Based Substance Abuse Treatment Program. Wayne County Department of Community Justice, 1998.
Tunis, S., Austin, J., Morris, M., Hardyman, P., and Bolyard, M. Evaluation of Drug Treatment in Local Corrections. National Institute of Justice Research Preview. NCJ 159313. Washington, DC: National Institute of Justice, 1997.
U.S. Census Bureau. Profile of General Demographic Characteristics for the United States: 2000. Washington, DC: U.S. Census Bureau, 2001.
U.S. Census Bureau. Table 1: Population by Race and Hispanic or Latino Origin, for All Ages and for 18 Years and Over, for the United States. 2000. Washington, DC: U.S. Census Bureau, 2001.
U.S. Department of Justice. Intervening With Substance-Abusing Offenders: A Framework for Action. Washington, DC: National Institute of Corrections, 1991.
U.S. Department of Justice. Drug Court Monitoring, Evaluation and Management Information Systems. Washington, DC: U.S. Department of Justice, 1998.
U.S. Parole Commission. United States Parole Commission Rules and Procedures Manual, Mar 1, 2001. Chevy Chase, MD: U.S. Parole Commission, March 1, 2001.
University of Arizona College of Agriculture. Society-Ready Graduates: PHASE Program-Project for Homemakers in Arizona Seeking Employment. Impact of the College of Agriculture. Tucson, AZ: University of Arizona, 2000.
Vacc, N.A., DeVaney, S.B., and Wittmer, J. Experiencing and Counseling Multicultural and Diverse Populations. 3d ed. Bristol, PA: Accelerated Development, 1995.
Valdez, A., Yin, Z., and Kaplan, C.D. A comparison of alcohol, drugs, and aggressive crime among Mexican-American, black, and white male arrestees in Texas. American Journal of Drug and Alcohol Abuse 23(2):249–265, 1997.
Van Bilsen, H.P., and Van Emst, A.J. Heroin addiction and motivational milieu therapy. International Journal of Addictions 21(6):707–713, 1986.
Varese, T., Pelowski, S., Riedel, H., and Heiby, E.M. Assessment of cognitive-behavioral skills and depression among female prison inmates. European Journal of Psychological Assessment 14(2):141–145, 1998.
Varghese, S., and Fields, H.F. The Link Between Substance Abuse and Infectious Disease in Correctional Settings. Washington, DC: Association of State and Territorial Health Officials, 1999.
Vigdal, G.L., and Stadler, D.W. Assessment, client treatment matching, and managing the substance abusing offender. In: Early, K.E., ed. Drug Treatment Behind Bars: Prison-Based Strategies For Change. Westport, CT: Praeger Publishers/Greenwood Publishing Group, Inc., 1996. pp. 17–43.
Walters, G.D., White, T.W., and Denney, D. The Lifestyle Criminality Screening Form: Preliminary data. Criminal Justice and Behavior 18(4):406–418, 1991.
Wanberg, K.W., and Milkman, H.B. Criminal Conduct and Substance Abuse Treatment: Strategies for Self-Improvement and Change. Thousand Oaks, CA: Sage Publications, 1998.
Warner v. Orange County Dept. of Probation. 115 F.3d 1068 (2d Cir. 1999), 1999.
Webster, C.D., Douglas, K.S., Eaves, D., and Hart, S.D. HCR-20: Assessing Risk for Violence (Verson 2). Burnaby, BC: Mental Health, Law, and Policy Institute, Simon Fraser University, 1997.
Webster, C.D., Douglas, K.S., Eaves, D., and Hart, S.D. Violence Risk Management Companion Guide. Lutz, FL: Psychological Assessment Resources, 2001.
Weiss, R.D., and Mirin, S.M. Dual diagnosis alcoholic: Evaluation and treatment. Psychiatric Annals 19(5):261–265, 1989.
Weiss, R.D., and Najavits, L.M. Overview of treatment modalities for dual diagnosis patients: Pharmacology, psychotherapy, and 12-Step programs. In: Kranzler, H.R., and Rounsaville, B.J., eds. Dual Diagnosis and Treatment: Substance Abuse and Comorbid Medical and Psychiatric Disorders. New York: Marcel Dekker, 1998. pp. 87–105.
Welle, D., Falkin, G.P., and Jainchill, N. Current approaches to drug treatment for women offenders: Project WORTH, Women's Options for Recovery, Treatment, and Health. Journal of Substance Abuse Treatment 15(2):151–163, 1998.9561955
Wender, P.H., Wolf, L.E., and Wasserstein, J. Adults with ADHD. An overview. Annals of the New York Academy of Science 931:1–16, 2001.
Wexler, H.K. A Criminal Justice System Strategy for Treating Cocaine-Heroin Abusing Offenders in Custody. Washington, DC: National Institute of Justice, 1988.
Wexler, H.K. Progress in prison substance abuse treatment: A five-year report. Journal of Drug Issues 24(1–2):349–360, 1994.
Wexler, H.K. Success of therapeutic communities for substance abusers in American prisons. Journal of Psychoactive Drugs 27(1):57–66, 1995.7602441
Wexler, H.K. Criminal justice aftercare: An integrated approach. The Counselor (July/August):30–34, 2000.
Wexler, H.K. Integrated approach to aftercare and employment for criminal justice clients. Offender Programs Report 5(2):2001a.
Wexler, H.K. New Directions in TC Research and Practice. National Therapeutic Community Conference, Columbus, September 2001b.
Wexler, H.K., De Leon, G., Thomas, G., Kressel, D., and Peters, J. Amity Prison TC evaluation: Reincarceration outcomes. Criminal Justice and Behavior 26(2):147–167, 1999a.
Wexler, H.K., Falkin, G.P., and Lipton, D.S. Outcome evaluation of a prison therapeutic community for substance abuse treatment. Criminal Justice and Behavior 17(1):71–92, 1990.
Wexler, H.K., Falkin, G.P., Lipton, D.S., Rosenblum, A.B., and Goodloe, L.P. A Model Prison Rehabilitation Program: An Evaluation of the Stay'N Out Therapeutic Community. A Final Report to the National Institute on Drug Abuse. New York: Narcotic and Drug Research, Inc., 1988.
Wexler, H.K., and Graham, W.F. “Prison-based therapeutic community for substance abusers: Six-month evaluation findings.” Paper presented at the American Psychological Association, Toronto, ON, 1993.
Wexler, H.K., Magura, S., Beardsley, M.M., and Josepher, H. ARRIVE: An AIDS prevention model for high-risk parolees. International Journal of the Addictions 29(3):363–388, 1994.
Wexler, H.K., Melnick, G., Lowe, L., and Peters, J. Three-year reincarceration outcomes for Amity in-prison therapeutic community and aftercare in California. Prison Journal 79(3):321–336, 1999b.
Wexler, H.K., and Williams, R. The Stay'n Out therapeutic community: Prison treatment for substance abusers. Journal of Psychoactive Drugs 18(3):221–230, 1986.3772647
Wexler, H.K., Williams, R.A., Early, K.E., and Trotman, C.D. Prison treatment for substance abusers: Stay'n Out revisited. In: Early, K.E., ed. Drug Treatment Behind Bars: Prison-Based Strategies for Change. Westport, CT: Praeger Publishers/Greenwood Publishing Group, 1996. pp. 101–108.
Whillhite, S., and O'Connell, J.P. The Delaware Drug Court: A Baseline Evaluation. Delaware: State of Delaware Executive Department, Statistical Analysis Center, 1998.
Wilcock, K., Hammett, T.M., Widom, R., and Epstein, J. Tuberculosis in Correctional Facilities 1994–95. Research in Brief. Washington, DC: National Institute of Justice, 1996.
Willenbring, M.L. Measurement of depression in alcoholics. Journal of Studies on Alcohol 47(5):367–372, 1986.3762159
Wilson, D.J. Drug Use, Testing, and Treatment in Jails. Washington, DC: Bureau of Justice Statistics, 2000.
Winerip, M. After years adrift, treatment in jail: Advocates seek another chance for a schizophrenic inmate. New York Times, June 3, 1999, p. B1.
Wingerson, D., and Ries, R.K. Assertive community treatment for patients with chronic and severe mental illness who abuse drugs. Journal of Psychoactive Drugs 31(1):13–18, 1999.10332634
Winnett, D.L., Mullen, R., Lowe, L.L., and Missakian, E.A. Amity Rightturn: A demonstration drug abuse treatment program for inmates and parolees. In: Leukefeld, C.G., and Tims, F.M., eds. Drug Abuse Treatment in Prison and Jails. NIDA Research Monograph 118. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 84–98.
Wisdom, G. Summary of Outcomes in the National Treatment Improvement Evaluation Study (NTIES). NEDS Fact Sheet 4. Fairfax, VA: National Evaluation Data Services, 1999.
Wood, H.R., and White, D.L. A model for habilitation and prevention for offenders with mental retardation: The Lancaster County (PA) Office of Special Offenders Services. In: Conley, R.W., Luckasson, R., and Bouthilet, G.N., eds. The Criminal Justice System and Mental Retardation: Defendants and Victims. Baltimore: Paul H. Brookes Publishing, 1992. pp. 153–165.
Wright, A., Mora, J., and Hughes, L. The Sober Transitional Housing and Employment Project (STHEP): Strategies for long-term sobriety, employment and housing. Alcoholism Treatment Quarterly 7(1):47–56, 1990.
Yates, B.T. Measuring and Improving Cost, Cost-Effectiveness, and Cost-Benefit for Substance Abuse Treatment Programs: A Manual. Rockville, MD: National Institute on Drug Abuse, 1999.
Ziedonis, D.M., and Fisher, W. Assessment and treatment of comorbid substance abuse in individuals with schizophrenia. Psychiatric Annals 24(9):477–483, 1994.
Zimmerman, R. Correctional Treatment Assessment Consortium Symposium: Proceedings Report. San Diego, CA: University of California at San Diego, 2000.
Zimmerman, R., ed. Custody Reentry Instrument Development Symposium: Proceedings Report. San Diego, CA: University of California, San Diego School of Medicine, 2000.