# TIP Development Participants

Note: The information given indicates participants’ affiliations at the time of their participation in this TIP's original development and may not reflect their current affiliations.

## Consensus Panel

Each TIP consensus panel is a group of primarily nonfederal addiction-focused clinical, research, administrative, and recovery support experts with deep knowledge of the TIP's topic. With SAMHSA's Knowledge Application Program team, members of the consensus panel develop each TIP via a consensus-driven, collaborative process that blends evidence-based, best, and promising practices with the panel members’ expertise and combined wealth of experience.

### Chair

Stanley Sacks, Ph.D.

Director

Center for the Integration of Research and Practice National Development and Research Institutes, Inc. New York, New York

### Co-Chair

Richard K. Ries, M.D.
Director/Professor, Outpatient Mental Health Services, Dual Disorder Programs, Harborview Medical Center, Seattle, Washington

### Workgroup Leaders

Donna Nagy McNelis, Ph.D.
Director, Behavioral Healthcare Education, Associate Professor, Psychiatry, Drexel University, School of Medicine, Philadelphia, Pennsylvania

David Mee-Lee, M.D., FASAM
DML Training and Consulting, Davis, California

James L. Sorenson, Ph.D.
Department of Psychiatry, San Francisco General Hospital, San Francisco, California

Douglas Ziedonis, M.D.
Director, Addiction Services, University Behavioral Healthcare System, Piscataway, New Jersey

Joan E. Zweben, Ph.D.
Executive Director, The 14th Street Clinic and Medical Group, East Bay Community Recovery Project, University of California, Berkeley, California

### Panelists

Betty Blackmon, M.S.W., J.D.
Parker-Blackmon and Associates, Kansas City, Missouri

Steve Cantu, LCDC, CADAC, RAS
Clinical Program Coordinator, South Texas Rural Health Services, Inc., Cotulla, Texas

Catherine S. Chichester, M.S.N., R.N., CS
Executive Director, Co-Occurring Collaborative of Southern Maine Portland, Maine

Colleen Clark, Ph.D.
Research Associate, Department of Community Mental Health, University of South Florida, Tampa, Florida

Christie A. Cline, M.D., M.B.A.
Medical Director, Behavioral Health Sciences Division, New Mexico Department of Health, Santa Fe, New Mexico

Raymond Daw, M.A.
Executive Director, Na'nizhoozhi Center, Inc., Gallup, New Mexico

Sharon C. Ekleberry, LCSW, LSATP, BCD
Division Director, Adult Outpatient Services, Fairfax County Mental Health Services, Fairfax/FaIIs Church Community Services Board, Centreville, Virginia

Byron N. Fujita, Ph.D.
Senior Psychologist, Clackamas County Mental Health Center, Oregon City, Oregon

Lewis E. Gallant, Ph.D.
Executive Director, National Association of State Alcohol and Drug, Abuse Directors, Inc., Washington, DC

Michael Harle, M.H.S.
President/Executive Director, Gaudenzia, Inc., Norristown, Pennsylvania

Michael W. Kirby, Jr., Ph.D.
Chief Executive Officer, Arapahoe House, Inc., Thornton, Colorado

Kenneth Minkoff, M.D.
Medical Director, Choate Health Management, Woburn, Massachusetts

Lisa M. Najavits, Ph.D.
Associate Professor of Psychology, Harvard Medical School/McLean Hospital, Belmont, Massachusetts

Tomas A. Soto, Ph.D.
Director, Behavioral Sciences, The CORE Center, Chicago
Illinois, The Chair and Co-Chair would like to thank Kenneth Minkoff, M.D., for his valuable contributions to Chapter 3 of this TIP.
Special thanks go to Donna Nagy McNelis, Ph.D., for providing content on workforce development; Tim Hamilton, for providing content about COD mutual-support groups; Theresa Moyers, Ph.D., for her critical review of motivational interviewing content; George A. Parks, Ph.D., for his input about relapse prevention; Cynthia M. Bulik, Ph.D., for writing content about eating disorders; Lisa M. Najavits, Ph.D., for her contributions addressing PTSD; Barry S. Brown, Ph.D., for providing consultation to the Chair; and Jo Scraba for her editorial assistance to the Chair.

## KAP Expert Panel and Federal Government Participants

Barry S. Brown, Ph.D.
Adjunct Professor, University of North Carolina at Wilmington, Carolina Beach, North Carolina

Jacqueline Butler, M.S.W., LISW, LPCC, CCDC III, CJS
Professor of Clinical Psychiatry College of Medicine, University of Cincinnati, Cincinnati, Ohio

Deion Cash
Executive Director, Community Treatment and Correction Center, Inc., Canton, Ohio

Debra A. Claymore, M.Ed.Adm.
Owner/Chief Executive Officer WC Consulting, LLC, Loveland, Colorado

Carlo C. DiClemente, Ph.D.
Chair, Department of Psychology, University of Maryland-Baltimore County, Baltimore, Maryland

Catherine E. Dube, Ed.D.
Independent Consultant, Brown University, Providence, Rhode Island

Jerry P. Flanzer, D.S.W., LCSW, CAC
Chief, Services, Division of Clinical and Services Research, National Institute on Drug Abuse, Bethesda, Maryland

Michael Galer, D.B.A.
Chairman of the Graduate School of Business, University of Phoenix—Greater Boston Campus, Braintree, Massachusetts

Renata J. Henry, M.Ed.
Director, Division of Alcoholism, Drug Abuse, and Mental Health, Delaware Department of Health and Social Services, New Castle, Delaware

Joel Hochberg, M.A.
President, Asher & Partners, Los Angeles, California

Jack Hollis, Ph.D.
Associate Director, Center for Health Research Kaiser Permanente, Portland, Oregon

Mary Beth Johnson, M.S.W.
Director, Addiction Technology Transfer Center, University of Missouri—Kansas City, Kansas City, Missouri

Eduardo Lopez, B.S.
Executive Producer, EVS Communications, Washington, DC

Holly A. Massett, Ph.D.
Academy for Educational Development, Washington, DC

Diane Miller
Chief, Scientific Communications Branch, National Institute on Alcohol Abuse and Alcoholism, Bethesda, Maryland

Harry B. Montoya, M.A.
President/Chief Executive Officer, Hands Across Cultures, Española, New Mexico

Richard K. Ries, M.D.
Director/Professor, Outpatient Mental Health Services, Dual Disorder Programs, Seattle, Washington

Gloria M. Rodriguez, D.S.W.
Research Scientist, Division of Addiction Services, New Jersey Department of Health and Senior, Services, Trenton, New Jersey

Everett Rogers, Ph.D.
Center for Communications Programs, Johns Hopkins University, Baltimore, Maryland

Jean R. Slutsky, P.A., M.S.P.H.
Senior Health Policy Analyst, Agency for Healthcare Research & Quality, Rockville, Maryland

Nedra Klein Weinreich, M.S.
President, Weinreich Communications, Canoga Park, California

Clarissa Wittenberg
Director, Office of Communications and Public Liaison, National Institute of Mental Health, Kensington, Maryland

## Consulting Members

Paul Purnell, M.A.
Social Solutions, LLC, Potomac, Maryland

Scott Ratzan, M.D., M.P.A., M.A.
Academy for Educational Development, Washington, DC

Thomas W. Valente, Ph.D.
Director, Master of Public Health Program, Department of Preventive Medicine, School of Medicine, University of Southern California, Alhambra, California

Patricia A. Wright, Ed.D.
Independent Consultant, Baltimore, Maryland

## Field Reviewers

Field reviewers represent each TIP's intended target audiences. They work in addiction, mental health, primary care, and adjacent fields. Their direct frontline experience related to the TIP's topic allows them to provide valuable input on a TIP's relevance, utility, accuracy, and accessibility. Additional advisors to this TIP include members of a resource panel and an editorial advisory board.

Calvin Baker
Addicted Homeless Project, Program Coordinator, Division of Addictions and Mental Health, Prince George's County Health Department, Forestville, Maryland

Richard J. Bilangi, M.S.
Executive Director/President, Connecticut Counseling Centers, Inc., Middlebury, Connecticut

Dennis L. Bouffard, Ph.D.
Program Manager, Connecticut Valley Hospital, Addiction Services Division, Middletown, Connecticut

Kim P. Bowman, M.S.
Executive Director, Chester County Department of Drug and Alcohol Services, West Chester, Pennsylvania

Patricia Hess Bridgman, M.A., CCDC IIIE
Associate Director, Ohio Council of Behavioral Healthcare Providers, Columbus, Ohio

Barry S. Brown, Ph.D.
Adjunct Professor, University of North Carolina at Wilmington, Carolina Beach, North Carolina

Vivian B. Brown, Ph.D.
President/Chief Executive Officer, PROTOTYPES, Culver City, California

Tamara J. Cadet, M.S.W., M.P.H.
Web Content Manager, Free to Grow: Head Start Partnerships to Promote, Substance-Free Communities, Columbia University, Andover, Massachusetts

Sharon M. Cadiz, Ed.D.
Senior Director of Special Projects, Project Return Foundation, Inc., New York, New York

Jerome F. X. Carroll, Ph.D.
Private Practice, Brooklyn, New York

Bruce Carruth, Ph.D., LCSW
Private Practice, Laredo, Texas

Michael Cartwright, Ph.D.
Executive Director, Foundations Associates, Nashville, Tennessee

Catherine S. Chichester, M.S.N., R.N., CS
Executive Director, Co-Occurring Collaborative of Southern Maine, Portland, Maine

CAPT Carol Coley, M.S., USPHS
Senior Program Management Advisor, Division of State and Community Assistance, Systems Improvement Branch, Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services, Administration, Rockville, Maryland

Margaret A. Cramer, Ph.D.
Clinical Psychologist/lnstructor, Melrose, Massachusetts

George De Leon, Ph.D.
Director, Center for Therapeutic Community Research, National Development and Research Institutes, Inc., New York, New York

Janice M. Dyehouse, Ph.D., R.N., M.S.N.
Professor and Department Head, College of Nursing, University of Cincinnati, Cincinnati, Ohio

Benjam in M. Eiland, M.A., CATS, EAP
Director of Substance Abuse Services, Haight Ashbury Free Clinic, San Francisco, California

Dorothy J. Farr
Clinical Director, Bucks County Drug and Alcohol Commission, Inc., Warminster, Pennsylvania

Michael I. Fingerhood, M.D., FACP
Associate Professor, Department of Medicine, Center for Chemical Dependence School of Medicine, Johns Hopkins Bayview Medical Center, Baltimore, Maryland

Jerry P. Flanzer, D.S.W., LCSW, CAC
Chief, Services, Division of Clinical and Services Research, National Institute on Drug Abuse, Bethesda, Maryland

Byron N. Fujita, Ph.D.
Senior Psychologist, Clackamas County Mental Health Center, Oregon City, Oregon

Gerard Gallucci, M.D., M.H.S.
Medical Director, Community Psychiatry Program, Bayview Medical Center, Johns Hopkins University, Baltimore, Maryland

Mary Gillespie, Psy.D., CASAC
Psychologist, Saratoga Springs, New York

Karen Scott Griffin, M.S.
Director of Administration, Gaudenzia, Inc., Norristown, Pennsylvania

Valerie A. Gruber, Ph.D., M.P.H.
Assistant Clinical Professor, University of California, San Francisco San, Francisco, California

Nancy Handmaker, Ph.D.
Professor, Department of Psychology, University of New Mexico, Albuquerque, New Mexico

Edward Hendrickson, LMFT, MAC
Clinical Supervisor, Arlington County MHSASD, Arlington, Virginia

David Hodgins, Ph.D.
Professor, Department of Psychology, University of Calgary, Calgary, Canada

Kimberly A. Johnson
Director, Maine Office of Substance Abuse, Augusta Mental Health Complex, Augusta, Maine

Edith Jungblut
Public Health Advisor, Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services, Administration, Rockville, Maryland

George A. Kanuck
Public Health Analyst, Co-Occurring and Homeless Branch, Division of State and Community Assistance, Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services, Administration, Rockville, Maryland

Michael W. Kirby, Jr., Ph.D.
Chief Executive Officer, Arapahoe House, Inc., Thornton, Colorado

Daniel R. Kivlahan, Ph.D.
Director, VA Center of Excellence in Substance Abuse, Treatment and Education, VA Puget Sound Health Care System, Seattle, Washington

TingFun May Lai, M.S.W., CSW, CASAC
Director, Chinatown Alcoholism Services, New York, New York

Linda Lantrip, D.O., R.N.
Medical Director, Central Oklahoma Community Mental Health Center, Norman, Oklahoma

Robert M. Long, M.S., LCDC, LADC
Director, Substance Abuse and Dual Diagnosis Services, Kennebee Valley Mental Health Center, Augusta, Maine

Russell P. MacPherson, Ph.D., CAP, CAPP, CCP, CDVC, DAC
President, RPM Addiction Prevention Training, Sanford, Florida

Philip R. Magaletta, Ph.D.
Clinical Training Coordinator, Federal Bureau of Prisons, Washington, DC

G. Alan Marlatt, Ph.D.
Professor of Psychology, Director, The Addictive Behaviors Research Center, University of Washington, Seattle, Washington

Julia W. Maxwell, LICSW, CAS
Branch Manager, Department of Mental Health/Community Services, Mental Health and Addiction Services, St. Elizabeth's Campus, Washington, DC

Frank A. McCorry, Ph.D.
Director, Clinical Services Unit, N.Y.S. Office of Alcoholism and Substance Abuse, Services, New York, New York

Gregory J. McHugo, Ph.D.
Research Associate Professor, Dartmouth Medical School, New Hampshire-Dartmouth Psychiatric Research Center, Lebanon, New Hampshire

David Mee-Lee, M.D., FASAM
DML Training and Consulting, Davis, California

Kenneth Minkoff, M.D.
Medical Director, Choate Health Management, Woburn, Massachusetts

Theresa Moyers, Ph.D.
Assistant Research Professor, Department of Psychology, University of New Mexico, Albuquerque, New Mexico

Ethan Nebelkopf, Ph.D., MFCC
Clinic Director, Family and Child Guidance Center, Native American Health Center, Oakland, California

Gwen M. Olitsky, M.S.
Chief Executive Officer, The Self-Help Institute for Training and Therapy, Lansdale, Pennsylvania

Thomas A. Peltz, M.Ed., LMHC, CAS
Private Practice Therapist, Beverly Farms, Massachusetts

Stephanie W. Perry, M.D.
Assistant Commissioner of Health, Bureau of Alcohol and Drug Abuse Services, Tennessee Department of Health, Nashville, Tennessee

Lawrence D. Rickards, Ph.D.
CoOccurring Disorders Program Manager, Homeless Programs Branch, Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services, Administration, Rockville, Maryland

Jeffery L. Rohacek, M.S., CASAC
Psychologist II, McPike Addiction Treatment Center, Utica, New York

Edwin M. Rubin, Psy.D.
Psychologist, Aurora Behavioral Health Services, Aurora Health Care, Milwaukee, Wisconsin

Theresa Rubin-Ortiz, LCSW
Clinical Director, Bonita House, Inc., Oakland, California

Margaret M. Salinger, M.S.N., R.N., CARN
Unit/Program Manager, Coatesville VA Medical Center, Coatesville, Pennsylvania

Steven V. Sawicki
Assistant Program Director, Center for Human Development, Connecticut Outreach-West, Waterbury, Connecticut

Anna M. Scheyett, M.S.W., LCSW, CASWCM
Clinical Assistant Professor, School of Social Work, University of North Carolina, Chapel Hill, North Carolina

Marilyn S. Schmal, M.A., CSAC
Mental Health Therapist II, Arlington County Mental Health, Substance Abuse Services, Arlington, Virginia

Darren C. Skinner, Ph.D., LSW, CAC
Director, Gaudenzia, Inc., Gaudenzia House West Chester, West Chester, Pennsylvania

David E. Smith, M.D.
Founder and President, Haight Ashbury Free Clinics, Inc., San Francisco, California

Antony P. Stephen, Ph.D.
Executive Director, Mental Health and Behavioral Sciences, New Jersey Asian American Association for Human, Services, Inc., Elizabeth, New Jersey

Norm Suchar
Program and Policy Analyst, National Alliance to End Homelessness, Washington, DC

Richard T. Suchinsky, M.D.
Associate Chief for Addictive Disorders and Psychiatric Rehabilitation, Mental Health and Behavioral Science Services, Department of Veterans Affairs, Washington, DC

Kimberly N. Sutton, Ph.D.
Director/Associate Professor of Psychiatry, Cork Institute on Alcohol and Other Drug Abuse, Morehouse School of Medicine, Atlanta, Georgia

Mary Lynn Ulrey, M.S., ARNP
Chief Operating Officer, Operation PAR, Inc., Pinellas Park, Florida

Robert Walker, M.S.W., LCSW
Assistant Professor, Center on Drug and Alcohol Research, University of Kentucky, Lexington, Kentucky

Verner Stuart Westerberg, Ph.D.
President, Addiction Services Research, Albuquerque, New Mexico

Aline G. Wommack, R.N., M.S.
Deputy Director, Division of Substance Abuse and Addiction Medicine, UCSF Deputy Department of Psychiatry, San Francisco, California

Ann S. Yabusaki, Ph.D.
Director, Coalition for a DrugFree Hawaii, Plonolulu, Plawaii

Mariko Yamada, LCSW
Clinical Supervisor, Asian American Drug Abuse Program Inc., Gardena, California

Debby Young
Windsor, California

Joan E. Zweben, Ph.D.
Executive Director, The 14th Street Clinic and Medical Group, East Bay Community Recovery Project, University of California Berkley, California

## Resource Panel

Robert E. Anderson
Director, Research and Program Applications, National Association of State Alcohol and Drug, Abuse Directors, Washington, DC

Nancy Bateman, LCSWC, CAC
Senior Staff Associate, Division of Professional Development and Advocacy, National Association of Social Workers, Washington, DC

James F. Callahan, D.P.A.
Executive Vice President, American Society of Addiction Medicine, Chevy Chase, Maryland

Frank Canizales, M.S.W.
Management Analyst, Alcohol Program, Division of Clinical and Preventive Services, Indian Health Service, Rockville, Maryland

Cathi Coridan, M.A.
Senior Director, Substance Abuse Programs and Policy, National Mental Health Association, Alexandria, Virginia

Jennifer Fiedelholtz
Public Health Analyst, Office of Policy and Program Coordination, Substance Abuse and Mental Health Services, Administration Rockville, Maryland

Ingrid D. Goldstrom, M.Sc.
Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services, Administration, Rockville, Maryland

Lynne M. Haverkos, M.D., M.P.H.
Program Director, Behavioral Pediatrics and Health Promotion, Research Program, National Institute of Child Health and Human, Development, Bethesda, Maryland

Edward Hendrickson, LMFT, MAC
Clinical Supervisor, Arlington County Mental Health and Substance, Abuse Services Division, Arlington, Virginia

Kevin D. Hennessy, Ph.D.
Senior Health Policy Analyst, Office of the Assistant Secretary for Planning and Evaluation, Department of Health and Human Services, Washington, DC

James (Gil) Hill, Ph.D.
Director, Office of Rural Health and Substance Abuse, American Psychological Association, Washington, DC

Hendree E. Jones, Ph.D.
Assistant Professor, Department of Psychiatry and Behavioral Sciences, Johns Hopkins University Center, Baltimore, Maryland

Diane M. Langhorst
Clinical Supervisor Substance Abuse Services, Henrico Area Mental Health and Retardation Services, Richmond, Virginia

Tom Leibfried, M.P.A.
Vice President of Government Relations, National Council for Community Behavioral, Healthcare, Rockville, Maryland

James J. Manlandro, D.O.
Director, Family Addiction Treatment Services, Inc., Dennisville, New Jersey

Julia W. Maxwell, LICSW, CAS
Branch Director, Mental Health Addiction and Services Branch, Commission on Mental Health Services District of Columbia, Washington, DC

William F. Northey, Jr., Ph.D.
Research Specialist, American Association for Marriage and Family Therapy, Alexandria, Virginia

Fred C. Osher, M.D.
Director, Center for Behavioral Health, Justice and Public Policy, University of Maryland, Jessup, Maryland

Terry C. Pellmar, Ph.D.
Director, Board on Neuroscience and Behavioral Health, Institute of Medicine, Washington, DC

Ernst Quimby, Ph.D.
Associate Professor, Department of Sociology and Anthropology, Howard University, Washington, DC

Susan E. Salasin
Director, Mental Health and Criminal Justice Program, Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services, Administration, Rockville, Maryland

Laurel L. Stine, J.D., M.A.
Director of Federal Relations, Bazelon Center for Mental Health Law, Washington, DC

Richard T. Suchinsky, M.D.
Associate Director for Addictive Disorders and Psychiatric Rehabilitation, Mental Health and Behavioral Sciences Services, Department of Veterans Affairs, Washington, DC

Jan Towers, Ph.D., CRNP
Director, Health Policy, American Academy of Nurse Practitioners, Washington, DC

Steve Wing
Senior Advisor for Drug Policy, Office of Policy and Program Coordination, Substance Abuse and Mental Health Services, Administration, Rockville, Maryland

## Cultural Competency and Diversity Network Participants

Raymond Daw, M.A.
Executive Director, Na'nizhoozhi Center, Inc., Gallup, New Mexico, Disabilities Work Group

Michael I. Fingerhood, M.D., FACP
Associate Professor, Department of Medicine, Center for Chemical Dependence School of, Medicine, Johns Hopkins Bayview Medical Center, Baltimore, Maryland, Aging Work Group

Ting-Fun May Lai, M.S.W., CSW, CASAC
Director, Chinatown Alcoholism Center, Hamilton-Madison House, New York, New York, Asian and Pacific Islanders Work Group

Antony P. Stephen, Ph.D.
Executive Director, Mental Health & Behavioral Sciences, New Jersey Asian American Association for Human Services, Inc., Elizabeth, New Jersey, Asian and Pacific Islanders Workgroup

Richard T. Suchinsky, M.D.
Associate Chief for Addictive Disorders and Psychiatric Rehabilitation, Mental Health and Behavioral Sciences Services, Department of Veterans Affairs, Washington, DC, Disabilities Work Group

Ann S. Yabusaki, Ph.D.
Director, Coalition for a DrugFree Hawaii, Honolulu, Hawaii, Asian and Pacific Islanders Work Group