# Appendix C—Provider Forms, Measures, and Tools

## Biopsychosocial Intake Forms

A sample assessment form is included in a PDF that is linked to the Providers Clinical Support System (PCSS) website. Go to https://30qkon2a8eif8wrj03zeh041-wpengine. netdna-ssl.com/wp-content/uploads/2017/09/ntake-Assessment-3.pdf and see pages 23-32 of the PDF.

## Suicide and Safety Screening and Assessment Tools

Columbia-Suicide Severity Rating Scale (http://cssrs.columbia.edu/the-columbia-scale-c-ssrs/cssrs-for-communities-and-healthcare/#filter=. general-use.english): Numerous versions of this screener are available for different populations, including adults, adolescents, and people with cognitive difficulties. Versions are also available for certain settings, including general care settings, military settings, schools, and military settings. Furthermore, this screener can be downloaded in both English and Spanish.

HUMILIATION, AFRAID, RAPE, AND KICK

• H: Humiliation-Within the last year, have you been humiliated or emotionally abused in other ways by your partner or your ex-partner?
• A: Afraid-Within the last year, have you been afraid of your partner or ex-partner?
• R: Rape-Within the last year, have you been raped or forced to have any kind of sexual activity by your partner or ex-partner?
• K: Kick-Within the last year, have you been kicked, hit, slapped, or otherwise physically hurt by your partner or ex-partner?

Source: Schal, Eld ridge, & Feder (2007). Adapted from material distributed under the terms of the Creative Commons Attribution License (https://creativecommons.orq/lícenses/by/2.0/.

## Mental Disorder Screening and Assessment Tools

Addiction Severity Index: This is a semistructured interview that takes approximately an hour to administer. Information on administration and scoring can be found at https://pubs.niaaa.nih.gov/publications/assessingalcohol/lnstrumentPDFs/04_ASI.pdf. The interview is available for free online, including here: (http://adai.Washington.edu/instruments/pdf/addiction_severity_index_baseline followup_4.pdf).

MENTAL HEALTH SCREENING FORM-III

## Substance Use/Misuse Screening and Assessment Tools

National Institute on Drug Abuse (NIDA)-Modified Alcohol, Smoking, and Substance Involvement Screening Test (ASSIST) (www.drugabuse.gov/nmassist/): NIDA developed an abbreviated version of the World Health Organization's (WHO) ASSIST tool called the NIDA-Modified ASSIST that can be completed online.

PCSS - Clinical Tools: https://pcssnow.org/resources/clinical-tools

ALCOHOL USE DISORDERS IDENTIFICATION TEST

THE ALCOHOL USE DISORDERS IDENTIFICATION TEST CONCISE

MICHIGAN ALCOHOLISM SCREENING TEST

SIMPLE SCREENING INSTRUMENT FOR SUBSTANCE ABUSE

### Substance Withdrawal Screening Tools

CLINICAL INSTITUTE NARCOTIC ASSESSMENT SCALE FOR WITHDRAWAL SYMPTOMS

CLINICAL INSTITUTE WITHDRAWAL ASSESSMENT OF ALCOHOL SCALE, REVISED

## Trauma Screening and Assessment Tools

PRIMARY CARE PTSD SCREEN FOR DSM-5

PTSD CHECKLIST FOR DSM-5

## Levels of Care Tool

Level of Care Utilization System for Psychiatric and Addiction Services (LOCUS; https://drive.google.com/file/d/0B89glzXJnn4cV1 dESWI2eFEzc3M/view): The LOCUS Adult Version 20 is a lengthy measure that assesses many areas of symptoms and functioning to determine level of care.

## Functioning and Disability Tools

WHO's Disability Assessment Schedule 2.0 (WHODAS 2.0; www.who.int/classifications/icf/whodasii/en/i: Various versions are available in the following locations:

• WHODAS 2.0 36-item version, self-administered: www.who.int/classifications/icf/WHODAS2.0_36itemsSELF.pdf
• WHODAS 2.0 36-item, interviewer-administered: www.who.int/classifications/icf/WHODAS2.0_36itemslNTERVIEW.pdf
• WHODAS 2.012-item, self-administered: www.who.int/classifications/icf/
  WHODAS2.012itemsSELF.pdf?ua=1
• WHODAS 2.012-item, interviewer-administered: www.who.int/classifications/icf/WHODAS2.0_12itemslNTERVIEW.pdf

## Stage of Change Tools

The Stages of Change Readiness and Treatment Eagerness Scale (https://casaa.unm.edu/inst/socratesv8.pdf): This scale is available in two formats: one for alcohol use and one for drug use.

The University of Rhode Island Change Assessment Scale (https://habitslab.umbc.edu/urica/): Multiple short-and long-form versions of this measure are available, including for alcohol use, drug use, and initiating psychotherapy.

SAMPLE TREATMENT PLAN FOR CASE EXAMPLE GEORGE T. (CHAPTER 3)

Problem | Intervention | Coal
Cocaine use disorder; • Work problem primary reason for referral; • Family and worksupport; • Resists 12-Step; • Mental symptoms trigger use; • Action phase | Outpatient treatment; • EAP monitoring; • Family meetings; • Work support group; • Teach skills to manage symptoms without using; • 12-Step meetings | Abstinence; • Negative urinalysis results; • Daily recovery plans
Rule out AUD; • No clear problem; • May trigger cocaine use; • Precontemplation phase | • Outpatient motivational enhancement; thorough evaluation of role of alcohol In patient's life, including family education | • Move into contemplation phase of readiness to change; • Willing to consider the risk of use or possible abuse
Bipolar disorder; • Long history; • On lithium; • Some mood symptoms; • Maintenance phase | • Medication management; • Help take medication while In recovery programs; • Bipolar Support Alliance meetings; • Advocate/collaborate with prescribing health professional; • Identify mood symptoms as triggers | • Maintain stable mood; • Able to manage fluctuating mood symptoms that do occur without using cocaine or other substances to regulate his bipolar disorder

CONSIDERATIONS IN TREATMENT MATCHING

Variable | Key Data
Acute safety needs; Determines need for immediate acute stabilization to establish safety prior to routine assessment | • Immediate risk of harm to self or others; • Immediate risk of physical harm or abuse from others (Mee-Lee et al., 2013); • Inability to provide for basic self-care; • Medically dangerous intoxication or withdrawal; • Potentially lethal medical condition; • Acute severe mental symptoms (e.g., mania, psychosis) leading to inability to function or communicate effectively
Quadrant assignment; Guides the choice of the most appropriate setting for treatment | • Serious, persistent mental illness (SPMI) vs. non-SPMI; • Severely acute or disabling mental symptoms vs. mild to moderate severity symptoms; • High (e.g., active SUD) vs. low (e.g., hazardous substance use) severity SUD; • Substance dependence in full vs. partial remission (Mee-Lee et al., 2013; American Psychiatric Association, 2013)
Level of care; Determines client's program assignment | • Dimensions of assessment for each disorder using criteria from the LOCUS
Diagnosis; Determines the recommended treatment intervention | • Specific diagnosis of each mental disorder and SUD, including distinction between and SUD and substance-induced symptoms; • Information about past and present successful and unsuccessful treatment efforts for each diagnosis; • Identification of trauma-related disorders and culture-bound syndromes, in addition to other mental disorders and substance-related problems
Disability; Determines case management needs and whether a standard intervention is sufficient—at capable or intermediate level— or whether a more advanced “enhanced” level Intervention Is essential | • Cognitive deficits, functional deficits, and skill deficits that interfere with ability to function independently or follow treatment recommendations and that may require varying types and amounts of case management or support; • Specific functional deficits that may interfere with ability to participate in SUD treatment in a particular program setting and may therefore require a co-occurring-enhanced setting rather than a co-occurring-capable one; • Specific deficits in learning or using basic recovery skills that require modified or simplified learning strategies
Strengths and skills; Determines areas of prior success around which to organize future treatment interventions and areas of skill building to manage either disorder | • Areas of particular capacity or motivation in relation to general life functioning (e.g., capacity to socialize, work, or obtain housing); • Ability to manage treatment participation for any disorder (e.g., familiarity and comfort with 12-Step programs, commitment to medication adherence)
Availability and continuity of recovery support; Determines whether to establish continuing relationships and existing relationship availability to provide contingencies to promote learning | • Presence or absence of continuing treatment relationships, particularly mental disorder treatment relationships, beyond the single episode of care; • Presence or absence of an existing and ongoing supportive family, peer support, or therapeutic community; quality and safety of recovery environment (Mee-Lee et al., 2013)
Cultural context; Determines most culturally appropriate treatment interventions and settings | • Areas of cultural identification and support in relation to each of the following; • Ethnic or linguistic culture identification (e.g., attachment to traditional American-lndian cultural healing practices); • Cultures that have evolved around treatment of mental disorders and SUDs (e.g., identification with 12-Step recovery culture; commitment to mental health empowerment movement); • Gender and gender identity; • Sexual orientation; • Rural vs. urban
Problem domains; Determines problems to be solved specifically, and opportunities for contingencies to promote treatment participation | • Is there impairment, need, or (conversely) strength in any of the following areas; • Financial; • Legal; • Employment; • Housing; • Socia l/family; • Medical, parenting/child protective, abuse/victimization/victimizer
Phase of recovery/stage of change (for each problem); Determines appropriate phase-specific or stage-specific treatment intervention and outcomes | • Requirement for acute stabilization of symptoms, engagement, or motivational enhancement; • Active treatment to achieve prolonged stabilization; • Relapse prevention/maintenance; • Rehabilitation, recovery, and growth; • In the motivational enhancement sequence, precontemplation, contemplation, preparation, action, maintenance, or relapse (Prochaska & DiClemente, 1992); • Engagement, stabilization/persuasion, active treatment, or continuing care/relapse prevention (Mueser & Gingerich, 2013; SAMHSA, 2009a)

## Additional Screening Tools for Common Mental Disorders

Depression. Patient Health Questionnaire (PHQ-9): https://www.hiv.uw.edu/page/mental-health-screening/phq-9

Anxiety. General Anxiety Disorder 7-item (GAD-7) Scale: https://www.hiv.uw.edu/paqe/mental-health-screening/gad-7