# Appendix B—Resources

## Training for Providers and Administrators

### Sources of Training in Substance Use Disorders

Addiction-Counselors.com (www.addiction-coun-selors.com/): A website to help professionals and trainees find state-by-state information about substance use disorder (SUD) counseling requirements.

Addictions Nursing Certification Board and the Center for Nursing Education and Testing, Inc. Offers certification in addiction nursing.

• Certified Addictions Registered Nurse: www.cnetnurse.com/carn-exam
• Certified Addictions Registered Nurse-Advanced Practice: www.theabpm.org/become-certified/subspecialties/addiction-medicine/

Addiction Technology Transfer Center (ATTC) Network (https://attcnetwork.org/centers/global-attc/products-resources-catalog): Find local ATTC. Course offerings vary.

• Curricula, lectures, videos, and printed training materials available through ATTCs: https://attcnetwork.org/centers/global-attc/products-resources-catalog
• Directory of ATTC trainers: https://attcnetwork.org/trainers

Addictions Training Institute (https://addictionstraininginstitute.com/certifications-in-florida/): Florida-based organization offering national certification in addiction counseling. Maintains a listing of drug and alcohol counseling certificates offered by state.

American Academy of Addiction Psychiatry (www.aaap.org/clinicians/): Offers professional education and trainee resources for psychiatrists.

American Board of Preventive Medicine Addiction Medicine Certification fwww.theabpm. org/become-certified/subspecialties/addiction-medicine/): Offers physicians subspecialty certification in addiction medicine.

American Osteopathic Academy of Addiction Medicine (www.aoaam.org/Essentials-and-Advanced): Offers physicians basic and advanced courses for in addiction medicine.

Hazelden Betty Ford Foundation (www.hazeldenbettyford.org/education): Flazelden offers training opportunities at many levels and locations, including graduate degree and certification programs, medical and professional education programs, and addiction psychology training (a clinical practicum, doctoral internships, and postdoctoral psychology residency training).

International Certification & Reciprocity Consortium (IC&RC) (https://internationalcredentialing.org/): IR&RC is the largest credentialing body in addiction prevention, treatment, and recovery. They offer six credential in addiction counseling, prevention, supervision, and peer recovery. The Advanced Alcohol & Drug Counselor certificate provides credentialing for co-occurring disorder (CODs) services: https://internationalcredentialing.org/creds/aadc.

NAADAC, the Association for Addiction Professionals (www.naadac.org/): Oversees the National Certification Commission for Addiction Professionals, through which NAADAC is a leading provider of national credentialing in addiction counseling.

• National Certified Addiction Counselor, Level I: www.naadac.org/ncac-i
• National Certified Addiction Counselor, Level II: www.naadac.org/ncac-ii
• International and State Certification Boards: www.naadac.org/state-international-certification-boards

National Association of Social Workers’ (NASW) Certified Clinical Alcohol, Tobacco & Other Drugs Social Worker (www.socialworkers.org/Careers/Credentials-Certifications/Apply-for-NASW-Social-Work-Credentials/Certified-Clinical-Alcohol-Tobacco-Other-Drugs-Social-Worker): Offers social workers certification in addiction services.

Society of Addiction Psychology (Division 50 of the American Psychological Association (https://addictionpsychology.org/education-training/certification): Offers psychologists credentialing in addiction care.

Rutgers Center of Alcohol & Substance Use Studies (https://alcoholstudies.rutgers.edu/): Offers professional development opportunities for addiction counselors and professionals in related fields, including the criminal justice system. Their programs are accredited by multiple state and national organizations, including the National Board for Certified Counselors, NAADAC, and NASW.

SAMHSA

• Technical Assistance Publication (TAP) 21, Addiction Counseling Competencies: The Knowledge, Skills, and Attitudes of Professional Practice: https://store.samhsa.gov/system/files/sma12-4171.pdf
• TAP 21 - A: Competencies for Substance Abuse Treatment Clinical Supervisors https://store.samhsa.gov/system/files/sma12-4243.pdf

### Sources of Training in Mental Health

American Counseling Association (ACA; www.counseling.org/continuing-education/overview): Home study courses, learning institutes, and onsite training.

American Psychological Association (www, apa.org/education/ce): Home study and other approved courses, including some COD-specific offerings (see Continuing Education programs under the topic “addiction”).

American Psychiatric Association (APA) (https://education.psychiatry.org/): The organization's Learning Center provides online courses and Continuing Education programs, including some in CODs (search the catalog of courses at https://education.psychiatry.org/Users/ProductList.aspx.

SAMHSA: Offers online mental health training in numerous areas:

• Disaster Technical Assistance Training: www.samhsa.gov/dtac/education-trainina
• Mental Health First Aid Training: www.samhsa.gov/homelessness-programs-resources/hpr-resources/mental-health-first-aid-training

### Sources of Training in CODs

Addiction Technology Transfer Center (ATTC) Network (https://attcnetwork.org/centers/global-attc/products-resources-catalog): Find local ATTC. Course offerings vary.

• Curricula, lectures, videos, and printed training materials available through ATTCs: https://attcnetwork.org/centers/global-attc/products-resources-catalog
• Directory of ATTC trainers: https://attcnetwork.ore/trainers

Adler Graduate School (https://alfredadler. edu/programs/certificate/certificate-in-COD): A nonprofit educational institute based in Minnesota that offers online training toward a Certificate in Co-Occurring Substance Use and Mental Health Disorders.

Breining Institute's Certified Co-Occurring Disorders Specialist (www.breining.edu/index.php/professional-certification/certified-co-occurring-disorders-specialist-ccds/): This higher education institution is specifically for addiction professionals and offers numerous courses and certifications, including in CODs.

IC&RC (https://internationalcredentialing.org/): IR&RC is the largest credentialing body in addiction prevention, treatment, and recovery. They offer six credential in addiction counseling, prevention, supervision, and peer recovery. The Advanced Alcohol & Drug Counselor certificate provides credentialing for COD services: https://internationalcredentialing.org/creds/aadc.

NAADAC, the Association for Addiction Professionals (www.naadac.org/): Oversees the National Certification Commission for Addiction Professionals, through which NAADAC is a leading provider of national credentialing in addiction counseling. They offer two credentials in CODs:

• Master Addiction Counselor With Co-Occurring Disorders Component: www.naadac.org/mac
• The Oregon Health Authority: Provides a directory of resources on CODs to assist counselors, administrators, and programs with implementation and training.
• Checklists for counselor competencies: www.oregon.gov/oha/HSD/AMH/Pages/Co-occurring.aspx
• Basic Competencies: www.oregon.gov/oha/HSD/AMH/CoQccurring%20Resources/Basic%20Compentencies%20Checklist.pdf
• Intermediate Competencies: www.oregon.gov/oha/HSD/AMH/CoQccurring%20Resources/lntermediate%20Compentencies%20CheckList.pdf
• Advanced Competencies: www.oregon.gov/oha/HSD/AMH/CoOccurrina%2QResources/Advanced%20Competencies%20Checklist.pdf

## Other Resources for Counselors, Providers, and Programs

### Publications

National Institute on Alcohol Abuse and Alcoholism (NIAAA; www.niaaa.nih.gov/publications): Offers resources, including fact sheets, educator resources, videos, and professional education materials.

National Institute on Drug Abuse (NIDA; www.drugabuse.gov/publications): NIDA publishes a wide variety of treatmentrelated materials.

• Comorbidity: Substance Use Disorders and Other Mental Illness: www.druaabuse.gov/publications/drugfacts/comorbidity-substance-use-disorders-other-mental-illnesses
• Common Comorbidities With Substance Use Disorders: www.drugabuse.gov/publications/research-reports/common-comorbidities-substance-use-disorders/introduction
• Criminal Justice Drug Abuse Treatment Studies Series archive of publications and research: www.icpsr.umich.edu/icpsrweb/NAHDAP/series/244/studies
• Other NIDA justice system-related research initiatives: www.drugabuse.gov/researchers/research-resources/criminal-justice-drug-abuse-treatment-studies-cj-dats

National Institute of Mental Health (NIMH; www.nimh.nih.gov/health/publications/index.shtml): NIMH provides manuals and research reports, including texts on disorders and conditions that commonly co-occur with SUDs, such as depression, anxiety, posttraumatic stress disorder (PTSD), schizophrenia, trauma, and suicide risk.

SAMHSA (https://store.samhsa.gov/professional-research-topics): Offers numerous publications on a range of evidence-based topics in prevention, treatment, workforce development, and more.

• TAP 21 - A, Competencies for Substance Abuse Treatment Clinical Supervisors: https://store.samhsa.gov/system/files/sma_12-4243.pdf
• TIP 27, Comprehensive Case Management for Substance Abuse Treatment: https://store.samhsa.gov/system/files/sma15-4215.pdf
• TIP 34, Brief Interventions and Brief Therapies for Substance Abuse: https://store.samhsa.gov/system/files/smal 2-3952.pdf
• TIP 35, Enhancing Motivation for Change in Substance Use Disorder Treatment: https://store.samhsa.aov/product/TIP-35-Enhandng-Motivation-for-Change-in-Substance-Use-Disorder-Treatment/PEP19-02-01-003
• TIP 38, Integrating Substance Abuse Treatment and Vocational Services: https://store.samhsa.qov/system/files/sma12-4216.pdf
• TIP 44, Substance Abuse Treatment for Adults in the Criminal Justice System: https://store.samhsa.gov/system/files/sma_13-4056.pdf
• TIP 45, Detoxification and Substance Abuse Treatment: https://store.samhsa.gov/system/files/sma15-4131 .pdf
• TIP 46, Substance Abuse: Administrative Issues in Outpatient Treatment: https://store.samhsa.aov/system/files/toc.pdf
• TIP 47, Substance Abuse: Clinical Issues in Intensive Outpatient Treatment: https://store.samhsa.gov/system/files/sma13-4182.pdf
• TIP 48, Managing Depressive Symptoms in Substance Abuse Clients During Early Recovery: https://www.ncbi.nlm.nih.gov/books/NBK64057/
• TIP 50, Addressing Suicidal Thoughts and Behaviors in Substance Abuse Treatment: https://store.samhsa.gov/product/TIP-50-Addressing-Suicidal-Thoughts-and-Behaviors-in-Substance-Abuse-Treatment/SMA15-4381
• TIP 51, Substance Abuse Treatment: Addressing the Specific Needs of Women: https://store.samhsa.gov/system/files/sma15-4426.pdf
• TIP 52, Clinical Supervision and Professional Development of the Substance Abuse Counselor: https://store.samhsa.gov/system/files/smal4-4435.pdf
• TIP 55, Behavioral Health Services for People Who Are Homeless: https://store.samhsa.qov/product/TIP-55-Behavioral-Health-Services-for-People-Who-Are-Homeless/SMA15-4734
• TIP 57, Trauma-Informed Care in Behavioral Health Services: https://store.samhsa.gov/svstem/files/sma_14-4816.pdf
• TIP 59, Improving Cultural Competence: https://store.samhsa.gov/system/files/sma14-4849.pdf
• TIP 63, Medications for Opioid Use Disorder: https://store.samhsa.gov/product/TIP-63-Medications-for-Opioid-Use-Disorder
• SAMHSA's Concept of Trauma and Guidance for a Trauma-Informed Approach: https://store.samhsa.gov/system/files/sma14-4884.pdf
• Screening and Assessment of Co-occurring Disorders in the Justice System: https://store.samhsa.gov/system/files/sma15-4930.pdf

### Treatment Locators

Addiction Recovery Guide's Treatment Locators (www.addictionrecoveryguide.org/treatment/treatment_locators): A listing of treatment locators, including methadone providers.

Department of Veterans Affairs Veterans Affairs Substance Use Disorder Program Locator (www.va.gov/directory/guide/SUD.asp): This website provides an interactive treatment locator for Veterans Affairs SUD treatment programs.

Faces & Voices of Recovery Guide to Mutual Aid Support Resources (http://facesandvoicesofrecovery.org/resources/mutual-aid-resources/): Offers a comprehensive listing of 1 2-Step and non-12-Step recovery support groups throughout the United States and online.

Foundations Recovery Network Finding Treatment for Drug Addiction (www.dualdiagnosis.org/addiction-treatment/): Includes a listing of resources to find treatment for CODs.

National Alliance of Advocates for Buprenorphine Treatment (www.treatmentmatch.org/TM index, php): Offers a free, 24/7, anonymous treatment matching service for patients and providers.

SAMHSA

• SAMHSA's Behavioral Health Treatment Services Locator is a confidential and anonymous source of information for patients and providers about treatment facilities in the United States or U.S. Territories for SUDs and mental disorders (https://findtreatment.gov/).
• Finding Quality Treatment for Substance Use Disorders indicates how and where to locate addiction treatment facilities and providers (https://store.samhsa.gov/system/files/pep18-treatment-loc.pdf).

### General Resources

#### ConfidentiaIity

Health and Human Services’ Mental Health Information Privacy FAQs: (www.hhs.gov/hipaa/for-professionals/faq/mental-health/index.html): A listing of mental health-related privacy and confidentiality questions by topic areas (e.g., disclosures for coordinated care, group therapy, disclosures to law enforcement).

National Conference of State Legislatures’ Mental Health Professionals Duty to Warn (www.ncsl.org/research/health/mental-health-professionals-duty-to-warn.aspx): A searchable database of duty to warn laws for mental health professionals by state.

SAMHSA

• Directory of Single State Agencies for Substance Abuse Services: https://www.samhsa.gov/sites/default/files/single-state-agencies-directory-08232019.pdf
• SAMHSA's Laws and Regulations (https://www.samhsa.gov/about-us/who-we-are/laws-regulations)

#### Supervision

Family Health International 360's Training Curriculum on Drug Addiction Counseling Trainer Manual. Chapter 9: Clinical Supervision and Support (www.fhi360.org/sites/default/files/media/documents/Training%20Curriculum%20 on%20Drug%20Addiction%20Counseling%20-%20Chapter%209.pdf): This training manual offers basic guidance for addiction counseling supervision, including case conferencing and helping supervisees avoid burnout.

SAMHSA

• Supervision Intervention Strategies (http://toolkit.ahpnet.com/Supervision-lntervention-Strategies.aspx): This section of SAMHSA's Recruitment and Retention Toolkit provides indepth information about effective supervision, including communication and motivation strategies, conflict negotiation, and performance appraisal.
• TIP 52, Clinical Supervision and Professional Development of the Substance Abuse Counselor (https://store.samhsa.gov/system/files/sma14-4435.pdf): This TIP provides guidance on teaching, coaching, consulting, and mentoring functions of clinical supervisors in addiction treatment.

#### Workforce Recruitment and Retention

ATTC Network's National Workforce Report 2017: Strategies for Recruitment, Retention, and Development of the Substance Use Disorder Treatment and Recovery Services Workforce (https://attcnetwork.org/centers/network-coordinating-office/product/national-workforce-report-national-qualitative-report): This nationwide survey summarizes findings on recruitment and retention challenges facing the addiction recovery labor force.

Behavioral Health Education Center of Nebraska's Retention Toolkit (www.naadac.org/assets/2416/samhsa-naadac_workforce_bhecn_retention_toolkit2.pdf): This toolkit was developed to help behavioral health employers improve retention. Although developed out of Nebraska, the toolkit offers suggestions and resources that can be used by any behavioral health service organization.

SAMHSA

• Focus on the Addiction and Mental Health Workforce: Increasing Retention For Today and Tomorrow: www.naadac.org/assets/2416/2016-09-12_wf retention_webinarslides.pdf
• Recruitment and Retention Toolkit: http://toolkit.ahpnet.com/Home.aspx
• Dealing With Stress in the Workplace: Frustration, Stress, and Compassion Fatigue/Burnout: http://toolkit.ahpnet.com/Dealing-with-Stress-in-the-Workplace.aspx
• Dual Diagnosis Capability in Addiction Treatment (DDCAT) Toolkit (version 4.0): www.centerforebp.case.edu/client-files/pdf/ddcat-toolkit.pdf

#### Criminal Justice System

NIDA

• Criminal Justice Drug Abuse Treatment Studies Series archive of publications and research: www.icpsr.umich.edu/icpsrweb/NAHDAP/series/244/studies
• Other NIDA justice system-related research initiatives: www.drugabuse.gov/researchers/research-resources/criminal-justice-drug-abuse-treatment-studies-cj-dats

SAMHSA

• GAINS Center for Behavioral Health and Justice Transformation: www.samhsa.gov/gains-center
• TIP 44, Substance Abuse Treatment for Adults in the Criminal Justice System: https://store.samhsa.gov/system/files/sma13-4056.pdf
• Screening and Assessment of Co-occurring Disorders in the Justice System: https://store.samhsa.gov/system/files/sma15-4930.pdf

#### Homelessness

Housing First

• The National Alliance to End Homelessness's toolkit for adopting a Housing First approach: https://endhomelessness.org/wp-content/uploads/2009/08/adopting-a-housing-first-approach.pdf
• United States Interagency Council on Homelessness's Implementing Housing First in Permanent Supportive Housing fact sheet: www.usich.gov/resources/uploads/asset_library/Implementing_Housing_First_in_Permanent_Supportive_Housing.pdf

Pathways to Housing

• Resources: https://pathwaystohousingpa.org/housing-first-university/HFU-resources#
• PA Training Institute's training and technical assistance: https://pathwaystohousingpa.org/Training

SAMHSA's Permanent Supportive Housing Evidence-Based Practices Toolkit (https://store.samhsa.gov/product/Permanent-Supportive-Housing-Evidence-Based-Practices-EBP-KIT/SMA10-45101: This toolkit describes key aspects of supportive housing for people with mental disorders.

#### Military Populations

American Counseling Association (ACA)

• Suicide Among Veterans and the Implications for Counselors: www.counseling.org/docs/default-source/vistas/suicide-among-veterans-and-the-implications-for-counselors. pdf?sfvrsn=3803a659 11
• Comparison of Civilian Trauma and Combat Trauma: https://pdfs.semanticscholar.org/eff2/8af43d3feaac7bac3cc5bb789bd4d5f100ec.pdf
• Counseling Addicted Veterans: What to Know and How to Help: https://pdfs.semanticscholar.org/9742/967aac-815ca02c4f599b36be996d0b10d3d9.pdf

Community Anti-Drug Coalitions of America's Strategies for Addressing Substance Abuse in Veteran Populations (www.cadca.org/sites/default/files/mckesson toolkit_1.pdf): This toolkit was created to help programs implement addiction prevention strategies targeting veterans in their communities.

Department of Veterans Affairs national Center for PTSD (www.ptsd.va.gov/):

• Practice Recommendations for Treatment of Veterans with Comorbid Substance Use Disorder and Posttraumatic Stress Disorder: www.mentalhealth.va.gov/providers/sud/docs/SUP_PTSD Practice Recommendations.pdf
• Veteran Outreach Toolkit: Preventing Veteran Suicide is Everyone's Business: www.va.gov/ve/docs/outreachToolkitPreventingVeteranSuicidel-sEveryonesBusiness.pdf
• National Strategy for Preventing Veteran Suicide 2018-2028: www.mentalhealth.va.gov/suicideprevention/docs/Office-of-Mental-Health-and-Suicide-Prevention-National-Strategy-for-Preventing-Veterans-Suicide.pdf

SAMHSA's Addressing the Substance Use Disorder Service Needs of Returning Veterans and Their Families (www.samhsa.gov/sites/default/files/veterans report.pdf): This report summarizes findings from case studies in nine states that implemented addiction prevention and treatment services for returning veterans and their families.

Women

The Iowa Pregnant and Postpartum Women's Residential Treatment Program (https://idph.iowa.gov/substance-abuse/programs/ppw): Offers provider resources for treating pregnant and postpartum women with addiction, including an intake form, follow-up strategies, a client satisfaction survey, and documentation requirements.

SAMHSA

• TIP 51, Substance Abuse Treatment: Addressing the Specific Needs of Women: https://store.samhsa.gov/system/files/sma15-4426.pdf
• TIP 57, Trauma-Informed Care in Behavioral Health Services: https://store.samhsa.gov/system/files/sma14-4816.pdf

#### Integrated Care

Case Western Reserve's Center for Evidence-Based Practices. Integrated Dual Disorder Treatment Clinical Guide (www.centerforebp.case.edu/client-files/pdf/iddtclinicalguide.pdf): This manual offer guidance on developing an Integrated Dual Disorder Treatment (IDDT) program.

Milbank Memorial Fund's Integrating Primary Care into Behavioral Health Settings: What Works for Individuals with Serious Mental Illness (SMI) (www.milbank.org/wp-content/uploads/2016/04/lntegrating-Primary-Care-Report.pdf): This report offers guidance on key implementation techniques to help programs treating clients with SMI learn how to integrate their services into primary care settings.

SAMHSA's Integrated Treatment for Co-Occurring Disorders Evidence-Based Practices KIT (https://store.samhsa.gov/product/lntegrated-Treatment-for-Co-Occurring-Disorders-Evidence-Based-Practices-EBP-KIT/SMA08-4366): This toolkit reviews the principles of integrated care for CODs and includes video and written materials.

#### Assertive Community Treatment (ACT)

Case Western Reserve's Center for Evidence-Based Practices. Integrated Dual Disorder Treatment Clinical Guide (www.centerforebp.case.edu/client-files/pdf/iddtclinicalguide.pdf): This manual offers guidance on developing an IDDT program.

Georgia Department of Behavioral Health & Developmental Disabilities Program Tool Kit for ACT (https://dbhdd.georgia.gov/sites/dbhdd.georgia.gov/files/related files/document/Georgia%20Toolkit%20for%20ACT%20Teams%20 docxfinal%202015.pdf): This toolkit is designed to support programs launching ACT services and covers such areas as staff requirements, critical services, treatment intensity, and program capacity.

SAMHSA's ACT for Co-Occurring Disorders Evidence-Based Practices KIT (https://store. samhsa.gov/product/Assertive-Community-Treatment-ACT-Evidence-Based-Practices-EBP-KIT/sma08-4344): This toolkit reviews the principles of assertive community outreach for clients with CODs and includes video and written materials.

University of Washington Program for ACT (https://depts.washington.edu/ebpa/projects/pact): Program resources offered here are wide ranging and include addiction and mental disorder assessment scales, sample staff and client schedules, a case study, a transition assessment tool, and other relevant client measures (e.g., stage of change, recovery beliefs, violence risk).

#### Therapeutic Communities

Arkansas Department of Human Services Therapeutic Communities Certification Manual (https://humanservices.arkansas.gov/images/uploads/dpsqa/DBHS_Therapuetic_Communities_Certification_FINAL.pdf): Summarizes the standards and certification requirements for therapeutic communities (TCs) under the Arkansas Department of Human Services, Division of Behavioral Health Services.

Missouri Department of Corrections and Maryville Treatment Center Therapeutic Community Program Handbook (www.law.umich.edu/special/policyclearinghouse/Documents/MO%20-%20Maryville%2QTreatment%20_Center%20Therapeutic%20Community%20_Program%20Handbook.pdf): Describes therapeutic community (TC) structure, roles, procedures, and guidelines.

National Institute of Justice's Program Profile: Modified Therapeutic Community for Offenders With Mental Illness and Chemical Abuse Disorders (www.crimesolutions.gov/ProgramDetails.aspx?ID=90): Offers guidance on adapting the TC model to people with CODs who are involved in the criminal justice system.

NlDA Research Report, Therapeutic Communities (https://d14rmgtrwzf5a.cloudfront.net/sites/default/files/therapueticcomm_rrs_0723.pdf): This research report describes the purpose of TCs, evidence of their effectiveness, fundamental components, and adaptations to special populations, including people experiencing homelessness, women, and people in the criminal justice system.

University of Delaware Center for Drug and Alcohol Studies. Therapeutic Community Treatment Methodology: Treating Chemically Dependent Criminal Offenders in Corrections (www.cdhs.udel.edu/content-sub-site/Documents/CDHS/CTC/Treating%20Chemically%20_Dependent%20Criminal%200ffenders%20in%20Corrections.pdf): This slide deck offers material on the use of TCs in criminal justice settings, including relapse prevention, use and misuse of therapeutic tools, and staff roles and functions.

#### Suicide Prevention

ACA

• Suicide Prevention Tip Sheet: www.counseling. org/docs/default-source/Communications-/suicide-prevention-final.pdf?sfvrsn=2
• Counselor Training in Suicide Assessment, Prevention, and Management: www.counseling.org/docs/default-source/vistas/article_65d15528f16116603abcacff0000bee5e7.pdf?sfvrsn=4f43482c_6
• Developing Clinical Skills in Suicide Assessment, Prevention, and Treatment: www.counseling.org/publications/frontmatter/72861-fm.pdf

APA's Practice Guidelines (2016) Recommendations Regarding Assessment of Suicide As Part of the Initial Psychiatric Assessment (https://stopasuicide.org/assets/docs/APAPracticeGuidelines.pdf): A checklist of items to assess in determining suicide risk and history during an initial psychiatric assessment.

International Association for Suicide Prevention's Guidelines for Suicide Prevention (www.iasp.info/suicide guidelines.php): A summary of prevention and risk-reduction strategies for behavioral health service providers.

National Suicide Prevention Lifeline (https://suicidepreventionlifeline.org/ or 1 - 800-273-8255): Funded by SAMSSA, this national network of local crisis centers offer free and confidential support to people in suicidal crisis or emotional distress 24 hours a day, 7 days a week. Professional initiatives to promote public knowledge of suicide prevention are also provided: https://suicidepreventionlifeline.org/professional-initiatives/

SAMHSA

• Suicide Prevention Resource Center: www.sprc.org/
• Suicide Assessment Five-Step Evaluation and Triage for Mental Health Professionals: https://store.samhsa.gov/system/files/sma09-4432.pdf
• TIP 50, Addressing Suicidal Thoughts and Behaviors in Substance Abuse Treatment: https://store.samhsa.gov/product/TIP-50-Addressing-Suicidal-Thoughts-and-Behaviors-in-Substance-Abuse-Treatment/SMA15-4381
• Video companion to TIP 50, Addressing Suicidal Thoughts and Behaviors in Substance Abuse Treatment: www.youtube.com/watch?v=1 n2QZIheuzc&feature=youtu.be

#### Trauma

SAMHSA's TIP 57, Trauma-Informed Care in Behavioral Health Services (https://store.samhsa. gov/system/files/sma14-4816.pdf): Includes guidance for working with behavioral health clients with trauma and for implementing trauma-informed programming.

Veterans Affairs National Center for PTSD (www.ptsd.va.gov/): The National Center for PTSD is one of the world's largest repositories of PTSD-related education and resources, designed to improve patient care, increase provider knowledge, and help clients and families better understand this condition. Many of the Center's publications, tools, and resources are aimed at military personnel (e.g., deployment measures) but many are useful for and applicable to civilian populations as well.

Veterans Affairs/Department of Defense Clinical Practice Guideline for the Management of Posttraumatic Stress Disorder and Acute Stress Disorder (www.healthquality.va.gov/guidelines/MH/ptsd/VADoDPTSDCPGFinal012418.pdf): Evidence-based guidelines for treating trauma and extreme stress in military populations, including treatment recommendations and algorithms.

#### Medication Management

SAMHSA

• TIP 63, Medications for Opioid Use Disorder (https://store.samhsa.gov/product/TIP-63-Medications-for-Opioid-Use-Disorder): A compendium of the latest evidence in support of Food and Drug Administration (FDA)-approved pharmacotherapy for opioid use disorder (OUD).
• Medication for the Treatment of Alcohol Use Disorder: A Brief Guide (https://store.samhsa. gov/system/files/sma15-4907.pdf): Offers a succinct summary of medications for AUD, including how to discuss them with clients, integrating medication into treatment, and medications for people with CODs.

APA's Practice Guideline for the Pharmacological Treatment of Patients With Alcohol Use Disorder (https://psychiatryonline.Org/doi/pdf/10.1176/appi.books.9781615371969): Clinical practice guideline to inform the use of mediation for AUD.

National Library of Medicine's Drug Information Portal (https://druginfo.nlm.nih.gov/drugportal/): A searchable database organized by medication name and category.

FDA's Medication Guides Database (www.accessdata.fda.gov/scripts/cder/daf/index. cfm?event=medguide.page): A searchable index of FDA-approved medications.

NIMH's Mental Health Medications (www.nimh. nih.gov/health/topics/mental-health-medications/index.shtml): A brief summary of psychotropic medication, their uses, and their side effects.

University of Washington's Commonly Prescribed Psychotropic Medications (https://aims. uw.edu/resource-library/commonly-prescribed-psychotropic-medications): A printable factsheet of common antidepressant, antianxiety, antipsychotic, and mood stabilizing medication.

## Client and Family Resources

### Organizations

Hazelden Betty Ford Foundation (www.hazeldenbettyford.org/recovery/families-friends): Includes support and tools for clients, families, and friends.

Learn to Cope (www.learn2cope.org/): A secular mutual-support group that offers education, resources, and peer support for families of people with SUDs (although primarily focused on OUD). They also maintain an online forum, but groups are only available in a few states.

Legal Action Center (www.lac.org): Offers information about the rights of people with criminal records, HIV/AIDS, and SUDs.

Mental Health America (www.mentalhealthamerica.net/): A nonprofit community-based organization that aims to improve public knowledge of mental disorders and enhance prevention and treatment strategies. It includes over 200 affiliates in 41 states, 6,500 affiliate staff, and over 10,000 volunteers.

National Alliance on Mental Illness (NAMI; www.nami.org): The largest grassroots educational, peer support, and mental health advocacy organization in the United States. Founded in 1979 by a group of family members of people with mental disorders, NAMI has developed into an association of hundreds of local affiliates, state organizations, and volunteers.

National Empowerment Center (https://power2u.org/): The Center has an extensive resource listing including a directory of consumer-run organizations, peer support, and webinars.

National Suicide Prevention Lifeline (https://suicidepreventionlifeline.org/ or 1-800-273-8255): Funded by SAMHSA, this national network of local crisis centers offer free and confidential support to people in suicidal crisis or emotional distress 24 hours a day, 7 days a week.

Parents of Addicted Loved Ones (https://palgroup.org/): A secular support group for parents who have a child with an SUD. They only have meetings in some states but also host telephone meetings.

### Mutual-Support Programs

Alcoholics Anonymous (AA; www.aa.org): Offers group meetings for people who have problems relating to drinking and wish to stop. AA sponsors offer members personal support from experienced individuals.

Al-Anon Family Groups (www.al-anon.org): Group meetings in which friends and families of people with substance use problems share experiences and learn to apply Al-Anon principles to their situations. Sponsorship helps members get personal support from more experienced individuals in the program.

Cocaine Anonymous (https://ca.org/): A mutual-support program for people with cocaine use disorder. Cocaine Anonymous follows the 12-Step tradition and offers meetings worldwide.

Dual Disorders Anonymous ([847] 781 - 1 553): A mutual-support program with 48 groups in several states (more than half in Illinois). This program is modeled after AA.

Dual Diagnosis Anonymous of Oregon (www.ddaoforegon.com/). This mutual-support program uses AA's 12 Step plus five more focused on CODs. The organization has chapters in several states and in Canada.

Dual Recovery Anonymous (www.draonline.org/): This mutual-support program follows 12-Step principles to support people in recovery from addiction and emotional/mental illness. It focuses on preventing relapse and actively improving quality of members’ lives via a mutual-support community.

Dual Diagnosis Recovery Network (www.dualdiagnosis.org/resource/ddrn/): Part of Foundations Recovery Network, the Dual Diagnosis Recovery Network is an advocacy group for people with CODs. They offer information on mutual-support programs, outreach, and education.

Emotions Anonymous (http://emotionsanonymous.org/): A 12-Step fellowship based on AA for people with any emotional difficulties (not only clinical mental disorders). Groups are located in more than 30 countries, with more than 600 active groups, including Skype and phone meetings.

Faces and Voices of Recovery (http://facesandvoicesofrecovery.org/): Offers recovery stories, news and events information, publications, and webinars.

Heroin Anonymous (www.heroinanonymous.org): A nonprofit fellowship of individuals in recovery from heroin addiction and committed to helping each other stay sober. This organization holds local support meetings, a directory of which can be found on their website.

Narcotics Anonymous (NA; www.na.org/): A global, community-based organization with a multilingual, multicultural membership that supports recovery from addiction through a 12-Step program, including regular attendance at group meetings. The group offers an ongoing support network for maintaining a drug-free lifestyle. NA does not focus on any particular addictive substance.

Nar-Anon Family Groups (www.nar-anon.org/): Group meetings in which friends and family of people with drug use problems can share their experiences and learn to apply the 12-Steps Nar-Anon program to their lives. Nar-Anon offers individualized support from experienced members acting as sponsors.

National Mental Health Consumers’ Self-Help Clearinghouse (www.mhselfhelp.org/): The organization has developed and offers a resource kit providing the names and contacts for resources and information on substance addictions, cooccurring disorders, services, and mutual help support.

Pills Anonymous (www.pillsanonymous.org): A 12-Step mutual-support fellowship that holds regular meetings in which individuals in recovery from addiction to medication can share their experiences, build their strengths, and offer hope for recovery to one another.

Recoveries Anonymous (www.r-a.org/): A 12-Step mutual fellowship that welcomes people with a broad range of problems, from addictions, to mental disorders, to “problem behaviors” (e.g., compulsive spending, risk-taking, suicidal behaviors).

Schizophrenia Alliance (https://sardaa.org/schizophrenia-alliance/sa-group-locations/): Operating under the auspices of the Schizophrenia and Related Disorders Alliance of America, this 12-Step mutual-support program offers information and fellowship for people with schizophrenia or other psychotic disorders, including bipolar disorder. They hold meetings among 1 50 groups throughout 31 states.

Secular Organizations for Sobriety (www.sossobriety.org/): A nonprofit, nonreligious network of autonomous, nonprofessional local groups that help people achieve and maintain abstinence from alcohol and drug addiction.

Self-Management and Recovery Training (SMART Recovery; www.smartrecovery.org/): SMART Recovery a self-empowering addiction recovery support group that teaches science-based tools for addiction recovery and grants access to an international recovery community of mutual-support groups.

Women for Sobriety (https://womenforsobriety.org/): An abstinence-based mutual-support program that helps women find individual paths to recovery by acknowledging their unique needs in recovery. It is not affiliated with other recovery organizations. It offers tools to help women in recovery develop coping skills focused on emotional growth, spiritual growth, self-esteem, and a healthy lifestyle.

### Publications and Other Resources

American Society of Addiction Medicine (www.asam.org/resources/patient-resources): Includes a treatment locator, listing of client and family support group, and a treatment guideline about opioid addiction.

Foundations Recovery Network Articles and Publications (www.dualdiagnosis.org/resource/): Offers material on COD treatment, gender-specific concerns, family functions, mutual support, advocacy, and success stories.

National Institute on Alcohol Abuse and Alcoholism (www.rethinkingdrinking.niaaa.nih.gov/help-links/): Provides links to patient and family education, help lines, and other recovery resources

NIDA (www.drugabuse.gov/nidamed-medical-health-professionals/tool-resources-your-practice/patient-materials): Patient materials include online tools, booklets, and fact sheets about substance misuse, prevention, and treatment.

SAMHSA (https://store.samhsa.gov/): Provides patient and family educational tools about SUD and co-occurring mental illness.

• No Longer Alone. A Story About Alcohol, Drugs, Depression, and Trauma: https://store.samhsa.gov/system/files/sma13-4781eng.pdf
• People Recover. An Educational Comic Book on Co-Occurring Disorders: https://store.samhsa.gov/product/people-recover/sma13-4712
• Should You Talk to Someone About a Drug, Alcohol, or Mental Health Problem? (https://store.samhsa.gov/product/Should-You-Talk-to-Someone-About-a-Drug-Alcohol-or-Mental-Health-Problem-/sma15-4585). This publication is available in English, Cambodian, Chinese, Russian, and Vietnamese.
• Steve's Path to a Better Life: Alcohol and Depression: https://store.samhsa.gov/system/files/sma16-5013.pdf

### Online Boards and Chat Rooms

12-Step forums: Some AA meetings are available online, each with their own view of medication.

• The AA online intergroup directory lists numerous online AA meetings: www.aa-intergroup.org/

Bipolar World Online (https://bipolarworld.org/): This online community includes support chat, an online forum, online journals, and articles about bipolar disorder.

Facebook forums and groups: A handful of COD and addiction recovery organizations maintain a presence on Facebook because of the ease of creating online mutual-support and chat groups.

• Dual Diagnosis Co-Occurring Mental Illness and Substance Disorders Treatment Programs: www.facebook.com/FirstDualDiagnosisTreatmentandPrograms1984/
• Recovery Group for Dual Diagnosis: www.facebook.com/events/139669280229645/
• Secular Organizations for Sobriety: www.facebook.com/groups/251215211975/

LifeRing Secular Recovery Dual Diagnosis Recovery Online Support Groups (https://www.lifering.org/post/lifering-offers-dual-diagnosis-recovery-support-group-online).

Mental Health America Online Support Groups (https://www.inspire.com/groups/menta l-health-america/).

SMART Recovery Online Forum (www.smartrecovery.org/community/forum.php).

### Mobile Apps

Foundations Recovery Network (www.dualdiag-nosis.org/apps-for-addiction-recovery-and-mental-health/): maintains a listing of COD, SUD, and mental illness-related mobile apps.