# Appendix A—Bibliography

Abroms, M., & Sher, L. (2016). Dual disorders and suicide. Journal of Dual Diagnosis, 72(2), 148–149. doi:10.1080/15504263.2016.1172898
Acri, M., Hooley, C. D., Richardson, N., & Moaba, L. B. (2017). Peer models in mental health for caregivers and families. Community Mental Health Journal, 53(2), 241–249. doi: 10.1007/s10597-016-0040-4 27344658
Afful, S. E., Strickland, J. R., Cottier, L, & Bierut, L. J. (2010). Exposure to trauma: A comparison of cocaine-dependent cases and a community-matched sample. Drug and Alcohol Dependence, 772(1-2), 46–53. doi:10.1016/j.drugalcdep.2010.05.012
Ahmedani, B. K., Peterson, E. L., Elu, Y., Rossom, R. C., Lynch, F., Lu, C. Y., … Simon, G. E. (2017). Major physical health conditions and risk of suicide. American Journal of Preventive Medicine, 53(3), 308–315. doi:10.1016/j.amepre.2017.04.001 28619532
Ait-Daoud, N., Blevins, D., Khanna, S., Sharma, S., & Holstege, C. P. (2017). Women and addiction. Psychiatric Clinics of North America, 40(2), 285–297. doi:10.1016/j.psc.2017.01.005 28477653
Akbar, M., Egli, M., Cho, Y., Song, B., & Noronha, A. (2018). Medications for alcohol use disorders: An overview. Pharmacology & Therapeutics, 185, 64–85. doi:10.1016/j.pharmthera.2017.11.007. 29191394
Alam, D. A., & Martorana, A. (2011). Addiction treatment: Level of care determination. Primary Care, 38(1), 125–136. doi:10.1016/j.pop.2010.11.009 21356425
Alarid, L. E, & Rubin, M. (2018). Misdemeanor arrestees with mental health needs: Diversion and outpatient services as a recidivism reduction strategy. International Journal of Offender Therapy and Comparative Criminology, 62(3), 575–590. doi:10.1177/0306624x16652892 27272524
Alcorn, J. L., 3rd, Gowin, J. L., Green, C. E., Swann, A. C., Moeller, E G., & Lane, S. D. (2013). Aggression, impulsivity, and psychopathic traits in combined antisocial personality disorder and substance use disorder. Journal of Neuropsychiatry and Clinical Neurosciences, 25(3), 229–232. doi:10.1176/appi.neuropsych.12030060 24026715
Alegría, A. A., Blanco, C., Retry, N. M., Skodol, A. E., Liu, S. M., Grant, B., & Hasin, D. (2013). Sex differences in antisocial personality disorder: Results from the National Epidemiologic Survey on Alcohol and Related Conditions. Personality Disorders, 4(3), 214–222. doi:10.1037/a0031681 23544428
Alexander, M., Layman, D., & Haugland, G. (2013). Validating the Modified Mini Screen (MMS) as a mental health referral screen for public assistance recipients in New York State. Annual Meeting of the American Public Health Association, Boston, MA.
Alexander, M. J., Haugland, G., Lin, S. P., Bertollo, D. N., & McCorry, F. A. (2008). Mental health screening in addiction, corrections and social service settings: Validating the MMS. International Journal of Mental Health and Addiction, 6(1), 105–119.
Ali, B., Green, K. M., Daughters, S. B., & Lejuez, C. W. (2017). Distress tolerance interacts with circumstances, motivation, and readiness to predict substance abuse treatment retention. Addictive Behaviors, 73, 99–104. doi:10.1016/j.addbeh.2017.04.016 28500908
Al-Rousan, T., Rubenstein, L., Sieleni, B., Deol, H., & Wallace, R. B. (2017). Inside the nation's largest mental health institution: A prevalence study in a state prison system. BMC Public Health, 77(1), 342. doi:10.1186/s12889-017-4257-0
American Association of Community Psychiatrists. (2016). LOCUS: Level of Care Utilization System for Psychiatric and Addiction Services: Adult version 20. Retrieved from https://drive.google.com/file/d/0B89alzXJnn4cV1dESWI2eFEzc3M/view
American College of Emergency Physicians. (January 2017). Alcohol screening in the emergency department. Policy statement. Retrieved from www.acep.org/qlobalassets/new-pdfs/policy-statements/alcohol-screeninq-in-the-emergency-department.pdf
American Psychiatric Association. (2010). Practice guideline for the treatment of patients with major depressive disorder. Retrieved from https://psychiatryonline.org/pb/assets/raw/sitewide/practiceguidelines/guidelines/mdd.jodf
American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: American Psychiatric Association.
Antai-Otong, D. (2016). Evidence-based care of the patient with borderline personality disorder. Nursing Clinics of North America, 57(2), 299–308. doi:10.1016/j.cnur.2016.01.012
Arkins, B., Begley, C., & Higgins, A. (2016). Measures for screening for intimate partner violence: A systematic review. Journal of Psychiatric Mental Health Nursing, 23(3-4), 217–235. doi:10.1111/jpm.12289 27029235
Arnold, L. E., Hodgkins, R, Caci, H., Kahle, J., & Young, S. (2015). Effect of treatment modality on long-term outcomes in attention-deficit/hyperactivity disorder: A systematic review. PLoS ONE, 70(2), e0116407. doi:10.1371/journal.pone.0116407
Arunogiri, S., & Lubman, D. I. (2015). Anxiety and substance use disorders: A worrying combination. Australasian Psychiatry, 23(4), 382–387. doi:10.1177/1039856215590053 26139701
Ashford, R. D., Meeks, M., Curtis, B., & Brown, A. M. (2018). Utilization of peer-based substance use disorder and recovery interventions in rural emergency departments: Patient characteristics and exploratory analysis. Journal of Rural Mental Health, 43(1), 17–29. doi:10.1037/rrnhOOOOl06
Asmundson, G. J., Taylor, S., & Smits, J. A. (2014). Panic disorder and agoraphobia: An overview and commentary on DSM-5 changes. Depression and Anxiety, 31(6), 480–486. doi:10.1002/da.22277 24865357
Atkinson, D. M., Rodman, J. L., Thuras, P. D., Shiroma, P. R., & Lim, K. O. (2017). Examining burnout, depression, and self-compassion in Veterans Affairs mental health staff. Journal of Alternative and Complementary Medicine, 23(7), 551–557. doi:10.1089/acm.2017.0087 28590766
Avery, J., Han, B. H., Zerbo, E., Wu, G., Mauer, E., Avery, J., … Penzner, J. B. (2017). Changes in psychiatry residents’ attitudes towards individuals with substance use disorders over the course of residency training. American Journal on Addictions, 26(1), 75–79. doi:10.1111/ajad.12406 27749984
Avery, J., & Zerbo, E. (2015). Improving psychiatry residents’ attitudes toward individuals diagnosed with substance use disorders. Harvard Review of Psychiatry, 23(4), 296–300. doi:10.1097/hrp.0000000000000047
Avery, J., Zerbo, E., & Ross, S. (2016). Improving psychiatrists’ attitudes towards individuals with psychotic disorders and co-occurring substance use disorders. Academic Psychiatry, 40(3), 520–522. doi:10.1007/s40596-015-0361-6 25977100
Ayangbayi, T., Okunade, A., Karakus, M., & Nianogo, T. (2017). Characteristics of hospital emergency room visits for mental and substance use disorders. Psychiatric Services, 68(4), 408–410. doi:10.1176/appi.ps.201600125 27974000
Babor, T. F., Higgins-Biddle, J. C., Saunders, J. B., & Monteiro, M. G. (2001). AUDIT: The alcohol use disorders identification test: Guidelines for use in primary care (2nd ed.). Retrieved from https://apps.who.int/iris/bitstream/handle/10665/67205/WHO_MSP_MSB_01.6a.pdf?sequence=1_&isAllowed=y
Bahji, A., Mazhar, M. N., Hudson, C. C., Nadkarni, P., MacNeil, B. A., & Hawken, E. (2019). Prevalence of substance use disorder comorbidity among individuals with eating disorders: A systematic review and metaanalysis. Psychiatry Research, 273, 58–66. doi:10.1016/j.psychres.2019.01.007 30640052
Bahorik, A. L., Sterling, S. A., Campbell, C. I., Weisner, C., Ramo, D., & Satre, D. D. (2018). Medical and nonmedical marijuana use in depression: Longitudinal associations with suicidal ideation, everyday functioning, and psychiatry service utilization. Journal of Affective Disorders, 241, 8–14. doi:10.1016/j.jad.2018.05.065 30086434
Baillargeon, J., Penn, J. V., Knight, K., Harzke, A. J., Baillargeon, G., & Becker, E. A. (2010). Risk of reincarceration among prisoners with co-occurring severe mental illness and substance use disorders. Administration and Policy in Mental Health, 37(4), 367–374. doi:10.1007/s10488-009-0252-9 19847638
Baker, A. L., Thornton, L. K., Hiles, S., Hides, L., & Lubman, D. I. (2012). Psychological interventions for alcohol misuse among people with co-occurring depression or anxiety disorders: A systematic review. Journal of Affective Disorders, 139(3), 217–229. doi:10.1016/j.jad.2011.08.004 21890213
Baker, J. H., Mitchell, K. S., Neale, M. C., & Kendler, K. S. (2010). Eating disorder symptomatology and substance use disorders: Prevalence and shared risk in a population based twin sample. International Journal of Eating Disorders, 43(7), 648–658. doi:10.1002/eat.20856 20734312
Bandelow, B., & Michaelis, S. (2015). Epidemiology of anxiety disorders in the 21st century. Dialogues in Clinical Neuroscience, 17(3), 327–335.26487813
Bandelow, B., Michaelis, S., & Wedekind, D. (2017). Treatment of anxiety disorders. Dialogues in Clinical Neuroscience, 79(2), 93–107.
Banerjee, S., & Spry, C. (2017). CADTH Rapid Response Reports. In Concurrent treatment for substance use disorder and trauma-related comorbidities: A review of clinical effectiveness and guidelines. Ottawa (ON): Canadian Agency for Drugs and Technologies in Health.
Barry, A. E., & Piazza-Gardner, A. K. (2012). Drunkorexia: Understanding the co-occurrence of alcohol consumption and eating/exercise weight management behaviors. Journal of American College Health, 60(3), 236–243. doi:10.1080/07448481.2011.587487 22420701
Barry, C. L., Epstein, A. J., Fiellin, D. A., Fraenkel, L., & Busch, S. H. (2016). Estimating demand for primary care-based treatment for substance and alcohol use disorders. Addiction, 111(8), 1376–1384. doi:10.1111/add.13364
Bartlett, D. (2017). Drug-induced serotonin syndrome. Critical Care Nurse, 37(1), 49–54. doi:10.4037/ccn2017.169
Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
Bateman, A. W., Gunderson, J., & Mulder, R. (2015). Treatment of personality disorder. Lancet, 385(9969), 735–743. doi:10.1016/s0140-6736(14)61394-5 25706219
Batterham, P. J., Ftanou, M., Pirkis, J., Brewer, J. L., Mackinnon, A. J., Beautrais, A., … Christensen, H. (2015). A systematic review and evaluation of measures for suicidal ideation and behaviors in population-based research. Psychological Assessment, 27(2), 501–512. doi:10.1037/pas0000053 25496086
Baum, N. (2016). Secondary traumatization in mental health professionals: A systematic review of gender findings. Trauma, Violence, & Abuse, 17(2), 221–235. doi:10.1177/1524838015584357
Beck, A. T., & Steer, R. A. (1987). Beck Depression Inventory manual. San Antonio, TX: The Psychological Corporation, Harcourt Brace Jovanovich.
Beck, A. T., Steer, R. A., & Brown, G. K. (1996). Beck Depression Inventory-II manual. San Antonio, TX: Psychological Corporation.
Becker, M. A., Boaz, T. L., Andel, R., & Hafner, S. (2017). Risk of early rehospitalization for non-behavioral health conditions among adult Medicaid beneficiaries with severe mental illness or substance use disorders. Journal of Behavioral Health Services & Research, 44(1), 113–121. doi:10.1007/s11414-016-9516-9 27270399
Beidas, R. S., Marcus, S., Wolk, C. B., Powell, B., Aarons, G. A., Evans, A. C., … Mandell, D. S. (2016). A prospective examination of clinician and supervisor turnover within the context of implementation of evidence-based practices in a publicly-funded mental health system. Administration and Policy in Mental Health and Mental Health Services Research, 43(5), 640–649.26179469
Bell, H. (2018). Creative interventions for teaching empathy in the counseling classroom. Journal of Creativity in Mental Health, 73(1), 106–120. doi:10.1080/15401383.2017.1328295
Belleau, E. L., Chin, E. G., Wanklyn, S. G., Zambrano-Vazquez, L., Schumacher, J. A., & Coffey, S. F. (2017). Pre-treatment predictors of dropout from prolonged exposure therapy in patients with chronic posttraumatic stress disorder and comorbid substance use disorders. Behaviour Research and Therapy, 91, 43–50.28147254
Benich, J. J., 3rd, Bragg, S. W., & Freedy, J. R. (2016). Psychopharmacology in primary care settings. Primary Care, 43(2), 327–340. doi:10.1016/j.pop.2016.01.002 27262011
Bennett, A. C., Gibson, C., Rohan, A. M., Howland, J. E, & Rankin, K. M. (2018). Mental health and substance use-related hospitalizations among women of reproductive age in Illinois and Wisconsin. Public Health Reports, 134(1), 17–26.30508497
Bennett, M. E., Bradshaw, K. R., & Catalano, L. T. (2017). Treatment of substance use disorders in schizophrenia. American Journal of Drug and Alcohol Abuse, 43(4), 377–390. doi:10.1080/00952990.2016.1200592 27715317
Benningfield, M. M., Arria, A. M., Kaltenbach, K., Heil, S. H. Stine, S. M. Coyle, M. G. Martin, P. R. (2010). Co-occurring psychiatric symptoms are associated with increased psychological, social, and medical impairment in opioid dependent pregnant women. American Journal on Addictions, 79(5), 416^121. doi:10.1111/j.1521-0391.2010.00064.x
Benston, E. A. (2015). Housing programs for homeless individuals with mental illness: Effects on housing and mental health outcomes. Psychiatric Services, 66(8), 806–816. dol:10.1176/appl.ps.20140029425873027
Bentley, K. H., Franklin, J. C., Ribelro, J. D., Kleiman, E. M., Fox, K. R., & Nock, M. K. (2016). Anxiety and Its disorders as risk factors for suicidal thoughts and behaviors: A meta-analytic review. Clinical Psychology Review, 43, 30–46. doi:10.1016/j.cpr.2015.11.008 26688478
Ben-Zeev, D., Kaiser, S. M., & Krzos, I. M. (2014). Remote “hovering” with individuals with psychotic disorders and substance use: Feasibility, engagement, and therapeutic alliance with a text-messaging mobile interventionist. Journal of Dual Diagnosis, 10(4), 197–203.
Berenz, E. C., & Coffey, S. F. (2012). Treatment of cooccurring posttraumatic stress disorder and substance use disorders. Current Psychiatry Reports, 74(5), 469–477. doi:10.1007/s11920-012-0300-0
Bergink, V., Rasgón, N., & Wisner, K. F. (2016). Postpartum psychosis: Madness, mania, and melancholia in motherhood. American Journal of Psychiatry, 773(12), 1179–1188. doi:10.1176/appi.ajp.2016.16040454
Bergman, B. G., Greene, M. C., Hoeppner, B. B., Slaymaker, V., & Kelly, J. F. (2014). Psychiatric comorbidity and 12-step participation: A longitudinal investigation of treated young adults. Alcoholism: Clinical and Experimental Research, 38(2), 501–510. doi:10.1111/acer.12249 24033550
Bernert, R. A., Horn, M. A., & Roberts, F. W. (2014). A review of multidisciplinary clinical practice guidelines in suicide prevention: Toward an emerging standard in suicide risk assessment and management, training and practice. Academic Psychiatry, 38(5), 585–592. doi:10.1007/s40596-014-0180-1 25142247
Bernstein, J., Derrington, T. M., Belanoff, C., Cabral, H. J., Babakhanlou-Chase, H., Diop, H., … Kotelchuck, M. (2015). Treatment outcomes for substance use disorder among women of reproductive age in Massachusetts: A population-based approach. Drug and Alcohol Dependence, 147, 151–159. doi:10.1016/j.drugalcdep 25496707
Bhugra, D. (2005). The global prevalence of schizophrenia. PLoS Medicine, 2(5), e151. doi:10.1371/journal.pmed.0020151 15916460
Black, D. W. (2015). The natural history of antisocial personality disorder. Canadian Journal of Psychiatry, 60(7), 309–314. doi:10.1177/070674371506000703 26175389
Black, D. W. (2017). The treatment of antisocial personality disorder. Current Treatment Options in Psychiatry, 4(4), 295–302.
Blanco, C., Alegría, A. A., Liu, S. M., Secades-Villa, R., Sugaya, L., Davies, C., & Nunes, E. V. (2012). Differences among major depressive disorder with and without co-occurring substance use disorders and substance-induced depressive disorder: Results from the National Epidemiologic Survey on Alcohol and Related Conditions. Journal of Clinical Psychiatry, 73(6), 865–873. doi:10.4088/JCP.10m06673 22480900
Blanco, C., Compton, W. M., Saha, T. D., Goldstein, B. I., Rúan, W. J., Huang, B., & Grant, B. F. (2017). Epidemiology of DSM-5 bipolar I disorder: Results from the National Epidemiologic Survey on Alcohol and Related Conditions - III. Journal of Psychiatric Research, 84, 310–317. doi:10.1016/j.jpsychires.2016.10.003 27814503
Blanco, C., Okuda, M., Markowitz, J. C., Liu, S. M., Grant, B. E, & Hasin, D. S. (2010). The epidemiology of chronic major depressive disorder and dysthymic disorder: Results from the National Epidemiologic Survey on Alcohol and Related Conditions. Journal of Clinical Psychiatry, 77(12), 1645–1656. doi:10.4088/JCR09rn05663gry
Blanco, C., Xu, Y., Brady, K., Perez-Fuentes, G., Okuda, M., & Wang, S. (2013). Comorbidity of posttraumatic stress disorder with alcohol dependence among US adults: Results from National Epidemiological Survey on Alcohol and Related Conditions. Drug and Alcohol Dependence, 132(3), 630–638. doi:S0376-8716(13)00145-2 [pii];10.1016/j.drugalcdep.2013.04.016 [doi]23702490
Blodgett, J. C., Maisel, N. C., Fuh, I. L., Wilbourne, P. L., & Finney, J. W. (2014). How effective is continuing care for substance use disorders? A meta-analytic review. Journal of Substance Abuse Treatment, 46(2), 87–97. doi:10.1016/j.jsat.2013.08.022 24075796
Boden, M. T., & Hoggatt, K. J. (2018). Substance use disorders among veterans in a nationally representative sample: Prevalence and associated functioning and treatment utilization. Journal of Studies on Alcohol and Drugs, 79(6), 853–861.30573015
Bogenschutz, M. P., Donovan, D. M., Mandler, R. N., Perl, H. I., Forcehimes, A. A., Crandall, C., … Douaihy, A. (2014a). Brief intervention for patients with problematic drug use presenting in emergency departments: A randomized clinical trial. JAMA Internal Medicine, 774(11), 1736–1745. doi:10.1001/jamainternmed.2014.4052
Bogenschutz, M. R., Rice, S. L., Tonigan, J. S., Vogel, H. S., Nowinski, J., Hume, D., & Arenella, P. B. (2014b). 1 2-step facilitation for the dually diagnosed: A randomized clinical trial. Journal of Substance Abuse Treatment, 46(4), 403–411. doi:10.1016/j.jsat.2013.12.009 24462479
Boggs, J. M., Beck, A., Hubley, S., Peterson, E. L., Hu, Y., Williams, L. K., … Ahmedani, B. K. (2018). General medical, mental health, and demographic risk factors associated with suicide by firearm compared with other means. Psychiatric Services, 69(6), 677–684. doi:10.1176/appi.ps.201700237 29446332
Bohnert, K. M., Ilgen, M. A., Louzon, S., McCarthy, J. R, & Katz, I. R. (2017). Substance use disorders and the risk of suicide mortality among men and women in the US Veterans Health Administration. Addiction, 772(7), 1193–1201. doi:10.1111/add.13774
Bolton, J. M., Gunnell, D., & Turecki, G. (2015). Suicide risk assessment and intervention in people with mental illness. BMJ, 351, h4978. doi:10.1136/bmj.h4978 26552947
Bond, G. R., & Drake, R. E. (2015). The critical ingredients of assertive community treatment. World Psychiatry, 74(2), 240–242. doi:10.1002/wps.20234
Bonsack, C., GibelIini Manetti, S., Favrod, J., Montagrin, Y., Besson, J., Bovet, R, & Conus, P. (2011). Motivational intervention to reduce cannabis use in young people with psychosis: A randomized controlled trial. Psychotherapy and Psychosomatics, 80(5), 287–297. doi:10.1159/000323466 21646823
Boothroyd, R. A., Peters, R. H., Armstrong, M. L., Rynearson-Moody, S., & Caudy, M. (2015). The psychometric properties of the simple screening instrument for substance abuse. Evaluation and the Health Professions, 38(4), 538–562. doi:10.1177/0163278713490165 23754847
Borges, G., Bagge, C. L., Cherpitel, C. J., Conner, K. R., Orozco, R., & Rossow, I. (2017). A meta-analysis of acute use of alcohol and the risk of suicide attempt. Psychological Medicine, 47(5), 949–957. doi:10.1017/S0033291716002841 27928972
Bowen, S., Witkiewitz, K., Clifasefi, S. L., Grow, J., Chawla, N., Hsu, S. H. … Larimer, M. E. (2014). Relative efficacy of mindfulness-based relapse prevention, standard relapse prevention, and treatment as usual for substance use disorders: A randomized clinical trial. JAMA Psychiatry, 77(5), 547–556. doi:10.1001/jamapsychiatry.2013.4546
Bradizza, C. M., Stasiewicz, P. R., & Dermen, K. H. (2014). Behavioral interventions for individuals dually-diagnosed with a severe mental illness and a substance use disorder. Current Addiction Reports, 7(4), 243–250. doi:10.1007/s40429-014-0032-9
Brady, K. T., Back, S. E., & Coffey, S. F. (2004). Substance abuse and posttraumatic stress disorder. Current Directions in Psychological Science, 13(5), 206–209. doi:10.1111/j.0963-7214.2004.00309.x
Brady, K. T., Haynes, L. F., Hartwell, K. J., & Killeen, T. K. (2013). Substance use disorders and anxiety: A treatment challenge for social workers. Social Work in Public Health, 28(3-4), 407–423. doi:10.1080/19371918.2013.774675 23731428
Brazil, I. A., van Dongen, J. D. M., Maes, J. H. R., Mars, R. B., & Baskin-Sommers, A. R. (2018). Classification and treatment of antisocial individuals: From behavior to biocognition. Neuroscience and Biobehavioral Reviews, 91, 259–277. doi:10.1016/j.neubiorev.2016.10.010 27760372
Brewerton, T. D. (2014). Are eating disorders addictions? In T. Brewerton & A. Baker Dennis (Eds.), Eating disorders, addictions and substance use disorders: Research, clinical and treatment perspectives (pp. 267–299). New York: Springer-Verlag Publishing.
Briggs, C. A., & Reneson, S. (2010). Counseling addicted veterans: What to know and how to help. Retrieved from https://pdfs.semanticscholar.org/9742/967aac815ca02c4f599b36be996d0b10d3d9.pdf
Brockington, I. (2017). Suicide and filicide in postpartum psychosis. Archives of Women's Mental Health, 20(1), 63–69. doi:10.1007/s00737-016-0675-8
Broderick, K. B., Kaplan, B., Martini, D., & Caruso, E. (2015). Emergency physician utilization of alcohol/substance screening, brief advice and discharge: A 10-year comparison. Journal of Emergency Medicine, 49(4), 400–407. doi:10.1016/j.jemermed.2015.05.014 26234716
Bromberg, S. R., Backman, T. L., Krow, J., & Frankel, K. A. (2010). The Haven Mother's House Modified Therapeutic Community: Meeting the gap in infant mental health services for pregnant and parenting mothers with drug addiction. Infant Mental Health Journal, 31(3), 255–276. doi:10.1002/imhj.20255 28543223
Brook, J. S., Zhang, C., Rubenstone, E., Primack, B. A., & Brook, D. W. (2016). Comorbid trajectories of substance use as predictors of antisocial personality disorder, major depressive episode, and generalized anxiety disorder. Addictive Behaviors, 62, 114–121. doi:10.1016/j.addbeh.2016.06.003 27344118
Brooner, R. K., Kidorf, M. S., King, V. L., Peirce, J., Neufeld, K., Stoller, K., & Kolodner, K. (2013). Managing psychiatric comorbidity within versus outside of methadone treatment settings: A randomized and controlled evaluation. Addiction, 708(11), 1942–1951.
Brown, C. H., Bennett, M. E., Li, L., & Bellack, A. S. (2011). Predictors of initiation and engagement in substance abuse treatment among individuals with co-occurring serious mental illness and substance use disorders. Addictive Behaviors, 36(5), 439–447. doi:10.1016/j.addbeh.2010.12.001 21196081
Brown, G. K., & Green, K. L. (2014). A review of evidence-based follow-up care for suicide prevention: Where do we go from here? American Journal of Preventive Medicine, 47(3)(Suppl. 2), S209–S215. doi:10.1016/j.amepre.2014.06.006 25145741
Brown, V. B., Harris, M., & Fallot, R. (2013). Moving toward trauma-informed practice in addiction treatment: A collaborative model of agency assessment. Journal of Psychoactive Drugs, 45(5), 386–393. doi:10.1080/02791072.2013.844381
Bryant, J. B., Darkes, J., & Rahal, C. (2012). College students’ compensatory eating and behaviors in response to alcohol consumption. Journal of American College Health, 60(5), 350–356. doi:10.1080/07448481.2011.630702 22686357
Buck, K. D., & Lysaker, P. H. (2010). Clinical supervision for the treatment of adults with severe mental illness: Pertinent issues when assisting graduate nursing students. Perspectives in Psychiatric Care, 46(3), 234–243. doi:10.1111/j.1744-6163.2010.00258.x 20591130
Buckner, J. D., Heimberg, R. G., Ecker, A. H., & Vinci, C. (2013). A biopsychosocial model of social anxiety and substance use. Depression and Anxiety, 30(3), 2Jb–284. doi:10.1002/da.22032
Bukach, A. M., Ejaz, F. K., Dawson, N., & Gitter, R. J. (2017). Turnover among community mental health workers in Ohio. Administration and Policy in Mental Health and Mental Health Services Research, 44(1), 115–122. doi:10.1007/s10488-015-0706-1 26662638
Bureau of Labor Statistics. (2019, March 7). Labor force statistics from the Current Population Survey. Databases, tables & calculators by subject. Retrieved from https://data.bls.gov/timeseries/lns14000000
Bureau of Labor Statistics (BLS). (2020, February 11). Job openings and labor turnover—August 2019. Retrieved from www.bls.gov/news.release/pdf/jolts.pdf
Bureau of Labor Statistics. (2020, March 3). Databases, tables & calculators by subject. Labor force statistics from the Current Population Survey. Retrieved from https://data.bls.aov/timeseries/LNS14000000
Burke, S. C., Cremeens, J., Vail-Smith, K., & Woolsey, C. (2010). Drunkorexia: Calorie restriction prior to alcohol consumption among college freshman. Journal of Alcohol and Drug Education, 54(2), 17–34.
Bush, K., Kivlahan, D. R., McDonell, M. B., Fihn, S. D., & Bradley, K. A. (1998). The AUDIT alcohol consumption questions (AUDIT-C): An effective brief screening test for problem drinking. Archives of Internal Medicine, 758(16), 1789–1795.
Büttner, M., O'Hara, M. W. & Watson, D. (2012). The structure of women's mood in the early postpartum. Assessment, 79, 247–256.
Cabassa, L. J., & Baumann, A. A. (2013). A two-way street: Bridging implementation science and cultural adaptations of mental health treatments. Implementation Science: IS, 8, 90. doi:10.1186/1748-5908-8-90 23958445
Campbell, B. K., Guydish, J., Le, T., Wells, E. A., & McCarty, D. (2015). The relationship of therapeutic alliance and treatment delivery fidelity with treatment retention in a multisite trial of twelve-step facilitation. Psychology of Addictive Behaviors, 29(1), 106–113. doi:10.1037/adb0000008 25134056
Cardno, A. G., & Owen, M. J. (2014). Genetic relationships between schizophrenia, bipolar disorder, and schizoaffective disorder. Schizophrenia Bulletin, 40(3), 504–51 5. doi:10.1093/schbul/sbu016 24567502
Carpenter, R. W., Wood, P. K. & Trull, T. J. (2016). Comorbidity of borderline personality disorder and lifetime substance use disorders in a nationally representative sample. Journal of Personality Disorders, 30(3), 336–350. doi:10.1521/pedi_2015_29_197 25893556
Carra, G., Bartoli, R., Crocamo, C., Brady, K. T., & Clerici, M. (2014) . Attempted suicide in people with co-occurring bipolar and substance use disorders: Systematic review and meta-analysis. Journal of Affective Disorders, 167, 125–135. doi:10.1016/j.jad.2014.05.066 24955564
Carroll, J. R X., & McGinley, J. J. (2000). Mental health screening form-iii (MHSR-III). Unpublished screening instrument, Project Return Roundation, Inc., New York, NY.
Carroll, J. F. X., & McGinley, J. J. (2001). A screening form for identifying mental health problems in alcohol/other drug dependent persons. Alcoholism Treatment Quarterly, 19(4), 33–47. doi:10.1300/J020v19n04_02
Carroll, T. D., Currier, J. M., McCormick, W. H., & Drescher, K. D. (2017). Adverse childhood experiences and risk for suicidal behavior in male Iraq and Afghanistan veterans seeking PTSD treatment. Psychological Trauma, 9(5), 583–586. doi:10.1037/tra0000250 28080076
Carter, A. C., Capone, C., & Short, E. E. (2011). Cooccurring posttraumatic stress disorder and alcohol use disorders in veteran populations. Journal of Dual Diagnosis, 7(4), 285–299. doi:10.1080/15504263.2011.620453 23087599
Center for Behavioral Health Statistics and Quality (CBHSQ). (2019). 2018 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://www.samhsa.gov/data/
Center for Mental Health Services. (1998). Cooccurring psychiatric and substance disorders in managed care systems: Standards of care, practice guidelines, workforce competencies, and training curricula. Retrieved from http://citeseerx.ist.psu.edu/viewdoc/download?doi=10.1.1.493.5621&rep=rep1_&type=pdf
Center for Quality Assessment and Improvement in Menta Health. (2007). The Suicide Behaviors Questionnaire-Revised (SBQ-R) - Overview. Retrieved from http://www.cqaimh.org/pdf/tool_sbq-r.pdf
Center for Substance Abuse Treatment. (1994). Simple screening instruments for outreach for alcohol and other drug abuse and infectious diseases. Treatment improvement Protocol (TIP) Series 11 (DHHS Publication No. (SMA) 94-2094). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1995). Alcohol and other drug screening of hospitalized trauma patients. Treatment Improvement Protocol (TIP) Series 16 (DHHS Publication No. (SMA) 95-3041). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (1997). A guide to substance abuse services for primary care clinicians. Treatment Improvement Protocol (TIP) Series 24 (DHHS Publication No. (SMA) 97-3139). Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment. (1998a). Comprehensive case management for substance abuse treatment. Treatment Improvement Protocol (TIP) Series 27 (DHHS Publication No. (SMA) 15-4215). Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment. (1998b). Substance use disorder treatment for people with physical and cognitive disabilities. Treatment Improvement Protocol (TIP) Series 29 (DHHS Publication No. (SMA) 98-3249). Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment. (1999a). Brief interventions and brief therapies for substance abuse. Treatment Improvement Protocol (TIP) Series 34 (DHHS Publication No. (SMA) 99-3353). Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment. (1999b). Enhancing motivation for change in substance abuse treatment. Treatment Improvement Protocol (TIP) Series 35 (DHHS Publication No. (SMA) 99-3354). Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment. (2000a). Changing the conversation: Improving substance abuse treatment. The National Treatment Improvement Plan. Panel reports, public hearings, and participant acknowledgements. HHS Publication No. (SMA) 003479. Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment. (2000b). Comprehensive case management for substance abuse treatment. Treatment Improvement Protocol (TIP) Series 27 (DHHS Publication No. (SMA) 1 5-421 5). Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment. (2000c). Substance abuse treatment for persons with child abuse and neglect issues. Treatment Improvement Protocol (TIP) Series 36 (DHHS Publication No. (SMA) 00-3357). Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment. (2005a). 9 substance-induced disorders. In Substance abuse treatment for persons with co-occurring disorders. Treatment Improvement Protocol (TIP) Series, No. 42. Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment. (2005b). Substance abuse treatment for adults in the criminal justice system. Treatment Improvement Protocol (TIP) Series 44 (DHHS Publication No. (SMA) 05-4056). Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment. (2006a). Addiction counseling competencies: The knowledge, skills, and attitudes of professional practice. Technical Assistance Publication (TAP) Series 21 (DHHS Publication No. (SMA) 06-4171). Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment. (2006b). Detoxification from alcohol and other drugs. Treatment Improvement Protocol (TIP) Series 45 (DHHS Publication No. (SMA) 06-4131). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2008). Managing depressive symptoms in substance abuse clients during early recovery. Treatment Improvement Protocol (TIP) Series 48. (DHHS Publication No. (SMA) 08-4353). Rockville, MD: Center for Substance Abuse Treatment.
Center for Substance Abuse Treatment. (2009). Addressing suicidal thoughts and behaviors in substance abuse treatment. Treatment Improvement Protocol (TIP) Series 50 (HHS Publication No. (SMA) 09-4381). Rockville, MD: Center for Substance Abuse Treatment.
Centers for Disease Control and Prevention (CDC). (2014). Healthy People 2020. Retrieved from www.cdc.gov/dhdsp7hp2020.htm
Centers for Disease Control and Prevention. (2018). Suicide rising across the US. Retrieved from www.cdc.gov/vitalsiqns/suicide/index.html
Centers for Disease Control and Prevention. (2020). Underlying Cause of Death 1999-2018 on CDC WONDER Online Database. Retrieved from https://wonder.cdc.gov/ucd-icd10.html
Chan, Y. E., Huang, H., Bradley, K., & Unutzer, J. (2014). Referral for substance abuse treatment and depression improvement among patients with co-occurring disorders seeking behavioral health services in primary care. Journal of Substance Abuse Treatment, 46(2), 106–112. doi:10.1016/j.jsat.2013.08.016 24095002
Chan, Y. F., Huang, H., Sieu, N., & Unutzer, J. (2013). Substance screening and referral for substance abuse treatment in an integrated mental health care program. Psychiatric Services, 64(1), 88–90. doi:10.1176/appi.ps.201200082 23280462
Chaple, M., Sacks, S., Randell, J., & Kang, B. (2016). A technical assistance framework to facilitate the delivery of integrated behavioral health services in Federally Qualified Health Centers (FQHCs). Journal of Substance Abuse Treatment, 60, 62–69. doi:10.1016/j.jsat.2015.08.006 26422450
Chapman, S. A., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental health and substance use disorders. American Journal of Preventive Medicine, 54(6S3), S267–S274. doi:10.1016/j.amepre.2018.02.019 29779551
Chapman, S. L., & Wu, L. T. (2013). Postpartum substance use and depressive symptoms: A review. Women and Health, 53(5), 479–503. doi:10.1080/03630242.2013.804025 23879459
Charzynska, K., Kucharska, K., & Mortimer, A. (2015). Does employment promote the process of recovery from schizophrenia? A review of the existing evidence. International Journal of Occupational Medicine and Environmental Health 28(3), 407–418. doi:10.13075/ijorneh.1896.00341 26190722
Cherry, D., Albert, M., & McCaig, L. F. (2018). Mental health-related physician office visits by adults aged 18 and over: United States, 2012-2014. NCHS Data Brief, June (311), 1–8.
Chhatre, S., Cook, R., Mallik, E., & Jayadevappa, R. (2017). Trends in substance use admissions among older adults. BMC Health Services Research, 17(1), 584. doi:10.1186/s12913-017-2538-z 28830504
Chinman, M., George, P., Dougherty, R. H., Daniels, A. S., Chose, S. S., Swift, A., & Delphin-Rittmon, M. E. (2014). Peer support services for individuals with serious mental illnesses: Assessing the evidence. Psychiatric Services, 65(4), 429–441.24549400
Choi, N. G., DiNitto, D. M., Marti, C. N. & Choi, B. Y. (2017). Association of adverse childhood experiences with lifetime mental and substance use disorders among men and women aged 50+ years. International Psychogeriatrics, 29(3), 359–372. doi:10.1017/s1041610216001800 27780491
Choi, S., Adams, S. M., MacMaster, S. A., & Seiters, J. (2013) . Predictors of residential treatment retention among individuals with co-occurring substance abuse and mental health disorders. Journal of Psychoactive Drugs, 45(2), 122–131. doi:10.1080/02791072.2013.785817 23909000
Chow, C. M., Wieman, D., Cichocki, B., Qvicklund, H., & Hiersteiner, D. (2013). Mission impossible: Treating serious mental illness and substance use co-occurring disorder with integrated treatment: A meta-analysis. Mental Health and Substance Use: Dual Diagnosis, 6(2), 150–168. doi:10.1080/17523281.2012.693130
Clark, C., Guenther, C. C., & Mitchell, J. N. (2016). Case management models in permanent supported housing programs for people with complex behavioral issues who are homeless. Journal of Dual Diagnosis, 12(2), 185–192. doi:10.1080/15504263.2016.1176852 27070841
Clark, R. E., Samnaliev, M., & McGovern, M. P. (2007). Treatment for co-occurring mental and substance use disorders in five state Medicaid programs. Psychiatric Services, 58(7), 942–948. doi:10.1176/ps.2007.58.7.942 17602010
Cleary, M., Hunt, G. E., Matheson, S., & Walter, G. (2009). Psychosocial treatments for people with co-occurring severe mental illness and substance misuse: Systematic review. Journal of Advanced Nursing, 65(2), 238–258. doi:10.1111/j.1365-2648.2008.04879.X 19016921
Coffey, S. R., Schumacher, J. A., Nosen, E., Littlefield, A. K., Henslee, A. M., Lappen, A., & Stasiewicz, R R. (2016). Trauma-focused exposure therapy for chronic posttraumatic stress disorder in alcohol and drug dependent patients: A randomized controlled trial. Psychology of Addictive Behaviors, 30(7), 778–790. doi:10.1037/adb0000201 27786516
Cohen, A., Freeborn, B., & McManus, B. (2013). Competition and crowding out in the market for outpatient substance abuse treatment. International Economic Review, 54(1), 159–184. doi:10.1111/j.1468-2354.2012.00729.x
Cohen, L. R., Lield, C., Campbell, A. N., & Hien, D. A. (2013). Intimate partner violence outcomes in women with PTSD and substance use: A secondary analysis of NIDA Clinical Trials Network “Women and Trauma” multi-site study. Addictive Behaviors, 38(7), 2325–2332. doi:10.1016/j.addbeh.2013.03.006 23584194
Colby, S. L., & Ortman, J. M. (2014). Projections of the size and composition of the U.S. population: 2014 to 2060. Current Population Reports, P25–1143, Washington, DC: U.S. Census Bureau.
Collins, S. E., Malone, D. K., & Clifasefi, S. L. (2013). Housing retention in single-site housing first for chronically homeless individuals with severe alcohol problems. American Journal of Public Health, 703(Suppl. 2), S269–S274. doi:10.2105/ajph.2013.301312
Conner, K. R., Gamble, S. A., Bagge, C. L., He, H., Swogger, M. T., Watts, A., & Houston, R. J. (2014). Substance-induced depression and independent depression in proximal risk for suicidal behavior. Journal of Studies on Alcohol and Drugs, 75(4), 567–572.24988255
Connors, G. J., Maisto, S. A., Schlauch, R. C., Dearing, R. L., Prince, M. A., & Duerr, M. R. (2016). Therapeutic alliances predict session by session drinking behavior in the treatment of alcohol use disorders. Journal of Consulting and Clinical Psychology, 84(11), 972–982. doi:10.1037/ccp0000130 27548032
Cook, B. L., Trinh, N. H., Li, Z., Hou, S. S., & Progovac, A. M. (2017). Trends in racial-ethnic disparities in access to mental health care, 2004-2012. Psychiatric Services, 68(1), 9–16. doi:10.1176/appi.ps.201500453 27476805
Cook, T. B. (2013). Recent criminal offending and suicide attempts: A national sample. Social Psychiatry and Psychiatric Epidemiology, 48(5), 767–774. doi:10.1007/s00127-012-0567-9 22918292
Cougle, J. R., Hakes, J. K., Macatee, R. J., Chavarria, J., & Zvolensky, M. J. (2015). Quality of life and risk of psychiatric disorders among regular users of alcohol, nicotine, and cannabis: An analysis of the National Epidemiological Survey on Alcohol and Related Conditions (NESARC). Journal of Psychiatric Research, 66-67, 135–141. doi:10.1016/j.jpsychires.(2015).05.004 26022838
Cox, K. B., Malte, C. A., & Saxon, A. J. (2017). Characteristics and service utilization of homeless veterans entering VA substance use treatment. Psychological Services, 14(2), 208–213. doi:10.1037/ser0000133 28481606
Craske, M. G., & Stein, M. B. (2016). Anxiety. Lancet, 388(10063), 3048–3059. doi:10.1016/s0140-6736(16)30381-6 27349358
Creswell, K. G., Bachrach, R. L., Wright, A. G., Pinto, A., & Anseil, E. (2016). Predicting problematic alcohol use with the DSM-5 alternative model of personality pathology. Personality Disorders, 7(1), 103–111. doi:10.1037/per0000131 26389625
Crisanti, A. S., Duran, D., Greene, R. N., Reno, J., Luna-Anderson, C., & Altschul, D. B. (2017). A longitudinal analysis of peer-delivered permanent supportive housing: Impact of housing on mental and overall health in an ethnically diverse population. Psychological Services, U(2), 141–153. doi:10.1037/ser0000135
Crits-Christoph, P., Hamilton, J. L., Ring-Kurtz, S., Gallop, R., McClure, B., Kulaga, A., & Rotrosen, J. (2011). Program, counselor, and patient variability in the alliance: A multilevel study of the alliance in relation to substance use outcomes. Journal of Substance Abuse Treatment, 40(4), 405–413. doi:10.1016/j.jsat.2011.01.003 21349680
Crowley, R. A., & Kirschner, N. (2015). The integration of care for mental health, substance abuse, and other behavioral health conditions into primary care: Executive summary of an American College of Physicians position paper. Annals of Internal Medicine, 163(4), 298–299. doi:10.7326/m15-0510 26121401
Crunelle, C. L., van den Brink, W., Moggi, R., Konstenius, M., Franck, J., Levin, F. R., … Matthys, F. (2018). International consensus statement on screening, diagnosis and treatment of substance use disorder patients with comorbid attention deficit/hyperactivity disorder. European Addiction Research, 24(1), 43–51. doi:10.1159/000487767 29510390
Cunill, R., Castells, X., Tobias, A., & Capella, D. (2015). Pharmacological treatment of attention deficit hyperactivity disorder with co-morbid drug dependence. Journal of Psychopharmacology, 29(1), 15–23. doi:10.1177/0269881114544777 25142405
Cunningham, K. C., Farmer, C., LoSavio, S. T., Dennis, P. A., Clancy, C. R., Hertzberg, M. A., … Beckham, J. C. (2017). A model comparison approach to trauma-related guilt as a mediator of the relationship between PTSD symptoms and suicidal ideation among veterans. Journal of Affective Disorders, 221, 227–231. doi:10.1016/j.jad.2017.06.046 28654847
Curtis, M. A., Garlington, S., & Schottenfield, L. S. (2013). Alcohol, drug, and criminal history restrictions in public housing. Cityscape, 15, 37–52.
Cusack, K. J., Morrissey, J. R., Cuddeback, G. S., Prins, A., & Williams, D. M. (2010). Criminal justice involvement, behavioral health service use, and costs of forensic assertive community treatment: A randomized trial. Community Mental Health Journal, 46(4), 356–363. doi:10.1007/s10597-010-9299-z 20217230
Cusack, M., & Montgomery, A. E. (2017). Examining the bidirectional association between veteran homelessness and incarceration within the context of permanent supportive housing. Psychological Services, 74(2), 250–256. doi:10.1037/ser0000110
Cutcliffe, J. R., Travale, R., Richmond, M. M., & Green, T. (2016). Considering the contemporary issues and unresolved challenges facing therapeutic communities for clients with alcohol and substance abuse. Issues in Mental Health Nursing, 37(9), 642–650. doi:10.3109/01612840.2016.1169465 27128141
Daley, D. C., & Mariait, G. A. (1992). Relapse prevention: Cognitive and behavioral interventions. In J. G. Lowinson, P. Ruiz, R. B. Millrnan, & J. G. Langrod (Eds.), Substance abuse: A comprehensive textbook (pp. 533–542). Baltimore, MD: Williams and Wilkins.
Danielson, M. L., Bitsko, R. H., Ghandour, R. M., Holbrook, J. R., Kogan, M. D., & Blumberg, S. J. (2018). Prevalence of parent-reported ADHD diagnosis and associated treatment among US children and adolescents, 2016. Journal of Clinical Child & Adolescent Psychology, 47(2), 199–212.29363986
Darvishi, N., Farhadi, M., Haghtalab, T., & Poorolajal, J. (2015) . Alcohol-related risk of suicidal ideation, suicide attempt, and completed suicide: A meta-analysis. PLoSONE, 10(5), e0126870. doi:10.1371/journal.pone.0126870
Dass-Brailsford, R, & Safilian, C. M. (2017). Integrated approaches to treating psychological trauma and substance abuse in women: An update. Trauma & Acute Care, 2(2), 41.
Daughters, S. B., Magidson, J. R., Lejuez, C. W., & Chen, Y. (2016). LETS ACT: A behavioral activation treatment for substance use and depression. Advances in Dual Diagnosis, 9(2-3), 74–84. doi:10.1108/ADD-02-2016-0006
Davidson, L., Bellamy, C., Guy, K., & Miller, R. (2012). Peer support among persons with severe mental illnesses: A review of evidence and experience. World Psychiatry, & 7(2), 123–128.
Davies, W. (2017). Understanding the pathophysiology of postpartum psychosis: Challenges and new approaches. World Journal of Psychiatry, 7(2), 77–88. doi:10.5498/wjp.v7.i2.77 28713685
Davis, H., & Attia, E. (2017). Pharmacotherapy of eating disorders. Current Opinion in Psychiatry 30(6), 452–457. doi:10.1097/YCO.0000000000000358 28806268
Dawson, D. A., Smith, S. M., Saha, T. D., Rubinsky, A. D., & Grant, B. F. (2012). Comparative performance of the AUDIT-C in screening for DSM-IV and DSM-5 alcohol use disorders. Drug and Alcohol Dependence, 126(3), 384–388. doi:10.1016/j.drugalcdep.2012.05.029 22728044
De Alwis, D., Lynskey, M. T., Reiersen, A. M., & Agrawal, A. (2014) . Attention-deficit/hyperactivity disorder subtypes and substance use and use disorders in NESARC. Addictive Behaviors, 39(8), 1278–1285. doi:10.1016/j.addbeh.2014.04.003 24821471
De Crescenzo, R., Cortese, S., Adamo, N., & Janiri, L. (2017). Pharmacological and non-pharmacological treatment of adults with ADHD: A meta-review. Evidence Based Mental Health, 20(1), 4–11. doi:10.1136/eb-2016-102415 27993933
De Hert, M., Cohen, D., Bobes, J., Cetkovich-Bakmas, M., Leucht, S., Ndetei, D. M., … Correli, C. U. (2011). Physical illness in patients with severe mental disorders. II. Barriers to care, monitoring and treatment guidelines, plus recommendations at the system and individual level. World Psychiatry, 10(2), 138–151.21633691
de Jonge, R., Roest, A. M., Lim, C. C., Florescu, S. E., Bromet, E. J., Stein, D. J., … Scott, K. M. (2016). Crossnational epidemiology of panic disorder and panic attacks in the world mental health surveys. Depression and Anxiety, 33(1 2), 1155–1177. doi:10.1002/da.22572 27775828
de la Sierra, L. R. (2002). Countertransference: Our difficulties in the treatment of substance abuse. In The psychodynamics of addiction (pp. 141–152). Philadelphia, PA: Whurr Publishers.
De Leon, G. (1996). Integrative recovery: A stage paradigm. Substance Abuse, 77(1), 51–63. doi:10.1080/08897079609444728
De Leon, G. (2000). Modified therapeutic community for homeless mentally ill chemical abusers: Treatment outcomes. American Journal of Drug and Alcohol Abuse 26(3), 461–480.10976669
De Leon, G. (2015). “The gold standard” and related considerations for a maturing science of substance abuse treatment. Therapeutic communities; a case in point. Substance Use and Misuse, 50(8-9), 1106–1109. doi:10.3109/10826084.2015.1012846 26361913
De Leon, G., Sacks, S., Staines, G., & McKendrick, K. (2000). Modified therapeutic community for homeless mentally ill chemical abusers: Treatment outcomes. American Journal of Drug and Alcohol Abuse, 26(3), 461–480.10976669
DeMarce, J. M., Lash, S. J., Stephens, R. S., Grambow, S. C., & Burden, J. L. (2008). Promoting continuing care adherence among substance abusers with co-occurring psychiatric disorders following residential treatment. Addictive Behaviors, 33(9), 1104–1112. doi:10.1016/j.addbeh.2008.02.008 18573617
Department of Veterans Affairs & Department of Defense. (2015) . VA/DoD clinical practice guideline for the management of substance use disorders. Version 3. 0. Retrieved from www.healthquality.va.gov/guidelines/MH/sud/VADODSUDCPGRevised22216.pdf
Department of Veterans Affairs & Department of Defense. (2017). VA/DoD clinical practice guideline for the management of posttraumatic stress disorder and acute stress disorder. Version 3.0. Retrieved from www.healthquality.va.gov/guidelines/MH/ptsd/VADoDPTSDCPGFinal012418.pdf
Detweiler, M. B., Pagadala, B., Candelario, J., Boyle, J. S., Detweiler, J. G., & Lutgens, B. W. (2016). Treatment of post-traumatic stress disorder nightmares at a Veterans Affairs medical center. Journal of Clinical Medicine, 5(12). pii: E117. doi:10.3390/jcm5120117
De Witte, N. A., Crunelle, C. L., Sabbe, B., Moggi, R, & Dom, G. (2014). Treatment for outpatients with comorbid schizophrenia and substance use disorders: A review. European Addiction Research, 20(3), 105–114. doi:10.1159/000355267 24192558
Diaz, N., Horton, E. G., & Weiner, M. (2012). Dysthymia, major depression, and double depression among individuals receiving substance abuse treatment. Health, 4(12), 1–9. doi:10.4236/health.2012.412181
Dickey, B., & Ware, N. C. (2008). Therapeutic communities and mental health system reform. Psychiatric Rehabilitation Journal, 32(2), 105–109. doi:10.2975/32.2.2008.105.109 18840564
DiClernente, C. C., Corno, C. M., Graydon, M. M., Wiprovnick, A. E., & Knoblach, D. J. (2017). Motivational interviewing, enhancement, and brief interventions over the last decade: A review of reviews of efficacy and effectiveness. Psychology of Addictive Behaviors, 37(8), 862–887. doi:10.1037/adb0000318
Dieterich, M., Irving, C. B., Bergman, H., Khokhar, M., Park, B., & Marshall, M. (2017). Intensive case management forsevere mental illness. Schizophrenia Bulletin, 43(4), 698–700. doi:10.1093/schbul/sbx061 28969355
Ding, K., Slate, M., & Yang, J. (2017). History of cooccurring disorders and current mental health status among homeless veterans. BMC Public Health, 18, 751.
Ding, K., Yang, J., Cheng, G., Schlitz, T., Summers, K. M., & Skinstad, A. H. (2011). Hospitalizations and hospital charges for co-occurring substance use and mental disorders. Journal of Substance Abuse Treatment, 40(4), 366–375. doi:10.1016/j.jsat.2010.12.005 21353443
Dixon, L. B., Holoshitz, Y, & Nossel, I. (2016). Treatment engagement of individuals experiencing mental illness: Review and update. World Psychiatry, 75(1), 13–20. doi:10.1002/wps.20306
Domenico, L. H., Lewis, B., Hazarika, M., & Nixon, S. J. (2018). Characterizing anxiety among individuals receiving treatment for alcohol and substance use disorders. Journal of the American Psychiatric Nurses Association, 24(4), 343–351. doi:10.1177/1078390317739106 29126358
Doucet, S., Jones, I., Letourneau, N., Dennis, C. L., & Blackmore, E. R. (2011). Interventions for the prevention and treatment of postpartum psychosis: A systematic review. Archives of Women's Mental Health, 74(2), 89–98. doi:10.1007/s00737-010-0199-6
Drainoni, M. L., Farrell, C., Sorensen-Alawad, A., Palmisano, J. N., Chaisson, C., & Walley, A. Y. (2014). Patient perspectives of an integrated program of medical care and substance use treatment. AIDS Patient Care and STDs, 28(2), 71–81. doi:10.1089/apc.2013.0179 24428768
Drake, R. E., Bond, G. R., Goldman, H. H., Hogan, M. R, & Karakus, M. (2016). Individual placement and support services boost employment for people with serious mental illnesses, but funding is lacking. Health Affairs (Millwood), 35(6), 1098–1105. doi:10.1377/hlthaff.2016.0001
Drake, R. E., Luciano, A. E., Mueser, K. T., Coveil, N. H., Essock, S. M., Xie, H., & McHugo, G. J. (2016). Longitudinal course of clients with co-occurring schizophrenia-spectrum and substance use disorders in urban mental health centers: A 7-year prospective study. Schizophrenia Bulletin, 42(1), 202–211. doi:10.1093/schbul/sbv110 26294706
Drymalski, W. M., & Campbell, T. C. (2009). A review of Motivational Interviewing to enhance adherence to antipsychotic medication in patients with schizophrenia: Evidence and recommendations. Journal of Mental Health, 78(1), 6–15. doi:10.1080/09638230802052161
Drymalski, W. M., & Nunley, M. R. (2016). The use of the Addiction Severity Index psychiatric composite scores to predict psychiatric inpatient admissions. Journal of Addictions Nursing, 27(3), 190–196. doi:10.1097/jan.0000000000000134 27580192
Drymalski, W. M., & Nunley, M. R. (2018). Sensitivity of the ASAM criteria to psychiatric need. International Journal of Mental Health and Addiction, 16(3), 617–629. doi:10.1007/s11469-017-9801-8
Duijkers, J. C., Vissers, C. T., & Egger, J. I. (2016). Unraveling executive functioning in dual diagnosis. Frontiers in Psychology, 7, 979.27445939
Dundon, W. D., Pettinati, H. M., Lynch, K. G., Xie, H., Varillo, K. M., Makadon, C. & Osiin, D. W. (2008). The therapeutic alliance in medical-based interventions impacts outcome in treating alcohol dependence. Drug and Alcohol Dependence, 95(3), 230–236. doi:10.1016/j.drugalcdep.2008.01.010 18329827
Dunne, E. M., Burrell, L. E., 2nd, Diggins, A. D., Whitehead, N. E., & Latimer, W. W. (2015). Increased risk for substance use and health-related problems among homeless veterans. American Journal of Addictions, 24(7), 676–680. doi:10.1111/ajad.12289
Dursa, E. K., Barth, S. K., Schneiderman, A. I., & Bossarte, R. M. (2016). Physical and mental health status of Gulf War and Gulf Era veterans: Results from a large population-based epidemiological study. Journal of Occupational and Environmental Medicine, 58(1), 41–46. doi:10.1097/jom.0000000000000627 26716848
Dye, M. H., Roman, P. M., Knudsen, H. K., & Johnson, J. A. (2012). The availability of integrated care in a national sample of therapeutic communities. Journal of Behavioral Health Services & Research, 39(1), 17–27. doi:10.1007/s11414-011-9251-1 21744180
Dykstra, R. E., Schumacher, J. A., Mota, N., & Coffey, S. F. (2015). Examining the role of antisocial personality disorder in intimate partner violence among substance use disorder treatment seekers with clinically significant trauma histories. Violence Against Women, 27(8), 958–974. doi:10.1177/1077801215589377
Eby, L. T., Burk, H., & Maher, C. P. (2010). How serious of a problem is staff turnover in substance abuse treatment? A longitudinal study of actual turnover. Journal of Substance Abuse Treatment, 39(3), 264–271. doi:10.1016/j.jsat.2010.06.009 20675097
Eby, L. T., Laschober, T. C., & Curtis, S. L. (2014). Substance abuse-specific knowledge transfer or loss? Treatment program turnover versus professional turnover among substance abuse clinicians. Journal of Addictive Diseases, 33(3), 243–252. doi:10.1080/10550887.2014.950022 25115318
Edwards, R. (2006). The role and competencies of staff in the treatment of coexisting problems of mental health and substance misuse. In R. G. Hussein (Ed.), Dual diagnosis nursing (pp. 285–295). Hoboken, NJ: Blackwell Publishing.
Egan, T. E., Dawson, A. E., & Wyrnbs, B. T. (2017). Substance use in undergraduate students with histories of attention-deficit/hyperactivity disorder (ADHD): The role of impulsivity. Substance Use and Misuse, 52(10), 1375–1386. doi:10.1080/10826084.2017.1281309 28406351
Ellenhorn, R. (2015). Assertive community treatment: A “living-systems” alternative to hospital and residential care. Psychiatric Annals, 45(3), 120–125. do i: 10.3928/00485713-20150304-06
Elmquist, J., Shorey, R. C., Anderson, S., & Stuart, G. L. (2015). Eating disorder symptoms and length of stay in residential treatment for substance use: A brief report. Journal of Dual Diagnosis, 11(3-4), 233–237. doi:10.1080/15504263.2015.1104480 26457661
Epstein, A. J., Barry, C. L., Fiellin, D. A., & Busch, S. H. (2015). Consumers’ valuation of primary care-based treatment options for mental and substance use disorders. Psychiatric Services, 66(8), 772–774. doi:10.1176/appi.ps.201500077 25930049
Evans, E., Padwa, H., Li, L., Lin, V., & Hser, Y. I. (2015). Heterogeneity of mental health service utilization and high mental health service use among women eight years after initiating substance use disorder treatment. Journal of Substance Abuse Treatment, 59, 10–19. doi:10.1016/j.jsat.2015.06.021 26321439
Ewing, G., Austin, L., Diffin, J., & Grande, G. (2015). Developing a person-centred approach to career assessment and support. British Journal of Community Nursing, 20(12), 580–584. doi:10.12968/bjcn.2015.20.12.580 26636891
Farren, C. K., Hill, K. R., & Weiss, R. D. (2012). Bipolar disorder and alcohol use disorder: A review. Current Psychiatry Reports, 14(6), 659–666. doi:10.1007/s11920-012-0320-9 22983943
Fazel, S., Yoon, I. A., & Hayes, A. J. (2017). Substance use disorders in prisoners: An updated systematic review and meta-regression analysis in recently incarcerated men and women. Addiction, 172(1 0), 1725–1739. doi:10.1111/add.13877
Fearn, N. E., Vaughn, M. G., Nelson, E. J., Salas-Wright, C. P., DeLisi, M., & Qian, Z. (2016). Trends and correlates of substance use disorders among probationers and parolees in the United States 2002-2014. Drug and Alcohol Dependence, 167, 128–139. doi:10.1016/j.drugalcdep.2016.08.003 27515722
Fisher, W. H., Geller, J. L, & Pandiani, J. A. (2009). The changing role of the state psychiatric hospital. Health Affairs, 28(3), 676–684. doi:10.1377/hlthaff.28.3.676 19414875
Flanagan, J. C., Korte, K. J., Killeen, T. K., & Back, S. E. (2016). Concurrent treatment of substance use and PTSD. Current Psychiatry Reports, 18(8). doi:10.1007/s11920-016-0709-y
Food and Drug Administration (FDA). (March 2007). Strattera. Patient information, www.accessdata.fda.gov/drugsatfda_docs/label/2007/021411s004s012s013s015s021_bl.pdf
Food and Drug Administration. (2010). Kapvay. Prescribing information, www.accessdata.fda.gov/drugsatfda_docs/label/2010/022331s001s002lbl.pdf
Food and Drug Administration. (2013). Intuniv. Prescribing information, www.accessdata.fda.gov/drugsatfda_docs/label/2013/022037s009lbl.pdf
Food and Drug Administration. (April 28, 2017). Depression: PDA-approved medications may help. Consumer updates. Retrieved from www.fda.gov/forconsumers/consumerupdates/ucm095980.htm
Food and Drug Administration. (March 5, 2019). FDA approves new nasal spray medication for treatment-resistant depression; available only at a certified doctor's office or clinic. Retrieved from www.fda.gov/NewsEvents/Newsroom/PressAnnouncements/ucm632761.htm
Ford, J. A., & Perna, D. (2015). Prescription drug misuse and suicidal ideation: Findings from the National Survey on Drug Use and Health. Drug and Alcohol Dependence, 157, 192–196. doi:10.1016/j.drugalcdep.2015.10.010 26520564
Fouladi, F., Mitchell, J. E., Crosby, R. D., Engel, S. G., Crow, S., Hill, L, … Steffen, K. J. (2015). Prevalence of alcohol and other substance use in patients with eating disorders. European Eating Disorders Review, 23(6), 531–536. doi:10.1002/erv.2410 26415622
Fountoulakis, K. N., Grunze, H., Vieta, E., Young, A., Yatham, L., Blier, P., … Moeller, H. J. (2017). The International College of Neuro-Psychopharmacology (CINP) treatment guidelines for bipolar disorder in adults (CINP-BD-2017), Part 3: The clinical guidelines. International Journal of Neuropsychopharmacology, 20(2), 180–195. doi:10.1093/ijnp/pyw109 27941079
Fowler, K. A., Jack, S. P. D., Lyons, B. H., Betz, C. J., & Petrosky, E. (2018). Surveillance for violent deaths— National Violent Death Reporting System, 18 states, 2014. MMWR Surveillance Summaries, 67(2), 1–36. doi:10.15585/mmwr.ss6702a1
Franko, D. L., Keshaviah, A., Eddy, K. T., Krishna, M., Davis, M. C., Keel, P. K., & Herzog, D. B. (2013). A longitudinal investigation of mortality in anorexia nervosa and bulimia nervosa. American Journal of Psychiatry, 170(8), 917–925. do i: 10.1176/appi.ajp.2013.1207086823771148
Fries, H. P, & Rosen, M. I. (2011). The efficacy of assertive community treatment to treat substance use. Journal of the American Psychiatric Nurses Association, 17(1), 45–50. doi:10.1177/1078390310393509 21532920
Frisman, L. K., Mueser, K. T., Coveil, N. H., Lin, H. J., Crocker, A., Drake, R. E., & Essock, S. M. (2009). Use of integrated dual disorder treatment via assertive community treatment versus clinical case management for persons with co-occurring disorders and antisocial personality disorder. Journal of Nervous and Mental Disease, 797(11), 822–828. doi:10.1097/NMD.0b013e3181beac52
Frounfelker, R. L., Wilkniss, S. M., Bond, G. R., Deviti, T. S., & Drake, R. E. (2011). Enrollment in supported employment services for clients with a co-occurring disorder. Psychiatric Services, 62(5), 545–547. doi:10.1176/ps.62.5.pss6205_0545 21532083
Fruzzetti, A. E. (October 03, 2017). Why borderline personality disorder is misdiagnosed. Retrieved from www.nami.org/Blogs/NAMI-Blog/October-2Q17/Why-Borderline-Personalitv-Disorder-is-Misdiagnose
Fulton, J. J., Calhoun, P. S., Wagner, H. R., Schry, A. R., Hair, L. R., Feeling, N., … Beckham, J. C. (2015). The prevalence of posttraumatic stress disorder in Operation Enduring Freedom/Operation Iraqi Freedom (OEF/OIF) veterans: A meta-analysis. Journal of Anxiety Disorders, 31, 98–107. doi:10.1016/j.janxdis.2015.02.003 25768399
Gadermann, A. M., Alonso, J., Vilagut, G., Zaslavsky, A. M., & Kessler, R. C. (2012). Comorbidity and disease burden in the National Comorbidity Survey Replication (NCS-R). Depression and Anxiety, 29(9), 797–806. doi:10.1002/da.21924 22585578
Gainsbury, S. M. (2017). Cultural competence in the treatment of addictions: Theory, practice and evidence. Clinical Psychology & Psychotherapy, 24(4), 987–1001. doi:10.1002/cpp.2062 27976434
Galán, C. A., & Humphreys, K. L. (Aug 2, 2017). ADHD and substance use: Current evidence and treatment considerations. Psychiatric Times, 34(8), 1–3.
Garcia, S., Martinez-Cengotitabengoa, M., Lopez-Zurbano, S., Zorrilla, I., Lopez, R., Vieta, E., & Gonzalez-Pinto, A. (2016) . Adherence to antipsychotic medication in bipolar disorder and schizophrenic patients: A systematic review. Journal of Clinical Psychopharmacology, 36(4), 355–371. doi:10.1097/jcp.0000000000000523 27307187
Garner, B. R., & Hunter, B. D. (2014). Predictors of staff turnover and turnover intentions within addiction treatment settings: Change over time matters. Substance Abuse, 8, 63–71. doi:10.4137/SART.S17133 25336960
GBD 2016 Disease and Injury Incidence and Prevalence Collaborators. (2017). Global, regional, and national incidence, prevalence, and years lived with disability for 328 diseases and injuries for 195 countries, 1990-2016: A systematic analysis for the Global Burden of Disease Study 2016. Lancet, 390(10100), 1211–1259. doi:10.1016/s0140-6736(17)32154-2 28919117
Gentile, S. (2017). Untreated depression during pregnancy: Short-and long-term effects in offspring. A systematic review. Neuroscience, 342, 154–166. doi:10.1016/j.neuroscience.2015.09.001 26343292
Ghafoori, B., Barragan, B., & Palinkas, L. (2014). Mental health service use among trauma-exposed adults: A mixed-methods study. Journal of Nervous and Mental Disease, 202(3), 239–246. doi:10.1097/nmd.0000000000000108 24566510
Gibbon, S., Duggan, C., Stoffers, J., Huband, N., Vollm, A., Ferriter, M., & Lieb, K. (2010). Psychological interventions for antisocial personality disorder. Cochrane Database of Systematic Reviews, 6, CD007668. doi:10.1002/14651858.CD007668.pub2
Gilmer, T. R., Manning, W. G., & Ettner, S. L. (2009). A cost analysis of San Diego County's REACH program for homeless persons. Psychiatric Services, 60(4), 445–450. doi:10.1176/appi.ps.60.4.445 19339318
Gilmore, A. K., Brignone, E., Painter, J. M., Lehavot, K., Fargo, J., Suo, Y, … Gundlapalli, A. V. (2016). Military sexual trauma and co-occurring posttraumatic stress disorder, depressive disorders, and substance use disorders among returning Afghanistan and Iraq veterans. Women's Health Issues, 26(5), 546–554. doi:10.1016/j.whi.2016.07.001 27528358
Glenn, A. L., Johnson, A. K., & Raine, A. (2013). Antisocial personality disorder: A current review. Current Psychiatry Reports, 75(12), 427. doi:10.1007/s11920-013-0427-7
Gold, A. K., Otto, M. W., Deckersbach, T., Sylvia, L. G., Nierenberg, A. A., & Kinrys, G. (2018). Substance use comorbidity in bipolar disorder: A qualitative review of treatment strategies and outcomes. American Journal of Addictions, 27(3), 188–201. doi:10.1111/ajad.12713
Gold, L. H. (2014). DSM-5 and the assessment of functioning: The World Health Organization disability assessment schedule 2.0 (WHODAS 2.0). Journal of the American Academy of Psychiatry and the Law, 42(2), 173–181.24986344
Goldstein, R. B., Smith, S. M., Chou, S. R., Saha, T. D., Jung, J., Zhang, H., … Grant, B. F. (2016). The epidemiology of DSM-5 posttraumatic stress disorder in the United States: Results from the National Epidemiologic Survey on Alcohol and Related Conditions-lll. Social Psychiatry and Psychiatric Epidemiology, 51(8), 1137–1148. doi:10.1007/s00127-016-1208-5 27106853
Goodman, D. J., Milliken, C. U., Theiler, R. N., Nordstrom, R., & Åkerman, S. C. (2015). A multidisciplinary approach to the treatment of co-occurring opioid use disorder and posttraumatic stress disorder in pregnancy: A case report. Journal of Dual Diagnosis, 17(3-4), 248–257. doi:10.1080/15504263.2015.1104484
Goodrich, D. E., Kilbourne, A. M., Nord, K. M., & Bauer, M. S. (2013). Mental health collaborative care and its role in primary care settings. Current Psychiatry Reports, 75(8), 383. doi:10.1007/s11920-013-0383-2
Goodwin, R. D., & Stein, D. J. (2013). Anxiety disorders and drug dependence: Evidence on sequence and specificity among adults. Psychiatry and Clinical Neurosciences, 67(3), 167–173. doi:10.1111/pcn.12030 23581868
Grant, B. R., Chou, S. R., Goldstein, R. B., Huang, B., Stinson, S., Saha, T. D., … Ruan, W. J. (2008). Prevalence, correlates, disability, and comorbidity of DSM-IV borderline personality disorder: Results from the Wave 2 National Epidemiologic Survey on Alcohol and Related Conditions. Journal of Clinical Psychiatry, 69(4), 533–545. doi:ej07m0391618426259
Grant, B. R., Goldstein, R. B., Saha, T. D., Chou, S. R., Jung, J., Zhang, H., … Häsin, D. S. (2015). Epidemiology of DSM-5 alcohol use disorder: Results from the National Epidemiologic Survey on Alcohol and Related Conditions III. JAMA Psychiatry, 72(8), 757–766. doi:10.1001/jamapsychiatry.2015.0584 26039070
Grant, B. R., Häsin, D. S., Stinson, F. S., Dawson, D. A., Chou, S. R., Ruan, W. J., & Pickering, R. P. (2004). Prevalence, correlates, and disability of personality disorders in the United States: Results from the National Epidemiologic Survey on Alcohol and Related Conditions. Journal of Clinical Psychiatry, 65(7), 948–958.15291684
Grant, B. R., Saha, T. D., Ruan, W. J., Goldstein, R. B., Chou, S. P., Jung, J., … Häsin, D. S. (2016). Epidemiology of DSM-5 drug use disorder: Results from the National Epidemiologic Survey on Alcohol and Related Conditions-lll. JAMA Psychiatry, 73(1), 39^17. doi:10.1001/jamapsychiatry.2015.2132 26580136
Grattan, A., Sullivan, M. D., Saunders, K. W., Campbell, C. I., & Von Korff, M. R. (2012). Depression and prescription opioid misuse among chronic opioid therapy recipients with no history of substance abuse. Annals of Family Medicine, 70(4), 304–311. doi:10.1370/afm.1371
Green, C. A., Yarborough, M. T., Polen, M. R., Janoff, S. L., & Yarborough, B. J. (2015). Dual recovery among people with serious mental illnesses and substance problems: A qualitative analysis. Journal of Dual Diagnosis, 11(1), 33^11. doi:10.1080/15504263.2014.975004 25491440
Green, K. L., Brown, G. K., Jager-Hyman, S., Cha, J., Steer, R. A., & Beck, A. T. (2015). The predictive validity of the Beck Depression Inventory suicide item. Journal of Clinical Psychiatry, 76(1 2), 1683–1686. doi:10.4088/JCP.14m09391 26717528
Gregorowski, C., Seedat, S., & Jordaan, G. P. (2013). A clinical approach to the assessment and management of co-morbid eating disorders and substance use disorders. BMC Psychiatry, 13, 289. doi:10.1186/1471-244x-13-289 24200300
Greila, C. E. (2008). From generic to gender-responsive treatment: Changes in social policies, treatment services, and outcomes of women in substance abuse treatment. Journal of Psychoactive Drugs, 40(Suppl. 5), 327–343.
Greila, C. E., & Shi, Y. (2011). Stability of outcomes following residential drug treatment for patients with co-occurring disorders. Journal of Dual Diagnosis, 7(1-2), 103–112. doi:10.1080/15504263.2011.566067 21804769
Grewal, R. S., & George, T. P. (July 14, 2017). Cannabis-induced psychosis: A review. Psychiatric Times, 34(7), 1–5.
Group, W. A. W. (2002). The Alcohol, Smoking and Substance Involvement Screening Test (ASSIST): Development, reliability and feasibility. Addiction, 97(9), 1183–1194.12199834
Guerrero, E., & Andrews, C. M. (2011). Cultural competence in outpatient substance abuse treatment: Measurement and relationship to wait time and retention. Drug and Alcohol Dependence, 119(1-2), e13–e22. doi:10.1016/j.drugalcdep.2011.05.020 21680111
Guerrero, E. G. (2013). Enhancing access and retention in substance abuse treatment: The role of Medicaid payment acceptance and cultural competence. Drug and Alcohol Dependence, 132(3), 555–561. doi:10.1016/j.drugalcdep.2013.04.005 23669458
Guerrero, E. G., Padwa, H., Lengnick-Hall, R., Kong, Y., & Perrigo, J. L. (2015). Leadership and licensure for drug treatment and the implementation of co-occurring disorder treatment in community mental health centers. Community Mental Health Journal, 57(5), 554–566. doi:10.1007/s10597-015-9886-0
Guille, C., Newman, R., Fryml, L. D., Llfton, C. K., & Epperson, C. N. (2013). Management of postpartum depression. Journal of Midwifery & Women's Health, 58(6), 643–653. doi:10.1111/jmwh.12104
Habel, L. A., Cooper, W. O., Sox, C. M., Chan, K. A., Fireman, B. H., Arbogast, P. G., … Selby, J. V. (2011). ADHD medications and risk of serious cardiovascular events in young and middle-aged adults. JAMA, 306(24), 2673–2683. doi:10.1001/jama.2011.1830 22161946
Hagler, K. J., Rice, S. L., Munoz, R. E., Salvador, J. G., Forcehimes, A. A., & Bogenschutz, M. P. (2015). “It Might Actually Work This Time”: Benefits and barriers to adapted 12-step facilitation therapy and mutual-help group attendance from the perspective of dually diagnosed individuals. Journal of Addictions Nursing, 26(3), 120–128. doi:10.1097/jan.0000000000000083 26340570
Haller, M., Colvonen, P. J., Davis, B. C., Trim, R. S., Bogner, R., Sevcik, J., & Norman, S. B. (2016). Examining pretreatment differences between veterans in residential versus outpatient treatment for alcohol use disorder and comorbid combat-related PTSD. Journal of Dual Diagnosis, 72(3-4), 282–289. doi:10.1080/15504263.2016.1256516
Haller, M., Norman, S. B., Cummins, K., Trim, R. S., Xu, X., Cui, R., … Tate, S. R. (2016). Integrated cognitive behavioral therapy versus cognitive processing therapy for adults with depression, substance use disorder, and trauma. Journal of Substance Abuse Treatment, 62, 38–48. doi:10.1016/j.jsat.2015.11.005 26718130
Halloran, L. (2013). Substance abuse in primary care. Journal for Nurse Practitioners, 9(7), 475–476.
Hamdi, N. R., & Iacono, W. G. (2014). Lifetime prevalence and co-morbidity of externalizing disorders and depression in prospective assessment. Psychological Medicine, 44(2), 315–324. doi:10.1017/S0033291713000627 23590946
Han, B., Compton, W. M., Blanco, C., & Colpe, L. J. (2017). Prevalence, treatment, and unmet treatment needs of US adults with mental health and substance use disorders. Health Affairs (Millwood), 36(1 0), 1739–1747.
Han, B., Olfson, M., & Mojtabai, R. (2017). Depression care among adults with co-occurring major depressive episodes and substance use disorders in the United States. Journal of Psychiatric Research, 97, 47–56. doi:10.1016/j.jpsychires.2017.02.026 29175297
Harrison, J., Cousins, L., Spybrook, J., & Curtis, A. (2017). Peers and co-occurring research-supported interventions. Journal of Evidence-Informed Social Work, 74(3), 201–215. doi:10.1080/23761407.2017.1316220
Harrison, M. L., Moore, K. A., Young, S., Flink, D., & Ochshorn, E. (2008). Implementing the comprehensive, continuous, integrated system of care model for individuals with co-occurring disorders: Preliminary findings from a residential facility serving homeless individuals. Journal of Dual Diagnosis, 4(3), 238–259.
Harrold, S. A., Libet, J., Pope, C., Lauerer, J. A., Johnson, E., & Edlund, B. J. (2018). Increasing physical activity for veterans in the Mental Health Intensive Case Management Program: A community-based intervention. Perspectives in Psychiatric Care, 54(2), 266–273. doi:10.1111/ppc.12233 28762507
Harrop, E. N., & Marlatt, G. A. (2010). The comorbidity of substance use disorders and eating disorders in women: Prevalence, etiology, and treatment. Addictive Behaviors, 35(5), 392–398. doi:10.1016/j.addbeh.2009.12.016 20074863
Hartz, S. M., Pato, C. N., Medeiros, H., Cavazos-Rehg, P., Sobell, J. L., Knowles, J. A., … Pato, M. T. (2014). Comorbidity of severe psychotic disorders with measures of substance use. JAMA Psychiatry, 77(3), 248–254. doi:10.1001/jamapsychiatry.2013.3726
Harvard Medical School. (2005). National Comorbidity Survey (NCS). Retrieved from https://www.hcp.med.harvard.edu/ncs/
Häsin, D., Fenton, M. C., Skodol, A., Krueger, R., Keyes, K., Geier, T., … Grant, B. (2011). Personality disorders and the 3-year course of alcohol, drug, and nicotine use disorders. Archives of General Psychiatry, 68(11), 1158–1167. doi:10.1001/archgenpsychiatry.2011.78 22065531
Häsin, D., & Kilcoyne, B. (2012). Comorbidity of psychiatric and substance use disorders in the United States: Current issues and findings from the NESARC. Current Opinion in Psychiatry, 25(3), 165–171. doi:10.1097/YCO.ObOl3e3283523dcc 22449770
Häsin, D. S., & Grant, B. F. (2015). The National Epidemiologic Survey on Alcohol and Related Conditions (NESARC) Waves 1 and 2: Review and summary of findings. Social Psychiatry and Psychiatric Epidemiology, 50(11), 1609–1640. doi:10.1007/s00127-015-1088-0 26210739
Häsin, D. S., Kerridge, B. T., Saha, T. D., Huang, B., Pickering, R., Smith, S. M., … Grant, B. F. (2016). Prevalence and correlates of DSM-5 cannabis use disorder, 2012-2013: Findings from the National Epidemiologic Survey on Alcohol and Related Conditions-III. American Journal of Psychiatry, 773(6), 588–599. doi:10.1176/appi.ajp.2015.15070907
Häsin, D. S., O'Brien, C. R., Auriacombe, M., Borges, G., Bucholz, K., Budney, A., … Grant, B. F. (2013). DSM-5 criteria for substance use disorders: Recommendations and rationale. American Journal of Psychiatry, 170(8), 834–851. doi:10.1176/appi.ajp.2013.12060782 23903334
Häsin, D. S., Sarvet, A. L., Meyers, J. L., Saha, T. D., Ruan, W. J., Stohl, M., & Grant, B. F. (2018). Epidemiology of Adult DSM-5 major depressive disorder and its specifiers in the United States. JAMA Psychiatry, 75(4), 336–346. doi:10.1001/jamapsychiatry.2017.4602 29450462
Haug, N. A., Duffy, M., & McCaul, M. E. (2014). Substance abuse treatment services for pregnant women: Psychosocial and behavioral approaches. Obstetrics and Gynecology Clinics of North America, 41(2), 267–296. doi:10.1016/j.ogc.2014.03.001 24845490
Havassy, B. E., & Mericle, A. A. (2013). Recent violence among persons entering short-term residential mental health and substance abuse treatment. Journal of Dual Diagnosis, 9(3). doi:10.1080/15504263.2013.804773
Haviland, M. G., Banta, J. E., Sonne, J. L., & Przekop, P. (2016). Posttraumatic stress disorder-related hospitalizations in the United States (2002-2011): Rates, co-occurring illnesses, suicidal ideation/self-harm, and hospital charges. Journal of Nervous and Mental Disease, 204(2), 78–86. doi:10.1097/NMD.0000000000000432 26588079
Hawk, K., & D'Onofrio, G. (2018). Emergency department screening and interventions for substance use disorders. Addiction Science & Clinical Practice, 73(1), 18. doi:10.1186/s13722-018-0117-1
Healey, P., Stager, M. L., Woodmass, K., Dettlaff, A. J., Vergara, A., Janke, R., & Wells, S. J. (2017). Cultural adaptations to augment health and mental health services: A systematic review. BMC Health Services Research, 77(1), 8. doi:10.1186/s12913-016-1953-x
Health Resources and Services Administration (HRSA). (2018). Behavioral health workforce projections, 2016-2030: Addiction counselors. Retrieved from https://bhw.hrsa.aov/sites/default/files/bhw/nchwa/projections/addiction-counselors-2018-pdf
Health Resources and Services Administration. (2020, March 1). Shortage areas. Retrieved from https://data.hrsa.gov/topics/health-workforce/shortage-areas
Heffner, J. L., Blom, T. J., & Anthenelli, R. M. (2011). Gender differences in trauma history and symptoms as predictors of relapse to alcohol and drug use. American Journal of Addictions, 20(4), 307–311. doi:10.1111/j.1521-0391.2011.00141.x
Heimberg, R. G., Hofmann, S. G., Liebowitz, M. R., Schneier, R., Smits, J. A. J., Stein, M. B., … Craske, M. G. (2014). Social anxiety disorder in DSM-5. Depression and Anxiety, 31(6), 472–479. doi:10.1002/da.22231 24395386
Hendershot, C. S., Witkiewitz, K., George, W. H., & Marlatt, A. (2011). Relapse prevention for addictive behaviors. Substance Abuse Treatment, Prevention, and Policy, 6, 17. doi:10.1186/1747-597x6-17 21771314
Henry, M., Shivji, A., de Sousa, T., and Cohen, R. (2015). The 2015 Annual Homeless Assessment Report (AHAR) to Congress. Part 1 - Point in time estimates of homelessness. Retrieved from https://files.hudexchange.info/resources/documents/2015-AHAR-Part-1.pdf
Henry, M., Watt, R., Rosenthal, L., & Shivji, A. (2016, November). The 2016 Annual Homeless Assessment Report (AHAR) to Congress. Part 1: Point-in-time estimates of homelessness. Retrieved from https://files,hudexchange.info/resources/documents/2016-AHAR-Part-1.pdf
Henry, M., Watt, R., Mahathey, A., Ouellette, J., Sitler, A, & Abt Associates. (2020, January). The 2019 Annual Homeless Assessment Report (AHAR) to Congress. Part 1: Point-in-time estimates of homelessness. Retrieved from https://files.hudexchange.info/resources/documents/2019-AHAR-Part-1.pdf
Hermes, E., & Rosenheck, R. (2016). Psychopharmacologic services for homeless veterans: Comparing psychotropic prescription fills among homeless and non-homeless veterans with serious mental illness. Community Mental Health Journal, 52(2), 142–147. doi:10.1007/s10597-015-9904-2 26202545
Heslin, K. C., Elixhauser, A., & Steiner, C. A. (2015, June). Hospitalizations involving mental and substance use disorders among adults, 2012. HCUP Statistical Brief #191. Agency for Healthcare Research and Quality, Rockville, MD. Retrieved from www.hcup-us.ahrq.gov/reports/statbriefs/sb191-Hospitalization-Mental-Substance-Use-Disorders-2012.pdf
Hien, D. A., Jiang, H., Campbell, A. N. C., Hu, M.-C., Miele, M., Cohen, L. R., … Nunes, E. V. (2010). Do treatment improvements in PTSD severity affect substance use outcomes? A secondary analysis from a randomized clinical trial in NIDA's Clinical Trials Network. American Journal of Psychiatry, 167(1), 95–101. doi:10.1176/appi.ajp.2009.09091261 19917596
Hjorthoj, C. R., Hjorthoj, A. R., & Nordentoft, M. (2012). Validity of Timeline Follow-Back for self-reported use of cannabis and other illicit substances—Systematic review and meta-analysis. Addictive Behaviors, 37(3), 225–233. doi:10.1016/j.addbeh.2011.11.025 22143002
Hogan, M. R, & Grumet, J. G. (2016). Suicide prevention: An emerging priority for health care. Health Affairs, 35(6), 1084–1090. doi:10.1377/hlthaff.2015.1672 27269026
Holden, K., McGregor, B., Thandi, P., Fresh, E., Sheats, K., Belton, A., … Satcher, D. (2014). Toward culturally centered integrative care for addressing mental health disparities among ethnic minorities. Psychological Services, 77(4), 357–368. doi:10.1037/a0038122
Horsfall, J., Cleary, M., Hunt, G. E., & Walter, G. (2009). Psychosocial treatments for people with co-occurring severe mental illnesses and substance use disorders (dual diagnosis): A review of empirical evidence. Harvard Review of Psychiatry, 77(1), 24–34. doi:10.1080/10673220902724599
Hudson, J. I., Hiripi, E., Pope, H. G., Jr., & Kessler, R. C. (2007). The prevalence and correlates of eating disorders in the National Comorbidity Survey Replication. Biological Psychiatry, 61(3), 348–358. dol:10.1016/j.bio psych.2006.03.04016815322
Huggard, P., Law, J., & Newcombe, D. (2017). A systematic review exploring the presence of vicarious trauma, compassion fatigue, and secondary traumatic stress In alcohol and other drug clinicians. Australasian Journal of Disaster and Trauma Studies, 21 (2), 65–72.
Hunt, E., Peters, R. H., & Kremllng, J. (2015). Behavioral health treatment history among persons In the justice system: Findings from the Arrestee Drug Abuse Monitoring II Program. Psychiatric Rehabilitation Journal, 38(1), 7–15. doi:10.1037/prj0000132 25799302
Hunt, G. E., Malhi, G. S., Cleary, M., Lal, H. M. X., & Sitharthan, T. (2016a). Comorbidity of bipolar and substance use disorders in national surveys of general populations, 1990-2015: Systematic review and metaanalysis. Journal of Affective Disorders, 206, 321–330. doi:10.1016/j.jad.2016.06.051 27426694
Hunt, G. E., Malhi, G. S., Cleary, M., Lal, H. M. X., & Sitharthan, T. (2016b). Prevalence of comorbld bipolar and substance use disorders in clinical settings, 1990-2015: Systematic review and meta-analysis. Journal of Affective Disorders, 206, 331–349. dol:10.1016/j.jad.2016.07.01127476137
Hunt, G. E., Siegfried, N., Morley, K., Sitharthan, T., & Cleary, M. (2013). Psychosocial interventions for people with both severe mental illness and substance misuse. Cochrane Database of Systematic Reviews, 10, CD001088. doi:10.1002/14651858.CD001088.pub3
Hunt, G. E., Siegfried, N., Morley, K., Sitharthan, T., & Cleary, M. (2014). Psychosocial interventions for people with both severe mental illness and substance misuse. Schizophrenia Bulletin, 40(1), 18–20.24179148
Hunt, T. K., & Forbush, K. T. (2016). Is “drunkorexia” an eating disorder, substance use disorder, or both? Eating Behaviors, 22, 40–45. doi:10.1016/j.eatbeh.2016.03.034 27085168
Hunter, S. B., Schwartz, R. R, & Friedmann, P. D. (2016). Introduction to the Special Issue on the Studies on the Implementation of Integrated Models of Alcohol, Tobacco, and/or Drug Use Interventions and Medical Care. Journal of Substance Abuse Treatment, 60, 1–5. doi:10.1016/j.jsat.2015.10.001 26549295
Ilgen, M. A., Bohnert, A. S., Ignacio, R. V., McCarthy, J. R., Valenstein, M. M., Kim, H. M. & Blow, F. C. (2010). Psychiatric diagnoses and risk of suicide in veterans. Archives of General Psychiatry, 67(11), 1152–1158. doi:10.1001/archgenpsychiatry.2010.129 21041616
Jaffe, D. J. (2017). What is “serious mental illness” and what is not? Retrieved from https://mentalillnesspolicy.org/serious-mental-illness-not/
Jahn, D. R., Muralidharan, A., Drapalski, A. L., Brown, C. H., Fang, L. J., & Lucksted, A. (2018). Differences in suicide and death ideation among veterans and nonveterans with serious mental illness. Psychological Services, 15(1), 31–39. doi:10.1037/ser0000127 28287770
Johnson, J. A., Lee, A., Vinson, D., & Seale, J. P. (2013). Use of AUDIT-based measures to identify unhealthy alcohol use and alcohol dependence in primary care: A validation study. Alcoholism: Clinical and Experimental Research, 37(Suppl. 1), e253–e259. doi:10.1111/j.1530-0277.2012.01898.x 22834916
Jones, C. M., & McCance-Katz, E. F. (2019). Co-occurring substance use and mental disorders among adults with opioid use disorder. Drug and Alcohol Dependence, 197, 78–82. doi:10.1016/j.drugalcdep.2018.12.030 30784952
Jones, D., & Arndt, S. (2017, October). The Iowa Pregnant and Postpartum Women's Residential Treatment Program: Annual report. Retrieved from https://idph.iowa.gov/Portals/1/userfiles/148/PPW%20Year%202°/c20EvaLpdf
Jones, L., Chandra, P. S., Dazzan, R, & Howard, L. M. (2014). Bipolar disorder, affective psychosis, and schizophrenia in pregnancy and the post-partum period. Lancet, 384(9956), 1789–1799. doi:10.1016/s0140-6736(14)61278-2 25455249
Jones, L, & Shakespeare, J. (2014). Postnatal depression. BMJ, 349, g4500. doi:10.1136/bmj.g4500 25125284
Jones, Q., Johnston, B., Biola, H., Gomez, S., & Crowder, C. (2018). Implementing standardized substance use disorder screening in primary care. Journal of the American Academy of Physician Assistants, 31(10), 42–45. doi:10.1097/01Jaa.0000511792.75301.73
Joseph, R., Kester, R., O'Brien, C., & Huang, H. (2017). The evolving practice of psychiatry in the era of integrated care. Psychosomatics, 58(5), 466–473. doi:10.1016/j.psym.2017.04.003 28606419
Joyce, T. R, & Bailey, B. (2015). Supporting recovery in acute care and emergency settings [PowerPoint slides]. Retrieved from www.samhsa.aov/sites/default/files/programs_campaigns/recoverv_to_practice/supporting-recovery-in-acute-care-emergency-settings.pdf
Kaiser Family Foundation. (2017). Uninsured rates for the nonelderly by race/ethnicity. Retrieved from www.kff.org/uninsured/state-indicator/rate-by-raceethnicity/?currentTimeframe=0&sortModel=%7B%22colld%22:%22Location%22%22sort%22:%22asc%22%7D
Kaiser Permanente. (2019). Alcohol use in older adults. Retrieved from https://wa.kaiserpermanente.org/healthAndWellness/index-jhtml?item=%2Fcommon%2FhealthAndWellness%2FhealthyLiving%2Flifestyle%2Falcoh ol-seniors.html
Kanbur, N., & Harrison, A. (2016). Co-occurrence of substance use and eating disorders: An approach to the adolescent patient in the context of family centered care. A literature review. Substance Use and Misuse, 51(7), 853–860. doi:10.3109/10826084.2016.1155614 27096462
Kang, H. K., Bullman, T. A., Smolenski, D. J., Skopp, N. A., Gahm, G. A., & Reger, M. A. (2015). Suicide risk among 1.3 million veterans who were on active duty during the Iraq and Afghanistan wars. Annals of Epidemiology, 25(2), 96–100. doi:10.1016/j.annepidem.2014.11.020 25533155
Kantor, V., Knefel, M., & Lueger-Schuster, B. (2017). Perceived barriers and facilitators of mental health service utilization in adult trauma survivors: A systematic review. Clinical Psychology Review, 52, 52–68. doi:10.1016/j.cpr.2016.12.001 28013081
Katzman, M. A., Bilkey, T. S., Chokka, P. R., Fallu, A., & Klassen, L. J. (2017). Adult ADHD and comorbid disorders: Clinical implications of a dimensional approach. BMC Psychiatry, 77(1), 302. doi:10.1186/s12888-017-1463-3
Keeley, R. D., Brody, D. S., Engel, M., Burke, B. L., Nordstrom, K., Moralez, E., … Emsermann, C. (2016). Motivational interviewing improves depression outcome in primary care: A cluster randomized trial. Journal of Consulting and Clinical Psychology, 84(11), 993–1007. doi:10.1037/ccp0000124 27599229
Keen, I. L., Whitehead, N. E., Clifford, L., Rose, J., & Latimer, W. (2014). Perceived barriers to treatment in a community-based sample of illicit-drug-using African American men and women. Journal of Psychoactive Drugs, 46(5), 444–449. doi:10.1080/02791072.2014.964382 25364997
Kelley, K. J., & Kelley, M. F. (2013). Teaching empathy and other compassion-based communication skills. Journal for Nurses in Professional Development, 29(6), 321–324. doi:10.1097/01.nnd.0000436794.24434.90 24256934
Kelly, J. F., Greene, M. C., & Bergman, B. G. (2016). Recovery benefits of the “therapeutic alliance” among 12-step mutual-help organization attendees and their sponsors. Drug and Alcohol Dependence, 162, 64–71. doi.10.1016/j.drugalcdep.2016.02.02826961963
Kelly, T. M., & Daley, D. C. (2013). Integrated treatment of substance use and psychiatric disorders. Social Work in Public Health, 28(3-4), 388^106. doi:10.1080/19371918.2013.774673 23731427
Kerfoot, K. E., Rosenheck, R. A., Petrakis, I. L., Swartz, M. S., Keefe, R. S., McEvoy, J. P., & Stroup, T. S. (2011). Substance use and schizophrenia: Adverse correlates in the CATIE study sample. Schizophrenia Research, 132(2-3), 177–182. doi:10.1016/j.schres.2011.07.032 21872443
Kerner, B. (2015). Comorbid substance use disorders in schizophrenia: A latent class approach. Psychiatry Research, 225(3), 395–401. doi:10.1016/j.psychres.2014.12.006 25576367
Kertesz, S. G., Crouch, K., Milby, J. B., Cusimano, R. E., & Schumacher, J. E. (2009). Housing first for homeless persons with active addiction: Are we overreaching? Milbank Quarterly, 87(2), 495–534. doi:10.1111/j.1468-0009.2009.00565.x 19523126
Kessler, R. C. (2005). National Comorbidity Survey. Retrieved from www.hcp.med.harvard.edu/ncs/
Kessler, R. C., Adler, L., Barkley, R., Biederman, J., Conners, K., Dernier, O., … Zaslavsky, A. M. (2006). The prevalence and correlates of adult ADHD in the United States: Results from the National Comorbidity Survey Replication. American Journal of Psychiatry, 163(4), 723. doi:10.1176/appi.ajp.163.4.716
D. Kessler, R. C., Andrews, G., Colpe, L. J., Hiripi, E., Mroczek, K., Normand, S. L., … Zaslavsky, A. M. (2002). Short screening scales to monitor population prevalences and trends in non-specific psychological distress. Psychological Medicine, 32(6), 959–976.12214795
Kessler, R. C., Barker, P. R., Colpe, L. J., Epstein, J. E., Gfroerer, J. C., Hiripi, E., … Zaslavsky, A. M. (2003). Screening for serious mental illness in the general population. Archives of General Psychiatry, 60(2), 184–189.12578436
Kessler, R. C., Berglund, P., Dernier, O., Jin, R., Merikangas, K. R., & Walters, E. E. (2005). Lifetime prevalence and age-of-onset distributions of DSM-IV disorders in the National Comorbidity Survey Replication. Archives Of General Psychiatry, 62(6), 593–602.15939837
Kessler, R. C., Green, J. G., Gruber, M. J., Sampson, N. A., Bromet, E., Cuitan, M., … Zaslavsky, A. M. (2010). Screening for serious mental illness in the general population with the K6 screening scale: Results from the WHO World Mental Health (WMH) survey initiative. International Journal of Methods in Psychiatric Research, 19(Supp1. 1), 4–22. doi:10.1002/mpr.310 20527002
Kessler, R. C., Petukhova, M., Sampson, N. A., Zaslavsky, A. M., & Wittchen, H. U. (2012). Twelve-month and lifetime prevalence and lifetime morbid risk of anxiety and mood disorders in the United States. International Journal of Methods in Psychiatric Research, 21(3), 169–184. doi:10.1002/mpr.1359 22865617
H. Keyser, D. J., Watkins, K. E., Vilamovska, A. M., & Pincus, A. (2008). Focus on alcohol & drug abuse: Improving service delivery for individuals with co-occurring disorders: New perspectives on the quadrant model. Psychiatric Services, 59(11), 1251–1253. doi:10.1176/appi.ps.59.11.1251 18971399
Keyser-Marcus, L., Alvanzo, A., Rieckmann, T., Thacker, L., Sepulveda, A., Forcehimes, A., Islam, L. Z., … Svikis, D. S. (2015). Trauma, gender, and mental health symptoms in individuals with substance use disorders. Interpersonal Violence, 30(1), 3–24. doi:10.1177/0886260514532523
Khalid, M. M., & Hamilton, R. J. (2020). Beta-blocker toxicity. StatPearls [Internet], Retrieved from www.ncbi.nlm.nih.aov/books/NBK448097/?report=printable
Kidd, S. A., Davidson, L., & McKenzie, K. (2017). Common factors in community mental health intervention: A scoping review. Community Mental Health Journal, 53(6), 627–637. doi:10.1007/s10597-017-0117-8 28194599
Kidorf, M., Brooner, R. K., Gandotra, N., Antoine, D., King, V. L., Peirce, J., & Ghazarian, S. (2013). Reinforcing integrated psychiatric service attendance in an opioid-agonist program: A randomized and controlled trial. Drug and Alcohol Dependence, 733(1), 30–36.
Killeen, T. K., Back, S. E. & Brady, K. T. (2015). Implementation of integrated therapies for comorbid post-traumatic stress disorder and substance use disorders in community substance abuse treatment programs. Drug and Alcohol Review, 34(3), 234–241. doi:10.1111/dar.12229 25737377
Kills Small, N. J., Simons, J. S., & Stricherz, M. (2007). Assessing criterion validity of the Simple Screening Instrument for Alcohol and Other Drug Abuse (SSI-AOD) in a college population. Addictive Behaviors, 32(10), 2425–2431. doi:10.1016/j.addbeh.2007.04.003 17481826
Kilpatrick, D. G., Resnick, H. S., Milanak, M. E., Miller, M. W., Keyes, K. M., & Friedman, M. J. (2013). National estimates of exposure to traumatic events and PTSD prevalence using DSM-IV and DSM-5 criteria. Journal of Traumatic Stress, 26(5), 537–547. doi:10.1002/jts.21848 24151000
Kim, G., DeCoster, J., Bryant, A. N., & Ford, K. L. (2016). Measurement equivalence of the K6 Scale: The effects of race/ethnicity and language. Assessment, 23(6), 758–768. doi:10.1177/1073191Ì15599639 26282779
Kirnerling, R., Makin-Byrd, K., Louzon, S., Ignacio, R.V., & McCarthy, J. F. (2016). Military sexual trauma and suicide mortality. American Journal of Preventive Medicine, 50(6), 684–691. doi:10.1016/j.amepre.2015.10.019 26699249
Klassen, L. J., Bilkey, T. S., Katzman, M. A., & Chokka, P. (2012) . Comorbid attention deficit/hyperactivity disorder and substance use disorder: Treatment considerations. Current Drug Abuse Reviews, 5(3), 190–198.22571450
Kline, A., Weiner, M. D., Ciccone, D. S., Interian, A., St. Hill, L., & Losonczy, M. (2014). Increased risk of alcohol dependency in a cohort of National Guard troops with PTSD: A longitudinal study. Journal of Psychiatric Research, 50, 18–25. doi:10.1016/j.jpsychires.2013.11.007 24332924
Knight, D. K., Broome, K. M., Edwards, J. R., & Flynn, P. M. (2011). Supervisory turnover in outpatient substance abuse treatment. Journal of Behavioral Health Services & Research, 38(1), 80–90. doi:10.1007/s11414-009-9198-7 19949883
Köck, P, & Walter, M. (2018). Personality disorder and substance use disorder—An update. Mental Health and Prevention, 12, 82–89. doi:10.1016/j.mhp.2018.10.003
Kolbasovsky, A. (2009). Reducing 30-day inpatient psychiatric recidivism and associated costs through intensive case management. Professional Case Management, 14(2), 96–105. doi:10.1097/NCM.0b013e31819e026a 19318901
Kondo, K., Low, A., Jindai, K., Mendelson, A., Motu'apuaka, M., Mansoor, D., … Hartung, D. (2015). Interventions to improve pharmacological adherence among adults with psychotic spectrum disorders, bipolar disorder, and posttraumatic stress disorder (Vol. VA ESP Project #05-225). Washington, DC: U.S. Department of Veterans Affairs.
Konkoly Thege, B., Horwood, L., Slater, L., Tan, M. C., Hodgins, D. C., & Wild, T. C. (2017). Relationship between interpersonal trauma exposure and addictive behaviors: A systematic review. BMC Psychiatry, 17(1), 164. doi:10.1186/s12888-017-1323-1 28472931
Krasnova, A., Eaton, W. W., & Samuels, J. F. (2019). Antisocial personality and risks of cause-specific mortality: Results from the Epidemiologic Catchment Area study with 27 years of follow-up. Social Psychiatry Psychiatric Epidemiology, 54(5), 617–625. doi:10.1007/s00127-018-1628-5 30506390
Krawczyk, N., Feder, K. A., Saloner, B., Crum, R. M., Kealhofer, M., & Mojtabai, R. (2017). The association of psychiatric comorbidity with treatment completion among clients admitted to substance use treatment programs in a U.S. national sample. Drug and Alcohol Dependence, 175, 157–163. doi:10.1016/j.drugalcdep.2017.02.006 28432939
Krebs, P., Norcross, J. C., Nicholson, J. M., & Prochaska, J. O. (2018). Stages of change and psychotherapy outcomes: A review and meta-analysis. Journal of Clinical Psychology, 74(11), 1964–1979. doi:10.1002/jclp.22683 30335193
Kuerbis, A. N., Neighbors, C. J., & Morgenstern, J. (2011). Depression's moderation of the effectiveness of intensive case management with substance-dependent women on temporary assistance for needy families: Outpatient substance use disorder treatment utilization and outcomes. Journal of Studies on Alcohol and Drugs, 72(2), 297–307.21388603
Kumar, G. S., & Klein, R. (2013). Effectiveness of case management strategies in reducing emergency department visits in frequent user patient populations: A systematic review. Journal of Emergency Medicine, 44(3), 729. doi:10.1016/j.jemermed.2012.08.035
Kumar, N., Stowe, Z. N., Han, X., & Mancino, M. J. (2016). Impact of early childhood trauma on retention and phase advancement in an outpatient Buprenorphine treatment program. American Journal on Addictions, 25(7), 542–548. doi:10.1111/ajad.12437. 27629823
Kuo, C., Schonbrun, Y. C., Zlotnick, C., Bates, N., Todorova, R., Kao, J. C., & Johnson, J. (2013). A qualitative study of treatment needs among pregnant and postpartum women with substance use and depression. Substance Use and Misuse, 48(14), 1498–1508. doi:10.3109/10826084.2013.800116 23819737
Kupfer, D. J. (2015). Anxiety and DSM-5. Dialogues in Clinical Neuroscience, 17(3), 245–246.26487805
Laakso, L. J. (2012). Motivational interviewing: Addressing ambivalence to improve medication adherence in patients with bipolar disorder. Issues in Mental Health Nursing, 33(1), 8–14. doi:10.3109/01612840.2011.618238 22224961
Lagisetty, P. A., Maust, D., Heisler, M., & Bohnert, A. (2017). Physical and mental health comorbidities associated with primary care visits for substance use disorders. Journal of Addiction Medicine, 17(2), 161–162. doi:10.1097/adm.0000000000000280
Lai, H. M., Cleary, M., Sitharthan, T., & Hunt, G. E. (2015). Prevalence of comorbid substance use, anxiety and mood disorders in epidemiological surveys, 1990-2014: A systematic review and meta-analysis. Drug and Alcohol Dependence, 154, 1–13. doi:10.1016/j.drugaIcdep.2015.05.031 26072219
Lally, J., & MacCabe, J. H. (2015). Antipsychotic medication in schizophrenia: A review. British Medical Bulletin, 774(1), 169–179. doi:10.1093/bmb/ldv017
Lam, C. N., Arora, S., & Menchine, M. (2016). Increased 30-day emergency department revisits among homeless patients with mental health conditions. Western Journal of Emergency Medicine, 77(5), 607–612. doi:10.5811/westjem.2016.6.30690
Lambert, M. J., & Simon, W. (2008). The therapeutic relationship: Central and essential in psychotherapy outcome. In S. F. Hick & T. Bien (Eds.), Mindfulness and the therapeutic relationship (pp. 19–33). New York, NY: Guilford Press.
Lambert-Harris, C., Saunders, E. C., McGovern, M. R., & Xie, G., (2013). Organizational capacity to address co-occurring substance use and psychiatric disorders: Assessing variation by level of care. Journal of Addiction Medicine, 7(1), 25–32. doi:10.1097/ADM.0b013e318276e7a4 23188042
Lamberti, J. S., Weisman, R. L., Gemili, C., Williams, G. C., Jacobowitz, D. B., Mueser, K. T., … Caine, E. D. (2017). A randomized controlled trial of the Rochester Forensic Assertive Community Treatment Model. Psychiatric Services, 68(10), 1016–1024. doi:10.1176/appi.ps.201600329 28566028
Landess, J., & Holoyda, B. (2017). Mental health courts and forensic assertive community treatment teams as correctional diversion programs. Behavioral Sciences and the Law, 35(5-6), 501–511. doi:10.1002/bsl.2307 28891121
Lanier, D., & Ko, S. (2008). Screening in primary care settings for illicit drug use: Assessment of screening instruments—A supplemental evidence update for the U.S. Preventive Services Task Force. Evidence Synthesis No. 58, Part 2. AHRQ Publication No. 08-05108-EF-2. Rockville, MD: Agency for Healthcare Research and Quality.
Laschober, T. C., & Eby, L. T. (2013). Substance use disorder counselors’ job performance and turnover after 1 year: Linear or curvilinear relationship? Administration and Policy in Mental Health and Mental Health Services Research, 40(4), 300–310.22527711
Lawson, K. M., Back, S. E., Hartwell, K. J., Moran-Santa Maria, M., & Brady, K. T. (2013). A comparison of trauma profiles among individuals with prescription opioid, nicotine, or cocaine dependence. American Journal of Addictions, 22(2), 127–131. doi:10.1111/j.1521-0391.2013.00319.x
Lee King, P. A., Duan, L, & Amaro, H. (2015). Clinical needs of in-treatment pregnant women with co-occurring disorders: Implications for primary care. Maternal and Child Health Journal, 79(1), 180–187. doi:10.1007/s10995-014-1508-x
Lee, M. T., Acevedo, A., Garnlck, D. W., Horgan, C. M., Panas, L., Ritter, G. A., & Campbell, K. M. (2018). Impact of agency receipt of Incentives and reminders on engagement and continuity of care for clients with cooccurring disorders. Psychiatric Services, 69(7), 804–811. doi:10.1176/appi.ps.201700465 29695226
Lee, M. T., Horgan, C. M., Garnlck, D. W., Acevedo, A., Panas, L., Ritter, G. A., … Reynolds, M. (2014). A performance measure for continuity of care after detoxification: Relationship with outcomes. Journal of Substance Abuse Treatment, 47(2), 130–139.24912862
Lee, N. K., Cameron, J., & Jenner, L. (2015). A systematic review of Interventions for co-occurring substance use and borderline personality disorders. Drug and Alcohol Review, 34(6), 663–672. doi:10.1111/dar.12267 25919396
Lee, S. S., Humphreys, K. L., Flory, K., Liu, R., & Glass, K. (2011). Prospective association of childhood attention-deficit/hyperactivity disorder (ADHD) and substance use and abuse/dependence: A meta-analytic review. Clinical Psychology Review, 37(3), 328–341. doi:10.1016/j.cpr.2011.01.006
LePage, J. P., Lewis, A. A., Crawford, A. M., Parish, J. A., Ottornanelli, L., Washington, E. L., & Cipher, D. J. (2016). Incorporating individualized placement and support principles into vocational rehabilitation for formerly incarcerated veterans. Psychiatric Services, 67(7), 735–742. doi:10.1176/appi.ps.201500058 27032655
Lijffijt, M., Hu, K., & Swann, A. C. (2014). Stress modulates illness-course of substance use disorders: A translational review. Frontiers in Psychiatry, 5, 83. doi:10.3389/fpsyt.2014.00083. 25101007
Lindsey, W. T., Stewart, D., & Childress, D. (2012). Drug interactions between common illicit drugs and prescription therapies. American Journal of Drug and Alcohol Abuse, 38(4), 334–343. doi:10.3109/00952990.2011.643997 22221229
Lo, C. C., Cheng, T. C., & de la Rosa, I. A. (2015). Depression and substance use: A temporal-ordered model. Substance Use & Misuse, 50(10), 1274–1283.25594110
Lockwood, P. L. (2016). The anatomy of empathy: Vicarious experience and disorders of social cognition. Behavioural Brain Research, 311, 255–266. doi:10.1016/j.bbr.2016.05.048 27235714
Lotito, M., & Cook, E. (2015). A review of suicide risk assessment instruments and approaches. Mental Health Clinician, 5(5), 216–223.
Lu, W., Yanos, P. T., Silverstein, S. M., Mueser, K. T., Rosenberg, S. D., Gottlieb, J. D., … Giacobbe, G. (2013). Public mental health clients with severe mental illness and probable posttraumatic stress disorder: Trauma exposure and correlates of symptom severity. Journal of Traumatic Stress, 26(2), 266–273. doi:10.1002/jts.21791 23508645
Lucas, C., & Martin, J. (2013). Smoking and drug interactions. Australian Prescriber, 36, 102–104.
Luciano, A., Beistock, J., Malmberg, P., McHugo, G. J., Drake, R. E., Xie, H., … Coveil, N. H. (2014). Predictors of incarceration among urban adults with co-occurring severe mental illness and a substance use disorder. Psychiatric Services, 65(11), 1325–1331. doi:10.1176/appi.ps.201300408 25022703
Luciano, A., Bryan, E. L., Carpenter-Song, E. A., Woods, M., Armstrong, K., & Drake, R. E. (2014). Long-term sobriety strategies for men with co-occurring disorders. Journal of Dual Diagnosis, 10(4), 212–219. doi:10.1080/15504263.2014.961884 25391279
Luciano, A., & Carpenter-Song, E. A. (2014). A qualitative study of career exploration among young adult men with psychosis and co-occurring substance use disorder. Journal of Dual Diagnosis, 10(4), 220–225. doi:10.1080/15504263 25391280
Lugobonl, E., Levin, F. R., Pieri, M. C., Manfredlnl, M., Zamboni, L., Somaini, L., … Gruppo InterSert Collaborazione, S. (2017). Co-occurring attention deficit hyperactivity disorder symptoms in adults affected by heroin dependence: Patients characteristics and treatment needs. Psychiatry Research, 250, 210–216. doi:10.1016/j.psychres.2017.01.052 28473157
Luo, S. X., & Levin, F. R. (2017). Towards precision addiction treatment: New findings in co-rnorbid substance use and attention-deficit hyperactivity disorders. Current Psychiatry Reports, 19(3), 14. doi:10.1007/s11920-017-0769-7 28251590
Lusk, S. L., Koch, L. C., & Paul, T. M. (2016). Recovery-oriented vocational rehabilitation services for individuals with co-occurring psychiatric disabilities and substance use disorders. Rehabilitation Research, Policy, and Education, 30(3), 243–258.
Lutterman, T., Shaw, R., Fisher, W., & Manderscheid, R. (2017, August). Trend in psychiatric inpatient capacity. United States and each state, 1970 to 2014. Retrieved from www.nri-inc.org/media/1319/tac-paper-10-psychiatric-inpatient-capacity-final-09-05-2017.pdf
Lydecker, K. R., Tate, S. R., Cummins, K. M., McQuaid, J., Granholm, E., & Brown, S. A. (2010). Clinical outcomes of an integrated treatment for depression and substance use disorders. Psychology of Addictive Behaviors, 24(3), 453–465. doi:10.1037/a0019943 20853931
Ma, M., Coles, A. S., & George, T. P. (2018, September 27). Understanding and treating co-occurring bipolar disorder and substance use disorders. Psychiatric Times. Retrieved from www.psychiatrictimes.com/bipolar-disorder/understanding-and-treating-co-occurring-bipolar-disorder-and-substance-use-disorders
Macy, R. J., Renz, C., & Pelino, E. (2013). Partner violence and substance abuse are intertwined: Women's perceptions of violence-substance connections. Violence Against Women, 19(7), 881–902. doi:10.1177/1077801213498208 23955931
Magidson, J. R., Liu, S.-M., Lejuez, C. W., & Blanco, C. (2012). Comparison of the course of substance use disorders among individuals with and without generalized anxiety disorder in a nationally representative sample. Journal of Psychiatric Research, 46(5), 659–666. doi:10.1016/j.jpsychires.2012.02.011 22444600
Magor-Blatch, L., Bhullar, N., Thomson, B., & Thorsteinsson, E. (2014). A systematic review of studies examining effectiveness of therapeutic communities. Therapeutic Communities, 35(4), 168–184. doi:10.1108/TC-07-2013-0024
Maisto, S. A., Roos, C. R., O'Sickey, A. J., Kirouac, M., Connors, G. J., Tonigan, J. S., & Witkiewitz, K. (2015). The indirect effect of the therapeutic alliance and alcohol abstinence self-efficacy on alcohol use and alcohol-related problems in Project MATCH. Alcoholism: Clinical and Experimental Research, 39(3), 504–513. doi:10.1111/acer.12649 25704134
Malivert, M., Fatséas, M., Denis, C., Langlois, E., & Auriacombe, M. (2012). Effectiveness of therapeutic communities: A systematic review. European Addiction Research, 18(1), 1–11. doi:10.1159/000331007 21997500
Malte, C. A., Cox, K., & Saxon, A. J. (2017). Providing intensive addiction/housing case management to homeless veterans enrolled in addictions treatment: A randomized controlled trial. Psychology of Addictive Behaviors, 31(3), 231–241. doi:10.1037/adb0000273 28481614
Mandavia, A., Robinson, G. G., Bradley, B., Ressler, K. J., & Powers, A. (2016). Exposure to childhood abuse and later substance use: Indirect effects of emotion dysrégulation and exposure to trauma. Journal of Traumatic Stress, 29(5), 422–429. doi:10.1002/jts.22131 27622844
Mangrum, L. F (2009). Client and service characteristics associated with addiction treatment completion of clients with co-occurring disorders. Addictive Behaviors, 34(10), 898–904. doi:10.1016/j.addbeh.2009.03.006 19303219
Mansfield, A. J., Greenbaurn, M. A., Schaper, K. M., Banducci, A. N., & Rosen, C. S. (2017). PTSD care among veterans with and without co-occurring substance use disorders. Psychiatric Services, 68(6), 632–635. doi:10.1176/appi.ps.201600128 28245698
Manuel, J. I., Covell, N. H., Jackson, C. T., & Essock, S. M. (2011). Does assertive community treatment increase medication adherence for people with co-occurring psychotic and substance use disorders? Journal of the American Psychiatric Nurses Association, 77(1), 51–56. doi:10.1177/1078390310395586
Markota, M., Rummans, T. A., Bostwick, J. M., & Lapid, M. I. (2016). Benzodiazepine use in older adults: Dangers, management, and alternative therapies. Mayo Clinic Proceedings, 97(11), 1632–1639. doi:10.1016/j.mayocp.2016.07.024
Marlatt, G. A. (1985). Relapse prevention: Theoretical rationale and overview of the model. In G. A. Marlatt & J. R. Gordon (Eds.), Relapse prevention: Maintenance strategies in the treatment of addictive behaviors (1st ed., pp. 3–70). New York: Guilford Press.
Marlatt, G. A., & Gordon, J. R. (Eds.). (1985). Relapse prevention: Maintenance strategies in the treatment of addictive behaviors. New York: Guilford Press.
Marmar, C. R., Schlenger, W., Henn-Haase, C., Qian, M., Purchia, E., Li, M., … Kulka, R. A. (2015). Course of posttraumatic stress disorder 40 years after the Vietnam War: Findings from the National Vietnam Veterans Longitudinal Study. JAMA Psychiatry, 72(9), 875–881. doi:10.1001/jamapsychiatry.2015.0803 26201054
Marmorstein, N. R. (2012). Anxiety disorders and substance use disorders: Different associations by anxiety disorder. Journal of Anxiety Disorders, 26(1), 88–94. doi:10.1016/j.janxdis.2011.09.005 22018969
Marotta, P. L. (2017). Childhood adversities and substance misuse among the incarcerated: Implications for treatment and practice in correctional settings. Substance Use and Misuse, 52(6), 717–733. doi:10.1080/10826084.2016.1261899 28379110
Marquant, T., Sabbe, B., Van Nuffel, M., & Goethals, K. (2016). Forensic assertive community treatment: A review of the literature. Community Mental Health Journal, 52(8), 873–881.27422650
Marshall, T., Goldberg, R. W., Braude, L., Dougherty, R. H., Daniels, A. S., Chose, S. S., … Delphin-Rittmon, M. E. (2014) . Supported employment: Assessing the evidence. Psychiatric Services, 65(1), 16–23. doi:10.1176/appi.ps.2013.00262 24247197
Martinez-Raga, J., Szerman, N., Knecht, C., & de Alvaro, R. (2013) . Attention deficit hyperactivity disorder and dual disorders. Educational needs for an underdiagnosed condition. International Journal of Adolescent Medicine and Health, 25(3), 231–243. doi:10.1515/ijamh-2013-0057 23846135
Martinez-Vispo, C., Martínez López-Durán, A., Fernández del Río, E., & Becoña, E. (2018). Effects of behavioural activation on substance use and depression: A systematic review. Substance Abuse: Treatment, Prevention, and Policy, 73(1), 36. doi:10.1186/s13011-018-0173-2
Martino, S., Carroll, K. M., Nich, C., & Rounsaville, B. J. (2006). A randomized controlled pilot study of motivational interviewing for patients with psychotic and drug use disorders. Addiction, 707(10), 1479–1492. doi:10.1111/j.1360-0443.2006.01554.x
Martins, S. S., & Gorelick, D. A. (2011). Conditional substance abuse and dependence by diagnosis of mood or anxiety disorder or schizophrenia in the U.S. population. Drug and Alcohol Dependence, 179(1-2), 28–36. doi:10.1016/j.drugalcdep.2011.05.010
Mason, R., & Dumont, J. (2015). Advancing our knowledge of the complexity and management of intimate partner violence and co-occurring mental health and substance abuse problems in women. F1000 Prime Reports, 7, 65. doi:10.12703/P7-65 26097738
Masson, C. L., Shropshire, M. S., Sen, S., Hoffman, K. A., Hengi, N. S., Bartolome, J., … Iguchi, M. Y. (2013). Possible barriers to enrollment in substance abuse treatment among a diverse sample of Asian Americans and Pacific Islanders: Opinions of treatment clients. Journal of Substance Abuse Treatment, 44(3), 309–315. doi:10.1016/j.jsat.2012.08.005 22985677
Matusow, H., Guarino, H., Rosenblum, A., Vogel, H., Uttaro, T., Khabir, S., … Magura, S. (2013). Consumers’ experiences in dual focus mutual aid for co-occurring substance use and mental health disorders. Substance Abuse: Research and Treatment, 7, 39^–7. doi:10.4137/SART.S11006 23515888
Maura, J., & Weisman de Mamani, A. (2017). Mental health disparities, treatment engagement, and attrition among racial/ethnic minorities with severe mental illness: A review. Journal of Clinical Psychology in Medical Settings, 24(3-4), 187–210. doi:10.1007/s10880-017-9510-2 28900779
Mauritz, M. W., Goossens, P. J., Draijer, N., & van Achterberg, T. (2013). Prevalence of interpersonal trauma exposure and trauma-related disorders in severe mental illness. European Journal of Psychotraumatology, 4. Published online. doi:10.3402/ejpt.v4i0.19985
McCabe, S. E., West, B. T., Jutkiewicz, E. M., & Boyd, C. J. (2017). Multiple DSM-5 substance use disorders: A national study of US adults. Human Psychopharmacology, 32(5). doi:10.1002/hup.2625
McCallum, S., Mikocka-Walus, A., Turnbull, D., & Andrews, J. M. (2015). Continuity of care in dual diagnosis treatment: Definitions, applications, and implications. Journal of Dual Diagnosis, 77(3-4), 217–232. doi:10.1080/15504263.2015.1104930
McCance-Katz, E. F. (2019). The National Survey on Drug Use and Health: 2018. Slide Presentation. Retrieved from https://www.samhsa.gov/data/sites/default/files/cbhsq-reports/Assistant-Secretary-nsduh2018_presentation.pdf
McCarty, D., Braude, L., Lyman, D. R., Dougherty, R. H., Daniels, A. S., Ghose, S. S., & Delphin-Rittmon, M. E. 2014. Substance abuse intensive outpatient programs: Assessing the evidence. Psychiatric Services, 65(6), 726.
McCauley, J. L., Killeen, T., Gros, D. E., Brady, K. T., & Back, S. E. (2012). Posttraumatic stress disorder and co-occurring substance use disorders: Advances in assessment and treatment. Clinical Psychology: Science and Practice, 79(3), 283–304. doi:10.1111/cpsp.12006
McCloskey, M. S., & Ammennan, B. A. (2018). Suicidal behavior and aggression-related disorders. Current Opinion in Psychology, 22, 54–58. doi:10.1016/j.copsyc.2017.08.010 28829989
McConnaughy, E. A., Prochaska, J., & Velicer, W. F. (1983). Stages of change in psychotherapy: Measurement and sample profiles. Psychotherapy: Theory, Research, and Practice, 20(3), 368–375.
McDerrnid, J., Sareen, J., El-Gabalawy, R., Pagura, J., Spiwak, R., & Enns, M. W. (2015). Co-morbidity of bipolar disorder and borderline personality disorder: Findings from the National Epidemiologic Survey on Alcohol and Related Conditions. Comprehensive Psychiatry, 58, 18–28. doi:10.1016/j.comppsych.2015.01.004 25666748
McDermott, K. W., Elixhauser, A., & Sun, R. (2017, June). Trends in hospital inpatient stays in the United States, 2005-2014. HCUP Statistical Brief #225. Agency for Healthcare Research and Quality, Rockville, MD. Retrieved from www.hcup-us.ahrq.gov/reports/statbriefs/sb225-lnpatient-US-Stays-Trends.pdf
McDonald, D., & Arlinghaus, S. L. (2014). The role of intensive case management services in reentry: The northern Kentucky female offender reentry project. Women and Criminal Justice, 24(3), 229–251. doi:10.1080/08974454.2014.909759
McDonell, M. G., Kerbrat, A. H., Comtois, K. A., Russo, J., Lowe, J. M., & Ries, R. K. (2012). Validation of the co-occurring disorder quadrant model. Journal of Psychoactive Drugs, 44(3), 266–273. doi:10.1080/02791072.2012.705065 23061327
McDonell, M. G., Srebnik, D., Angelo, F., McPherson, S., Lowe, J. M., Sugar, A., … Ries, R. K. (2013). Randomized controlled trial of contingency management for stimulant use in community mental health patients with serious mental illness. American Journal of Psychiatry, 170(1), 94–1 01. doi:10.1176/appi.ajp.2012.11121831 23138961
McGovern, M. P., Clark, R. E., & Samnaliev, M. (2007). Co-occurring psychiatric and substance use disorders: A multistate feasibility study of the quadrant model. Psychiatric Services, 58(7), 949–954. doi:10.1176/ps.2007.58.7.949 17602011
McGovern, M. P., Lambert-Harris, C., Alterman A. L., Xie, H., & Meier, A. (2011). A randomized controlled trial comparing integrated cognitive behavioral therapy versus individual addiction counseling for co-occurring substance use and posttraumatic stress disorders. Journal of Dual Diagnosis, 7(4), 207–227.22383864
McGovern, M. P., Lambert-Harris, C., Gotham, H. J., Claus, R. E., & Xie, H. (2014). Dual diagnosis capability in mental health and addiction treatment services: An assessment of programs across multiple state systems. Administration and Policy in Mental Health, 41(2), 205–214. doi:10.1007/s10488-012-0449-1 23183873
McGovern, M. P., Lambert-Harris, C., Xie, H., Meier, A., McLeman, B., & Saunders, E. (2015). A randomized controlled trial of treatments for co-occurring substance use disorders and post-traumatic stress disorder. Addiction, 110(7), 1194–1204. doi:10.1111/add.12943 25846251
McGovern, M. P., Saunders, E. C., & Kim, E. (2013). Substance abuse treatment implementation research. Journal of Substance Abuse Treatment, 44(1), 1–3. doi:10.1016/j.jsat.2012.09.006 23083972
McGrath, J., Saha, S., Welham, J., El Saadi, O., MacCauley, C., & Chant, D. (2004). A systematic review of the incidence of schizophrenia: The distribution of rates and the influence of sex, urbanicity, migrant status and methodology. BMC Medicine, 2, 13. doi:10.1186/1741-7015-2-13 15115547
McHugh, R. K. (2015). Treatment of co-occurring anxiety disorders and substance use disorders. Harvard Review of Psychiatry, 23(2), 99–111. doi:10.1097/HRP.0000000000000058 25747923
McHugh, R. K., Gratz, K. L, & Tull, M. T. (2017). The role of anxiety sensitivity in reactivity to trauma cues in treatment-seeking adults with substance use disorders. Comprehensive Psychiatry, 78, 107–114. doi:10.1016/j.comppsych.2017.07.011 28822277
McHugh, R. K., Votaw, V. R., Sugarman, D. E., & Greenfield, S. F. (2018). Sex and gender differences in substance use disorders. Clinical Psychology Review, 12-23. doi:10.1016/j.cpr.2017.10.012
McHugo, G. J., Drake, R. E., Burton, H. L., & Ackerson, T. H. (1995). A scale for assessing the stage of substance abuse treatment in persons with severe mental illness. Journal of Nervous and Mental Disease, 183(12), 762–767.8522938
McHugo, G. J., Drake, R. E., Xie, H. & Bond, G. R. (2012). A 1 0-year study of steady employment and non-vocational outcomes among people with serious mental illness and co-occurring substance use disorders. Schizophrenia Research, 138(2-3), 233–239. doi:10.1016/j.schres.2012.04.007 22546432
McKay J. R. (2009). Continuing care research: What we have learned and where we are going. Journal of Substance Abuse Treatment, 36(2), 131–145.19161894
McKay, J. R., Knepper, C., Deneke, E., O'Reilly, C., & DuPont, R. L. (2016). An initial evaluation of a comprehensive continuing care intervention for clients with substance use disorders: My first year of recovery (MyFYR). Journal of Substance Abuse Treatment, 67, 50–54. doi:10.1016/j.jsat.2016.04.003 27296662
McKee, S. A., Harris, G. T., & Cormier, C. A. (2013). Implementing residential integrated treatment for co-occurring disorders. Journal of Dual Diagnosis, 9(3), 249–259.23976887
McKenzie, K., & Chang, Y. P. (2015). The effect of nurse-led motivational interviewing on medication adherence in patients with bipolar disorder. Perspectives in Psychiatric Care, 57(1), 36^14. doi:10.1111/ppc.12060
McKeown, R. E., Holbrook, J. R., Danielson, M. L., Cuffe, S. P., Wolraich, M. L., & Visser, S. N. (2015). The impact of case definition on attention-deficit/hyperactivity disorder prevalence estimates in community-based samples of school-aged children. Journal of the American Academy of Child Adolescent Psychiatry, 54(1), 53–61. doi:10.1016/j.jaac.2014.10.014 25524790
McKetin, A. R., Voce, A., Burns, R., Ali, R., Lubman, D. I., Baker, L., & Castle, D. J. (2018). Latent psychotic symptom profiles amongst people who use methamphetamine: What do they tell us about existing diagnostic categories? Frontiers in Psychiatry, 9, 578. doi:10.3389/fpsyt.2018.00578 30524318
McKinney, J. M., Hirsch, J. K. & Britton, P. C. (2017). PTSD symptoms and suicide risk in veterans: Serial indirect effects via depression and anger. Journal of Affective Disorders, 214, 100–107. doi:10.1016/j.jad.2017.03.008 28288403
McLellan, A. T., Kushner, H., Metzger, D., Peters, R., Smith, H., Grissom, G., … Argeriou, M. (1992). The fifth edition of the Addiction Severity Index. Journal of Substance Abuse Treatment, 9(3), 199–213.1334156
Mdege, N. D., & Lang, J. (2011). Screening instruments for detecting illicit drug use/abuse that could be useful in general hospital wards: A systematic review. Addictive Behaviors, 36(12), 1111–1119. doi:10.1016/j.addbeh.2011.07.007 21821364
Mee-Lee, D., Shulman, G. D., Fishman, M. J., Gastfriend, R., & Miller, M. M. (Eds.). (2013). The ASAM criteria: Treatment for addictive, substance-related, and cooccurring conditions (3rd ed.). Carson City, NV: The Change Companies.
Meier, A., McGovern, M. P., Larnbert-Harris, C., McLeman, B., Franklin, A., Saunders, E. C., & Xie, H. (2014) . Adherence and competence in two manual-guided therapies for co-occurring substance use and posttraumatic stress disorders: Clinician factors and patient outcomes. American Journal of Drug and Alcohol Abuse, 47(6), 527–534. doi:10.3109/00952990.2015.1062894
Meier, P. S., & Barrowclough, C. (2009). Mental health problems: Are they or are they not a risk factor for dropout from drug treatment? A systematic review of the evidence. Drugs: Education, Prevention and Policy, 76(1), 7–38. doi:10.1080/09687630701741030
Melernis, S. M. (2015). Relapse prevention and the five rules of recovery. Yale Journal of Biology and Medicine, 88(3), 325–332.26339217
Mentalhelp.Net. (2019a). Mental Health, Dual-Diagnosis, & Behavioral Addictions. Retrieved from www.mentalhelp.net/articles/behavioral-addictions-mental-health-dual-diagnosis/
MentalHelp.Net. (2019b). Schizophrenia. Retrieved from www.mentalhelp.net/articles/schizophrenia/
Mericle, A. A., Ta Park, V. M., Hoick, P, & Arria, A. M. (2012). Prevalence, patterns, and correlates of co-occurring substance use and mental disorders in the United States: Variations by race/ethnicity. Comprehensive Psychiatry, 53(6), 657–665. doi:10.1016/j.comppsych.2011.10.002 22152496
Merrick, E. M. T., Ports, K. A., Ford, D. C., Afifi, T. O., Gershoff, T, & Grogan-Kaylor, A. (2017). Unpacking the impact of adverse childhood experiences on adult mental health. Child Abuse and Neglect, 69, 10–19. doi:10.1016/j.chiabu.2017.03.016 28419887
Meyer, R. E., Salzman, C., Youngstrom, E. A., Clayton, P. J., Goodwin, F. K., Mann, J. J., … Sheehan, D. V. (2010). Suicidality and risk of suicide—Definition, drug safety concerns, and a necessary target for drug development: A consensus statement. Journal of Clinical Psychiatry, 77(8), e1–e21. doi:10.4088/JCP.10cs06070blu
Miller, J. M., & Khey, D. N. (2016). An implementation and process evaluation of the Louisiana 22nd judicial district's behavioral health court. American Journal of Criminal Justice, 47(1). doi:10.1007/s12103-015-9326-2
Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). New York: Guilford Press.
Miller, W. R., & Tonigan, J. S. (1996). Assessing drinkers’ motivation for change: The Stages of Change Readiness and Treatment Eagerness Scale (SOCRATES). Psychology of Addictive Behaviors, 70(2), 81–89. doi:10.1037/0893-164X.10.2.81
Minassian, A., Vilke, G. M., & Wilson, M. P. (2013). Frequent emergency department visits are more prevalent in psychiatric, alcohol abuse, and dual diagnosis conditions than in chronic viral illnesses such as hepatitis and human immunodeficiency virus. Journal of Emergency Medicine, 45(4), 520–525. doi:10.1016/j.jemermed.2013.05.007 23845528
Minkoff, K. (1989). An integrated treatment model for dual diagnosis of psychosis and addiction. Hospital and Community Psychiatry, 40(10), 1031–1036.2807203
Minnich, A., Erford, B. T., Bardhoshi, G., & Atalay, Z. (2018). Systematic review of the Michigan Alcoholism Screening Test. Journal of Counseling and Development, 96(3), 335–344. doi:10.1002/jcad.12207
Mitchell, F. M. (2015). Racial and ethnic health disparities in an era of health care reform. Health and Social Work, 40(3), e66–e74. doi:10.1093/hsw/hlv038
Mitchell, M. S., Leon, C. L. K., Byrne, T. H., Lin, W. C., & Bharel, M. (2017). Cost of health care utilization among homeless frequent emergency department users. Psychological Services, 14(2), 193–202. dol:10.1037/ser000011328481604
Mohamed, S. (2013). Dual diagnosis among intensive case management participants in the Veterans Health Administration: Correlates and outcomes. Journal of Dual Diagnosis, 9(4), 311–321. doi:10.1080/15504263.2013.835162
Molina, B. S. G., Howard, A. L., Swanson, J. M., Stehli, A., Mitchell, J. T. Kennedy, T. M., … Hoza, B. (2018). Substance use through adolescence into early adulthood after childhood-diagnosed ADHD: Findings from the MTA longitudinal study. Journal of Child Psychology and Psychiatry, 59(6), 692–702. doi:10.1111/jcpp.12855 29315559
Monica, C. Nikkei, R. E. & Drake, R. E. (2010). Dual Diagnosis Anonymous of Oregon. Psychiatric Services, 61, 738–740.20675831
Moore, K. A., Young, M. S., Barrett, B., & Ochshorn, E. (2009). A 12-month follow-up evaluation of integrated treatment for homeless individuals with co-occurring disorders. Journal of Social Service Research, 35(4), 322–335. doi:10.1080/01488370903110829
Morgan, O., Kuramoto, E., Emmet, W., Stange, J. L., & Nobunaga, E. (2014). The impact of the Affordable Care Act on behavioral health care for individuals from racial and ethnic communities. Journal of Social Work in Disability and Rehabilitation, 73(1-2), 139–161. doi:10.1080/1536710X.2013.870518
Morgenstern, J., Neighbors, C. J., Kuerbis, A., Riordan, A., Blanchard, K. A., McVeigh, K. H., … McCrady, B. (2009). Improving 24-month abstinence and employment outcomes for substance-dependent women receiving temporary assistance for needy families with intensive case management. American Journal of Public Health, 99(2), 328–333. doi:10.2105/ajph.2007.133553 19059855
Morisano, D., Babor, T. E, & Robaina, K. A. (2014). Co-occurrence of substance use disorders with other psychiatric disorders: Implications for treatment services. Nordic Studies on Alcohol and Drugs, 37(1), 5–25.
Morrens, M., Dewilde, B., Sabbe, B., Dorn, G., De Cuyper, R., & Moggi, F. (2011). Treatment outcomes of an integrated residential programme for patients with schizophrenia and substance use disorder. European Addiction Research, 17(3), 154–163. doi:10.1159/000324480 21447952
Morse, G., Salyers, M. R., Rollins, A. L., Monroe-DeVita, M., & Pfahler, C. (2012). Burnout in mental health services: A review of the problem and its remediation. Administration and Policy in Mental Health, 39(5), 341–352. doi:10.1007/s10488-011-0352-1
Morse, G. A., York, M. M., Dell, N., Blanco, J., & Birchmier, C. (2017). Improving outcomes for homeless people with alcohol disorders: A multi-program community-based approach. Journal of Mental Health, 1-8. doi:10.1080/09638237.2017.1340617
Morse, S., & Bride, B. E. (2017). Decrease in healthcare utilization and costs for opioid users following residential integrated treatment for co-occurring disorders. Healthcare (Basel), 5(3), 54. doi:10.3390/healthcare5030054
Morse, S. A., Watson, C., MacMaster, S. A., & Bride, B. E. (2015) . Differences between older and younger adults in residential treatment for co-occurring disorders. Journal of Dual Diagnosis, 11(1), 75–82. doi:10.1080/15504263.2014.993263 25531670
Moulin, A., Evans, E. J., Xing, G., & Melnikow, J. (2018). Substance use, homelessness, mental illness and Medicaid coverage: A set-up for high emergency department utilization. Western Journal of Emergency Medicine, 79(6), 902–906. doi:10.5811/westjem.2018.9.38954
Mueser, K. T., Campbell, K., & Drake, R. E. (2011). The effectiveness of supported employment in people with dual disorders. Journal of Dual Diagnosis, 7(1-2), 90–102.23275763
Mueser, K. T, & Gingerich, S. (2013). Treatment of cooccurring psychotic and substance use disorders. Social Work in Public Health, 28(3^), 424–439. doi:10.1080/19371918.2013.774676 23731429
Muhuri, P. K., & Gfroerer, J. C. (2009). Substance use among women: Associations with pregnancy, parenting, and race/ethnicity. Maternal and Child Health Journal, 13(3), 376–385. doi:10.1007/s10995-008-0375-8 18566878
Mundon, C. R., Anderson, M. L., & Najavits, L. M. (2015). Attitudes toward substance abuse clients: An empirical study of clinical psychology trainees. Journal of Psychoactive Drugs, 47(4), 293–300. doi:10.1080/02791072.2015.1076090 26375324
Munn-Chernoff, M. A., & Baker, J. H. (2016). A primer on the genetics of comorbid eating disorders and substance use disorders. European Eating Disorders Review, 24(2), 91–100. doi:10.1002/erv.2424 26663753
Munn-Chernoff, M. A., Grant, J. D., Agrawal, A., Sartor, C. E., Werner, K. B., Bucholz, K. K., … Duncan, A. E. (2015). Genetic overlap between alcohol use disorder and bulimic behaviors in European American and African American women. Drug and Alcohol Dependence, 153, 335–340. doi:10.1016/j.drugalcdep.2015.05.043 26096536
Nam, E., Matejkowski, J., & Lee, S. (2017). Racial/ethnic differences in contemporaneous use of mental health and substance use treatment among individuals experiencing both mental illness and substance use disorders. Psychiatric Quarterly, 88(1), 185–198. doi:10.1007/s11126-016-9444-0 27271529
Nanni, V., Uher, R., & Danese, A. (2012). Childhood maltreatment predicts unfavorable course of illness and treatment outcome in depression: A meta-analysis. American Journal of Psychiatry, 769(2), 141–151.
National Academies of Sciences, Engineering, and Medicine. (2016). Part 3: Instruments available for measuring specific mental illness diagnoses with functional impairment. In Measuring specific mental illness diagnoses with functional impairment: Workshop summary. Washington, DC: National Academies Press.
National Association of State Mental Health Program Directors (NASMHPD). (June 2012). Fact sheet on accelerating integration of primary care, behavioral health and prevention: The SBHA role. Retrieved from www.nasmhpd.org/sites/default/files/Behavioral%20Health%20PrimaryFact%20Sheet%20Accelerating%20lntegration%20of%20Primary%20Care.pdf
National Association of State Mental Health Program Directors, & National Association of State Alcohol and Drug Abuse Directors (NASADAD). (March 1999). National dialogue on co-occurring mental health and substance abuse disorders. Retrieved from http://nasadad.org/2015/03/national-dialogue-on-co-occurrina-mental-health-and-substance-abuse-disorders/
National Institute of Mental Health (NIMH), (n.d.). Ask Suicide-Screening Questions (ASQ) Toolkit. Retrieved from https://www.nimh.nih.aov/research/research-conducted-at-nimh/asq-toolkit-materials/index.shtml
National Institute of Mental Health. (2016, February). Schizophrenia. Retrieved from www.nirnh.nih.gov/health/topics/schizophrenia/index.shtml
National Institute of Mental Health. (2016, October). Mental health medications: Overview. Retrieved from www.nimh.nih.gov/health/topics/mental-health-medications/index.shtml
National Institute of Mental Health. (2017, November). Attention-deficit/hyperactivity disorder (ADHD). Retrieved from www.nimh.nih.gov/health/statistics/attention-deficit-hyperactivity-disorder-adhd.shtml-part154905
National Institute of Mental Health. (2019). Suicide. Retrieved from www.nimh.nih.gov/health/statistics/suicide.shtml
National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from https://www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
National Institute on Drug Abuse. (2012a). Adoption of NIDA's evidence-based treatments in real world settings—A National Advisory Council on Drug Abuse Workgroup report. Retrieved from www.drugabuse.gov/sites/default/files/files/evidence-basedtreatmentsinrealworldsettingsworkgroupreport.pdf
National Institute on Drug Abuse. (2012b). Resource guide: Screening for drug use in general medical settings. Retrieved from www.drugabuse.gov/publications/resource-guide-screening-drug-use-in-general-medical-settings/nida-quick-screen
National Institute on Drug Abuse. (2015, July). How are therapeutic communities adapting to the current environment? Retrieved from www.drugabuse.aov/publications/research-reports/therapeutic-communities/how-are-therapeutic-communities-adapting-to-current-environment
National Institute on Drug Abuse. (2018a). Common comorbidities with substance use disorders. Retrieved from https://d14rmgtrwzf5a.cloudfront.net/sites/default/files/1155-common-comorbidities-with-substance-use-disorders.pdf
National Institute on Drug Abuse. (2018b). Principles of drug addiction treatment: A research-based guide (3rd ed.). Rockville, MD: National Institute on Drug Abuse, National Institutes of Health, U.S. Department of Health and Human Services.
National Institute on Drug Abuse. (2018c). Treatment and recovery. In Drugs, brains, and behavior: The science of addiction (pp. 22–25). Bethesda, MD: National Institute on Drug Abuse.
National Institute on Drug Abuse. (2018d, July). Sex and gender differences in substance use disorder treatment. Retrieved from www.drugabuse.gov/publications/research-reports/substance-use-in-women/sex-gender-differences-in-substance-use-disorder-treatment
National Institute on Drug Abuse. (Revised March 2018). Benzodiazepines and opioids. Retrieved from www.drugabuse.gov/drugs-abuse/opioids/benzodiazepines-opioids
Neumiller, S., Bennett-Clark, F., Young, M. S., Dates, B., Broner, N., Leddy, J., … De Jong, F. (2009). Implementing assertive community treatment in diverse settings for people who are homeless with co-occurring mental and addictive disorders: A series of case studies. Journal of Dual Diagnosis, 5(3-4), 239–263. doi:10.1080/15504260903175973
Newell, J. M. Nelson-Gardell, D. & MacNeil, G. (2016). Clinician responses to client traumas: A chronological review of constructs and terminology. Trauma, Violence, & Abuse, 77(3), 306–13. doi:10.1177/1524838015584365
Newton-Howes, G., & Foulds, J. (2018). Personality disorder and treatment outcome in alcohol use disorder. Current Opinion in Psychiatry, 37(1), 50–56. doi:10.1097/YCO.0000000000000375
Nicosia, N., Macdonald, J. M., & Arkes, J. (2013). Disparities in criminal court referrals to drug treatment and prison for minority men. American Journal of Public Health, 703(6), e77–e84. doi:10.2105/ajph.2013.301222
Noel, V., Woods, M., Routhier, J. & Drake, R. (2016). Planning treatment and assessing recovery In participants with dual diagnosis: Preliminary evaluation of a new clinical tool. Journal of Dual Diagnosis, 72(1), 55–62. doi:10.1080/15504263.2016.1146555
Norman, R. E., Byambaa, M., De, R., Butchart, A., Scott, I., & Vos, T. (2012). The long-term health consequences of child physical abuse, emotional abuse, and neglect: A systematic review and meta-analysis. PLoS Medicine, 9(11), e1001349. doi:10.1371/journal.pmed.1001349 23209385
Nowotny, K. M. (2015). Race/ethnic disparities in the utilization of treatment for drug dependent inmates in U.S. state correctional facilities. Addictive Behaviors, 40, 148–153. doi:10.1016/j.addbeh.2014.09.005 25270722
O'Connell, M., Kasprow, W., & Rosenheck, R. A. (2010). National dissemination of supported housing in the VA: Model adherence versus model modification. Psychiatric Rehabilitation Journal, 33(4), 308–319. doi:10.2975/33.4.2010.308.319 20374989
O'Connell, M. J., Flanagan, E. H., Delphin-Rittmon, M. E., & Davidson, L. (2017). Enhancing outcomes for persons with co-occurring disorders through skillstraining and peer recovery support. Journal of Mental Health, 1-6. doi:10.1080/09638237.2017.1294733
O'Connor, R., & Pirkis, J. (2016). The international handbook of suicide prevention (2nd ed.). Chichester, UK: Wiley Blackwell.
O'Grady, M. A., Kapoor, S., Kwon, N., Morley, J., Auerbach, M., Neighbors, C. J., … Morgenstern, J. (2019). Substance use screening and brief intervention: Evaluation of patient and implementation differences between primary care and emergency department settings. Journal of Evaluation in Clinical Practice 25(3), 441–447. doi:10.1111/jep.l3060 30426596
O'Grady, M. A., Neighbors, C. J., Lincourt, R., Burke, C., & Maldonado, A. (2019). Development and testing of an addiction treatment level of care determination tool. Journal of Behavioral Health Services & Research, 46, 487–496. doi:10.1007/s11414-018-9623-x 29790038
O'Hara, M. W., & Engeldinger, J. (2018). Treatment of postpartum depression: Recommendations for the clinician. Clinical Obstetrics and Gynecology, 67(3), 604–614. doi:10.1097/grf.0000000000000353
O'Hara, M. W., & McCabe, J. E. (2013). Postpartum depression: Current status and future directions. Annual Review of Clinical Psychology, 9, 379–407. doi:10.1146/annurev-clinpsy-050212-185612
Office of Disease Prevention and Health Promotion. (2019). Topics & objectives A-Z. Healthy People 2020. Retrieved from www.healthypeople.gov/2020/topics-objectives
Office of Minority Health. (October 2018). The national CLAS standards. Retrieved from https://minorityhealth.hhs.gov/omh/browse.aspx?lvl=2&lvlid=53
Oldham, J. M. (March 2005). Guideline watch: Practice guideline for the treatment of patients with borderline personality disorder. Arlington, VA: American Psychiatric Association. Retrieved from https://psychiatrvonline.org/pb/assets/raw/sitewide/practiceguidelines/guidelines/bpd-watch.pdf
Olfson, M. (2016). Building the mental health workforce capacity needed to treat adults with serious mental illnesses. Health Affairs, 35(6), 983–990. doi:10.1377/hlthaff.2015.1619 27269013
Oquendo, M. A., Currier, D., Liu, S. M., Hasin, D. S., Grant, B. F., & Blanco, C. (2010). Increased risk for suicidal behavior in comorbid bipolar disorder and alcohol use disorders: Results from the National Epidemiologic Survey on Alcohol and Related Conditions (NESARC). Journal of Clinical Psychiatry, 77(7), 902–909. doi:10.4088/JCP.09m05198gry
Oser, C. B. Biebel, E. R. Pullen, E. & Harp, K. L. (2013). Causes, consequences, and prevention of burnout among substance abuse treatment counselors: A rural versus urban comparison. Journal of Psychoactive Drugs, 45(1), 17–27. doi:10.1080/02791072.2013.763558 23662328
Osman, A., Bagge, C. L., Gutierrez, P. M., Konick, L. C. Kopper, B. A., & Barrios, F. X. (2001). The Suicidal Behaviors Questionnaire-Revised (SBQ-R): Validation with clinical and nonclinical samples. Assessment, 8(4), 443–454. doi:10.1177/107319110100800409 11785588
Paddock, S. M., Hunter, S. B., & Leininger, T. J. (2014). Does group cognitive-behavioral therapy module type moderate depression symptom changes in substance abuse treatment clients? Journal of Substance Abuse Treatment, 47(1), 78–85. doi:10.1016/j.jsat.2014.02.005 24657006
Padgett, D. K., Stanhope, V., Henwood, B. P, & Stefancic, A. (2011). Substance use outcomes among homeless clients with serious mental illness: Comparing Housing First with Treatment First programs. Community Mental Health Journal, 47(2), 227–232. doi:10.1007/s10597-009-9283-7 20063061
Padwa, H., Guerrero, E. G., Braslow, J. T, & Fenwick, K. M. (2015). Barriers to serving clients with co-occurring disorders in a transformed mental health system. Psychiatric Services, 66(5), 547–550. doi:10.1176/appi.ps.201400190 25686812
Padwa, H., Larkins, S., Crevecoeur-MacPhail, D. A., & Creila, C. E. (2013). Dual diagnosis capability in mental health and substance use disorder treatment programs. Journal of Dual Diagnosis, 9(2), 179–186. doi:10.1080/15504263.2013.778441 23687469
Palmer, R. H., Nugent, N. R., Brick, L. A., Bidwell, C. L., McGeary, J. E. Keller, M. C. & Knopik, V. S. (2016). Evidence of shared genome-wide additive genetic effects on interpersonal trauma exposure and generalized vulnerability to drug dependence in a population of substance users. Journal of Traumatic Stress, 29(3), 197–204. doi:10.1002/jts.22103 27214850
Paquette, K., & Pennella Winn, L. A. (2016). The role of recovery housing: Prioritizing choice In homeless services. Journal of Dual Diagnosis, 72(2), 153–162. doi:10.1080/15504263.2016.1175262
Paris, J. (2014). After DSM-5: Where does personality disorder research go from here? Harvard Review of Psychiatry, 22(4), 216–221. dol:10.1097/HRP.000000000000004124983869
Park, T. W., Cheng, D. M., Samet, J. H., Winter, M. R., & Saitz, R. (2015). Chronic care management for substance dependence in primary care among patients with co-occurring disorders. Psychiatric Services, 66(1), 72–79. doi:10.1176/appi.ps.201300414 25219686
Parks, J., & Radke, A. Q. (Eds.) (July 2014). The vital role of state psychiatric hospitals. Retrieved from https://www.nasmhpd.org/sites/default/files/The%20Vital%20Role%20of%20State%20Psychiatric%20HospitalsTechnical%20ReportJuly2014.pdf
Pasche, S. (2012). Exploring the comorbidity of anxiety and substance use disorders. Current Psychiatry Reports, 14(3), 176–181. doi:10.1007/s11920-012-0264-0 22527871
Patel, K. R., Cherian, J., Gohil, K., & Atkinson, D. (2014). Schizophrenia: Overview and treatment options. Pharmacy & Therapeutics, 39(9), 638–645.25210417
Pathways to Housing DC. (2017). Program updates. Retrieved from https://pathwaystohousingdc.org/wp-content/uploads/financials/Annual%20Highliahts%202016-2017.pdf
Pathways to Housing PA. (2018). Reclaiming lives. Triennial Report 2018. Retrieved from https://pathwaystohousingpa.org/sites/pathwaystohousinapa.org/files/PTH%20Trienniel_11.1.18.pdf
Peachey, J. E., & Lei, H. (1988). Assessment of opioid dependence with naloxone. British Journal of Addiction, 83(2), 193–201.3345396
Pearce, S., & Autrique, M. (2010). On the need for randomised trials of therapeutic community approaches. Therapeutic Communities, 31(4), 338–355.
Pearce, S., & Pickard, H. (2013). How therapeutic communities work: Specific factors related to positive outcome. International Journal of Social Psychiatry, 59(7), 636–645. doi:10.1177/0020764012450992 22820178
Pearson, C., Montgomery, A. E., & Locke, G. (2009). Housing stability among homeless individuals with serious mental illness participating in Housing First programs. Journal of Community Psychology, 37(3), 404–417. doi:10.1002/jcop.20303
Penn, P. E., Brooke, D., Brooks, A. J., Gallagher, S. M., & Barnard, A. D. (2016). Co-occurring conditions clients and counselors compare 12-step and smart recovery mutual help. Journal of Groups in Addiction and Recovery, 17(2), 76–92. doi:10.1080/1556035X.2015.1104643
Perry, A. E., Neilson, M., Martyn-St. James, M., Glanville, J. M., McCool, R., Duffy, S. … Hewitt, C. (2015). Interventions for drug-using offenders with co-occurring mental illness. Cochrane Database of Systematic Reviews, 1, CD01–0901. doi:10.1002/14651858.cd010901
Peters, R. H., Young, M. S., Rojas, E. C., & Gorey, C. M. (2017). Evidence-based treatment and supervision practices for co-occurring mental and substance use disorders in the criminal justice system. American Journal of Drug and Alcohol Abuse, 43(4), 475–488. doi:10.1080/00952990.2017.1303838 28375656
Petrakis, I. L., & Simpson, T. L. (2017). Posttraumatic stress disorder and alcohol use disorder: A critical review of pharmacologic treatments. Alcoholism: Clinical and Experimental Research, 41(2), 226–237. doi:10.1111/acer.13297 28102573
Petrakis, M., Robinson, R., Myers, K., Kroes, S., & O'Connor, S. (2018). Dual diagnosis competencies: A systematic review of staff training literature. Addictive Behaviors Reports, 7, 53–57. doi:10.1016/j.abrep.2018.01.003 29892698
Pew Research Center. (2018, January 12). Blacks and Hispanics are overrepresented in U.S. prisons. Retrieved from http://www.pewresearch.org/fact-tank/2018/01712/shrinking-aap-between-number-of-blacks-and-whites-in-prison/ft18-01-10prisonracegaps2/
Pierre, J. M. (2018). Real world challenges in managing dual diagnosis patients. Current Psychiatry, 77(9), 24–30.
Pietrzak, B. R. H., Goldstein, R. B., Southwick, S. M., & Grant, F. (2011). Prevalence and Axis I comorbidity of full and partial posttraumatic stress disorder in the United States: Results from Wave 2 of the National Epidemiologic Survey on Alcohol and Related Conditions. Journal of Anxiety Disorders, 25(3), 456–465. doi:10.1016/j.janxdis.2010.11.010 21168991
Pinedo, M., Zemore, S., & Rogers, S. (2018). Understanding barriers to specialty substance abuse treatment among Latinos. Journal of Substance Abuse Treatment, 94, 1–8. doi:10.1016/j.jsat.2018.08.004 30243409
Plakun, E. M. (2018). Clinical and insurance perspectives on intermediate levels of care in psychiatry. Journal of Psychiatric Practice, 24(2), 111–116. doi:10.1097/pra.0000000000000291 29509181
Polcin, D. L. (2016). Co-occurring substance abuse and mental health problems among homeless persons: Suggestions for research and practice. Journal of Social Distress and the Homeless, 26(1), 1–1 0. doi:10.1179/1573658X15Y.0000000004
Polcin, D. L., Galloway, G. P., Bond, J., Korcha, R., & Greenfield, T. K. (2010). How do residents of recovery houses experience confrontation between entry and 12-month follow-up? Journal of Psychoactive Drugs, 42(1), 49–62. doi:10.1080/02791072.2010.10399785 20464806
Po lein, D. L., Mulia, N., & Laura, J. M. A. (2012). Substance users’ perspectives on helpful and unhelpful confrontation: Implications for recovery. Journal of Psychoactive Drugs, 44(2), 144–152. doi:10.1080/02791072.2012.684626 22880542
Pompili, M., Serafini, G., Innamorati, M., Dominici, G., Ferracuti, S., Kotzalidis, G. D., … Lester, D. (2010). Suicidal behavior and alcohol abuse. International Journal of Environmental Research and Public Health, 7(4), 1392–1431. doi:10.3390/ijerph7041392 20617037
Pompili, M., Sher, L., Serafini, G., Forte, A., Innamorati, M., Dominici, G., … Girardi, P. (2013). Posttraumatic stress disorder and suicide risk among veterans: A literature review. Journal of Nervous and Mental Disease, 201(9), 802–812. doi:10.1097/NMD.0b013e3182a21458 23995037
Posner, J. K., Brown, G. K., Stanley, B., Brent, D. A., Yershova, V., Oquendo, M. A., … Mann, J. J. (2011). The Columbia-Suidde Severity Rating Scale: Initial validity and internal consistency findings from three multisite studies with adolescents and adults. American Journal of Psychiatry, 168(12), 1266–1277. doi:10.1176/appi.ajp.2011.10111704 22193671
Post, L. M., Feeny, N. C., Zoellner, L. A., & Connell, A. M. (2016) . Post-traumatic stress disorder and depression co-occurrence: Structural relations among disorder constructs and trait and symptom dimensions. Psychology and Psychotherapy, 89(4), 418–434. doi:10.1111/papt.12087 26643451
Powell, D. J., & Brodsky, A. (2004). Clinical supervision in alcohol and drug abuse counseling: Principles, models, methods (Revised ed.).San Francisco: Jossey-Bass.
Priester, M. A., Browne, T., lachini, A., Clone, S., DeHart, D., & Seay, K. D. (2016). Treatment access barriers and disparities among individuals with co-occurring mental health and substance use disorders: An integrative literature review. Journal of Substance Abuse Treatment, 61, 47–59. doi:10.1016/j.jsat.2015.09.006 26531892
Pringle, J., Grasso, K., & Lederer, L. (2017). Integrating the integrated: Merging Integrated Dual Diagnosis Treatment (IDDT) with Housing First. Community Mental Health Journal, 53(6), 672–678. doi:10.1007/s10597-017-0107-x 28185135
Pringsheim, T., & Gardner, D. M. (2014). Dispensed prescriptions for quetiapine and other second-generation antipsychotics in Canada from 2005 to 2012: A descriptive study. CMAJ Open, 2(4), e225–e232. doi:10.9778/cmajo.20140009
Prins, A., Bovin, M. J., Kimerling, R., Kaloupek, D. G., Marx, B. R., Pless Kaiser, A., & Schnurr, R R (2015). Primary Care PTSD Screen for DSM-5 (PC-PTSD-5) [Measurement instrument]. Retrieved from www.ptsd.va.gov/professional/assessment/documents/pc-ptsd5-screen.pdf
Prins, A., Bovin, M. J., Smolenski, D. J., Marx, B. P., Kimerling, R., Jenkins-Guarnieri, M. A., … Tiet, Q. Q. (2016). The Primary Care PTSD Screen for DSM-5 (PC-PTSD-5): Development and evaluation within a veteran primary care sample. Journal of General Internal Medicine, 31(10), 1206–1211. doi:10.1007/s11606-016-3703-5 27170304
Prins, S. J. (2014). Prevalence of mental illnesses in US state prisons: A systematic review. Psychiatric Services, 65(7), 862–872. doi:10.1176/appi.ps.201300166 24686574
Prochaska, J. J., Sung, H. Y., Max, W., Shi, Y, & Ong, M. (2012). Validity study of the K6 scale as a measure of moderate mental distress based on mental health treatment need and utilization. International Journal of Methods in Psychiatric Research, 21(2), 88–97. doi:10.1002/mpr.1349 22351472
Prochaska, J. O., & DiClemente, C. C. (1992). Stages of change in the modification of problem behaviors. Progress in Behavior Modification, 28, 183–218.1620663
Prochaska, J. O., DiClemente, C. C., & Norcross, J. C. (1992). In search of how people change: Applications to addictive behaviors. American Psychologist, 47(9), 1102–1114.1329589
Proctor, S. L., & Herschman, P. L. (2014). The continuing care model of substance use treatment: What works, and when is “enough,” “enough?” Psychiatry Journal, 692423. doi:10.1155/2014/692423
Puntis, S., Rugkåsa, J., Forrest, A., Mitchell, A., & Burns, T. (2015). Associations between continuity of care and patient outcomes in mental health care: A systematic review. Psychiatric Services, 66(4), 354–363.25828980
Quinn, K., Boone, L., Scheidell, J. D., Mateu-Gelabert, R., McGorray, S. R., Beharie, N. … Khan, M. R. (2016). The relationships of childhood trauma and adulthood prescription pain reliever misuse and injection drug use. Drug and Alcohol Dependence, 169, 190–198. doi:10.1016/j.drugalcdep.2016.09.021 27816251
Raza, G. T., DeMarce, J. M., Lash, S. J., & Parker, J. D. (2014). Paranoid personality disorder in the United States: The role of race, illicit drug use, and income. Journal of Ethnic Substance Abuse, 13(3), 247–257. doi:10.1080/15332640.2013.850463
Regnart, J., Truter, I., & Meyer, A. (2017). Critical exploration of co-occurring attention-deficit/hyperactivity disorder, mood disorder and substance use disorder. Expert Review of Pharmacoeconomics & Outcomes Research, 17(3), 275–282. doi:10.1080/14737167.2017.1351878 28686107
Reif, A. S., Braude, L., Lyman, D. R., Dougherty, R. H., Daniels, S., Chose, S. S., … Delphin-Rittmon, M. E. (2014). Peer recovery support for individuals with substance use disorders: Assessing the evidence. Psychiatric Services, 65(7), 853–861. doi:10.1176/appi.ps.201400047 24838535
Reif, S., George, R., Braude, L., Dougherty, R. H., Daniels, A. S., Chose, S. S., & Delphin-Rittrnon, M. E. (2014). Residential treatment for individuals with substance use disorders: assessing the evidence. Psychiatric Services, 65(3), 301–312. doi:10.1176/appi.ps.201300242 24445598
Reingle Gonzalez, J. M., & Connell, N. M. (2014). Mental health of prisoners: Identifying barriers to mental health treatment and medication continuity. American Journal of Public Health, 704(12), 2328–2333. doi:10.2105/AJPH.2014.302043
Ries, R. K. (1993). The dually diagnosed patient with psychotic symptoms. Journal of Addictive Diseases, 12(3), 103–122. doi:10.1300/J069v12n03_09 8251538
Riper, H., Andersson, G., Hunter, S. B., de Wit, J., Berking, M., & Cuijpers, P. (2014). Treatment of comorbid alcohol use disorders and depression with cognitive-behavioural therapy and motivational interviewing: A meta-analysis. Addiction, 109(3), 394^06. doi:10.1111/add.12441 24304463
Ritschel, L. A., Lim, N. E., & Stewart, L. M. (2015). Transdiagnostic applications of DBT for adolescents and adults. American Journal of Psychotherapy, 69(2), 111–128. doi:10.1176/appi.psychotherapy.2015.69.2.111 26160618
Ritter, S., & Platt, L. M. (2016). What's new in treating inpatients with personality disorders?: Dialectical behavior therapy and old-fashioned, good communication. Journal of Psychosocial Nursing and Mental Health Services, 54(1), 38–45. doi:10.3928/02793695-20151216-03
Roberts, N. P., Roberts, P. A., Jones, N., & Bisson, J. I. (2016). Psychological therapies for post-traumatic stress disorder and comorbid substance use disorder. Cochrane Database of Systematic Reviews, 4, CD010204. doi:10.1002/14651858.CD010204.pub2 27040448
Rog, D. J., Marshall, T., Dougherty, R. H., George, P., Daniels, A. S., Chose, S. S., & Delphin-Rittrnon, M. E. (2014). Permanent supportive housing: Assessing the evidence. Psychiatric Services, 65(3), 287–294. doi:10.1176/appi.ps.201300261 24343350
Rojas, E. C., & Peters, R. H. (2015). Evidence-based practices for co-occurring disorders in offenders. Addiction Research & Theory, 24(3), 223–235.
Romano, M., & Peters, L. (2015). Evaluating the mechanisms of change in motivational interviewing in the treatment of mental health problems: A review and meta-analysis. Clinical Psychology Review, 38, 1–12. doi:10.1016/j.cpr.2015.02.008 25779459
Root, T. L., Pinheiro, A. P., Thornton, L., Straber, M., Fernandez-Aranda, E., Brandt, H., … Bulik, C. M. (2010). Substance use disorders in women with anorexia nervosa. International Journal of Eating Disorders, 43(1), 14–21. doi:10.1002/eat.20670 19260043
Rosenblum, A., Matusow, H., Fong, C., Vogel, H., Uttaro, T., Moore, T. L., & Magura, S. (2014). Efficacy of dual focus mutual aid for persons with mental illness and substance misuse. Drug and Alcohol Dependence, 135, 78–87. doi:10.1016/j.drugalcdep.2013.11.012 24342419
Rosenthal, R. J. (1992). Pathological gambling. Psychiatric Annals, 22(2), 72–78. doi:10.3928/0048-5713-19920201-09
Ross, L. E., & Dennis, C. L. (2009). The prevalence of postpartum depression among women with substance use, an abuse history, or chronic illness: A systematic review. Journal of Women's Health, 78(4), 475–486. doi:10.1089/jwh.2008.0953
Roush, S., Monica, C., Carpenter-Song, E., & Drake, R. E. (2015). First-person perspectives on Dual Diagnosis Anonymous (DDA): A qualitative study. Journal of Dual Diagnosis, 77(2), 136–141. doi:10.1080/15504263.2015.1025215
Rowe, J. (2012). Great expectations: A systematic review of the literature on the role of family carers in severe mental illness, and their relationships and engagement with professionals. Journal of Psychiatric and Mental Health Nursing, 79(1), 70–82. doi:10.1111/j.1365-2850.2011.01756.x
Rubinsky, A. D., Ellerbe, L. S., Gupta, S., Phelps, T. E., Bowe, T., Burden, J. L, & Harris, A. H. S. (2017). Outpatient continuing care after residential substance use disorder treatment in the US Veterans Health Administration: Facilitators and challenges. Substance Abuse, 39(3), 322–330. doi:10.1080/08897077.2017.1391923 29043947
Ruglass, L. M., Lopez-Castro, T., Papini, S., Killeen, T., Back, S. E., & Hien, D. A. (2017). Concurrent treatment with prolonged exposure for co-occurring full or subthreshold posttraumatic stress disorder and substance use disorders: A randomized clinical trial. Psychotherapy and Psychosomatics, 86(3), 150–161. doi:10.1159/000462977 28490022
Ruglass, L. M., Miele, G. M., Hien, D. A., Campbell, A. N., Hu, M. C., Caldeira, N., Nunes, E. V. (2012). Helping alliance, retention, and treatment outcomes: A secondary analysis from the NIDA Clinical Trials Network Women and Trauma Study. Substance Use & Misuse, 47(6), 695–707. doi:10.3109/10826084.2012.659789 22475068
Ruiz, M. A., Douglas, K. S., Edens, J. F., Nikolova, N. L., & Lilienfeld, S. O. (2012). Co-occurring mental health and substance use problems in offenders: Implications for risk assessment. Psychological Assessment, 24(1), 77–87. doi:10.1037/a0024623 21787090
Ruiz, M. A., Peters, R. H., Sanchez, G. M., & Bates, J. P. (2009). Psychometric properties of the Mental Health Screening Form III within a metropolitan jail. Criminal Justice and Behavior, 36(6), 607–619. doi:10.1177/0093854809334013
Ruscio, A. M., Hallion, L. S., Lim, C. C. W., Aguilar-Gaxiola, S., Al-Harnzawi, A., Alonso, J., … Scott, K. M. (2017). Cross-sectional comparison of the epidemiology of DSM-5 Generalized Anxiety Disorder across the globe. JAMA Psychiatry, 74(5), 465–475. doi:10.1001/jarnapsychiatry.2017.0056 28297020
Sacks, S., Chaple, M., Sacks, J. Y., McKendrick, K., & Cleland, C. M. (2012). Randomized trial of a reentry modified therapeutic community for offenders with co-occurring disorders: Crime outcomes. Journal of Substance Abuse Treatment, 42(3), 247–259. doi:10.1016/j.jsat.2011.07.011 21943810
Sacks, S., Chaple, M., Sirikantraporn, J., Sacks, J. Y., Knickman, J., & Martinez, J. (2013). Improving the capability to provide integrated mental health and substance abuse services in a state system of outpatient care. Journal of Substance Abuse Treatment, 44(5), 488–493. doi:10.1016/j.jsat.2012.11.001 23317513
Sacks, S., McKendrick, K., Sacks, J. Y, & Cleland, C. M. (2010). Modified therapeutic community for co-occurring disorders: Single investigator meta analysis. Substance Abuse, 31(3), 146–161. doi:10.1080/08897077.2010.495662
Sacks, C. S., McKendrick, K., Vazan, R., Sacks, J. Y, & Cleland, M. (2011). Modified therapeutic community aftercare for clients triply diagnosed with HIV/AIDS and cooccurring mental and substance use disorders. AIDS Care, 23(1 2), 1676–1686. doi:10.1080/09540121.2011.582075 21711215
Sacks, S., & Sacks, J. Y. (2011, February 10). Modified therapeutic community and specialized housing programs for justice-involved individuals with co-occurring mental and substance use disorders illnesses. A presentation at the JMHCP National Training and Technical Assistance Event: Achieving and Communicating Public Health and Safety Outcomes for our Communities. Baltimore, MD.
Saha, S., Chant, D., Welharn, J., & McGrath, J. (2005). A systematic review of the prevalence of schizophrenia. PLoS Medicine, 2(5). doi:10.1371/journal.pmed.0020141
Saloner, B., & Le Cook, B. (2013). Blacks and Hispanics are less likely than whites to complete addiction treatment, largely due to socioeconomic factors. Health Affairs, 32(1), 135–145. doi:10.1377/hlthaff.2011.0983 23297281
Samet, S., Fenton, M. C., Nunes, E., Greenstein, E., Aharonovich, E., & Hasin, D. (2013). Effects of independent and substance-induced major depressive disorder on remission and relapse of alcohol, cocaine and heroin dependence. Addiction, 708(1), 115–123. doi:10.1111/j.1360-0443.2012.04010.x
Samuels, E. A., Bernstein, S. L., Marshall, B. D. L., Krieger, M., Baird, J., & Mello, M. J. (2018). Peer navigation and take-home naloxone for opioid overdose emergency department patients: Preliminary patient outcomes. Journal of Substance Abuse Treatment, 94, 29–34. doi:10.1016/j.jsat.2018.07.013 30243414
Sanchez, K., Ybarra, R., Chapa, T, & Martinez, O. N. (2016). Eliminating behavioral health disparities and improving outcomes for racial and ethnic minority populations. Psychiatric Services, 67(1), 13–15. doi:10.1176/appi.ps.201400581 26325461
Sanchez-Moreno, J., Martinez-Aran, A., & Vieta, E. (2017). Treatment of functional impairment in patients with bipolar disorder. Current Psychiatry Reports, 79(1), 3. doi:10.1007/s11920-017-0752-3
Sansone, R. A., & Sansone, L. A. (2011a). Gender patterns in borderline personality disorder. Innovations in Clinical Neuroscience, 8(5), 16–20.21686143
Sansone, R. A., & Sansone, L. A. (2011b). Substance use disorders and borderline personality. Innovations in Clinical Neuroscience, 8(9), 10–13.
Sansone, R. A., & Sansone, L. A. (2015). Borderline personality in the medical setting. Primary Care Companion for CNS Disorders, 77(3). doi:10.4088/PCC.14r01743
Sarkar, J., & Duggan, C. (2010). Diagnosis and classification of personality disorder: Difficulties, their resolution and implications for practice. Advances in Psychiatric Treatment, 76(5), 388–396. doi:10.1192/apt.16.6.476a
Sarvet, A. L., Wall, M. M., Keyes, K. M., Olfson, M., Cerdá, M., & Hasin, D. S. (2018). Self-medication of mood and anxiety disorders with marijuana: Higher in states with medical marijuana laws. Drug and Alcohol Dependence, 186, 10–15. doi:10.1016/j.drugalcdep.2018.01.009
Savie, M., Best, D., Manning, V., & Lubman, D. I. (2017). Strategies to facilitate integrated care for people with alcohol and other drug problems: A systematic review. Substance Abuse: Treatment, Prevention, and Policy, 72(1). doi:10.1186/s13011-017-0104-7
Schaffer, A., Isometsa, E. T., Tondo, L. H. Moreno, D., Turecki, G., Reis, C., … Yatham, L. N. (2015). International Society for Bipolar Disorders Task Force on Suicide: Meta-analyses and meta-regression of correlates of suicide attempts and suicide deaths in bipolar disorder. Bipolar Disorders, 77(1), 1–16. doi:10.1111/bdi.12271
Schaumberg, K., Welch, E., Breithaupt, L., Hubel, C., Baker, J. H. Munn-Chernoff, M. A Bulik, C. M. (2017). The science behind the Academy for Eating Disorders’ nine truths about eating disorders. European Eating Disorders Review, 25(6), 432–450. doi:10.1002/erv.2553 28967161
Schneier, F. R., Foose, T. E., Hasin, D. S., Heimberg, R. G., Liu, S. M., Grant, B. E, & Blanco, C. (2010). Social anxiety disorder and alcohol use disorder co-morbidity in the National Epidemiologic Survey on Alcohol and Related Conditions. Psychological Medicine, 40(6), 977–988. doi:S003329170999123120441690
Schoenthaler, S. J., Blum, K., Fried, L., Oscar-Berman, M., Giordano, J., Modestino, E. J., & Badgaiyan, R. (2017). The effects of residential dual diagnosis treatment on alcohol abuse. Journal of Systems and Integrative Neuroscience, 3(4). doi:10.15761/jsin.1000169
Schulte, S. J., Meier, P. S., & Stirling, J. (2011). Dual diagnosis clients’ treatment satisfaction - A systematic review. BMC Psychiatry, 77, 64.
Schulz, P. E., & Arora, G. (2015). Depression. Behavioral Neurology and Neuropsychiatry, 21(3), 756–771. doi:10.1212/01.CON.0000466664.35650.b4
Schümm, J. A., & Gore, W. L. (2016). Simultaneous treatment of co-occurring posttraumatic stress disorder and substance use disorder. Current Treatment Options in Psychiatry 3(1), 28–36. doi:10.1007/s40501-016-0071-z
Scott, E. L., & Hulvershorn, L. (2011, September 7). Anxiety disorders with comorbid substance abuse. Psychiatric Times, 28(9), 1–2.
Seal, K. H., Cohen, G., Waldrop, A., Cohen, B. E., Maguen, S., & Ren, L. (2011). Substance use disorders in Iraq and Afghanistan veterans in VA healthcare, 2001-2010: Implications for screening, diagnosis and treatment. Drug and Alcohol Dependence, 776(1-3), 93–101. doi:10.1016/j.drugalcdep.2010.11.027
Selzer, M. L. (1971). The Michigan Alcoholism Screening Test: The quest for a new diagnostic instrument. American Journal of Psychiatry, 727(12), 1653–1658. doi:10.1176/ajp.127.12.1653
Shapiro, B., Coffa, D., & McCance-Katz, E. F. (2013). A primary care approach to substance misuse. American Family Physician, 88(2), 113–121.23939642
Shattock, L., Berry, K., Degnan, A., & Edge, D. (2018). Therapeutic alliance in psychological therapy for people with schizophrenia and related psychoses: A systematic review. Clinical Psychology & Psychotherapy, 25(1), e60–e85. doi:10.1002/cpp.2135 28961352
Sheehan, D. V., Harnett-Sheehan, K., & Raj, B. A. (1996). The measurement of disability. International Clinical Psychopharmacology, 77(Suppl. 3), 89–95.
Sheehan, D. V., Lecrubier, Y., Sheehan, K. H., Amorim, P., Janavs, J., Weiller, E., … Dunbar, G. C. (1998). The Mini-International Neuropsychiatrie Interview (M.I.N.I.): The development and validation of a structured diagnostic psychiatric interview for DSM-IV and ICD-1 0. Journal of Clinical Psychiatry, 59(Suppl. 20), 22–33; quiz 34-57.
Sheehan, L., Nieweglowski, K., & Corrigan, P. (2016). The stigma of personality disorders. Current Psychiatry Reports, 78(1), 1–7. doi:10.1007/s11920-015-0654-1
Shenoy, A., & Appel, J. M. (2017). Safeguarding confidentiality in electronic health records. Cambridge Quarterly of Healthcare Ethics, 26(2), 337–341. doi:10.1017/s0963180116000931 28361730
Esher, L., Siever, L. J., Goodman, M., McNamara, M., Hazlett, A., Koenigsberg, H. W., & New, A. S. (2015). Gender differences in the clinical characteristics and psychiatric comorbidity in patients with antisocial personality disorder. Psychiatry Research, 229(3), 685–689. doi:10.1016/j.psychres.2015.08.022 26296756
Sherman, L. J., Lynch, S. E., Greeno, C. G., & Hoeffel, E. M. (2017, July 11). Behavioral health workforce: Quality assurance practices in substance abuse treatment facilities. SAMHSA CBHSQ report. Retrieved from www.samhsa.gov/data/sites/default/files/report3059/ShortReport-3059.html
Shinn, G., & Brose, M. (2017). Building partnerships and collaboration between housing providers and behavioral health practitioners. Mental Health Association Oklahoma. Retrieved from www.samhsa.gov/sites/default/files/programscampaigns/recoverytopractice/homelessness-3-building-partnerships.pdf
Shionogi Pharma Inc. (2010). KAPVAY (clonidine hydrochloride) extended-release tablets, oral Initial U.S. approval: 1974. Prescribing information. Retrieved from www.accessdata.fda.gov/drugsatfda_docs/label/2010/022331sQ01s002lbl.pdf
Shire US Inc. (Revised February 2013). INTUNIV® (guanfacine) extended-release tablets, for oral use. Initial U.S. approval: 1986 Retrieved from www.accessdata.fda.gov/drugsatfdadocs/label/2013/022037s009lbl.pdf
Simon, R. I., Hales, R. E., & American Psychiatric Publishing. (2012). The American Psychiatric Publishing textbook of suicide assessment and management (2nd ed.). Washington, DC: American Psychiatric Publishing.
Simon, V., Czobor, P., Balint, S., Meszaros, A., & Bitter, I. (2009). Prevalence and correlates of adult attention-deficit hyperactivity disorder: Meta-analysis. British Journal of Psychiatry, 794(3), 204–211. doi:10.1192/bjp.bp.107.048827
Simpson, T. L., Lehavot, K., & Petrakis, I. L. (2017). No wrong doors: Findings from a critical review of behavioral randomized clinical trials for individuals with co-occurring alcohol/drug problems and posttraumatic stress disorder. Alcoholism: Clinical and Experimental Research, 47(4), 681–702. doi:10.1111/acer.13325
Simpson, T. L., Stappenbeck, C. A., Luterek, J. A., Lehavot, K., & Kaysen, D. L. (2014). Drinking motives moderate daily relationships between PTSD symptoms and alcohol use. Journal of Abnormal Psychology, 723(1), 237–247. doi:10.1037/a0035193
Sinha, B. A., Lewis, O., Kumar, R., Yeruva, S. L. H., & Curry, H. (2016). Adult ADHD medications and their cardiovascular implications. Case Reports in Cardiology, 2016, 2343691. doi:10.1155/2016/2343691 27579185
Skinner, H. A. (1982). The Drug Abuse Screening Test. Addictive Behaviors, 7(4), 363–371. doi:10.1016/0306-4603(82)90005-3 7183189
Smelson, D., Farquhar, I., Fisher, W., Pressman, K., Pinals, D. A., Samek, B., … Sawh, L. (2018). Integrating a co-occurring disorders intervention in drug courts: An open pilot trial. Community Mental Health Journal, 55(2), 222–231. doi:10.1007/s10597-018-0255-7 29516336
Smelson, D. A., Zaykowski, H., Guevermont, N., Siegfriedt, J., Sawh, L., Modzelewski, D., … Kane, V. (2016). Integrating permanent supportive housing and cooccurring disorders treatment for individuals who are homeless. Journal of Dual Diagnosis, 12(2), 193–201. doi:10.1080/15504263.2016.1174010 27064939
Smink, F. R. E., van Hoeken, D., & Hoek, H. W. (2013). Epidemiology, course, and outcome of eating disorders. Current Opinion in Psychiatry, 26(6), 543–548. doi:10.1097/YCO.0b013e328365a24f
Smith, D. E. (2012). Editor's note: The medicalization of therapeutic communities in the era of health care reform. Journal of Psychoactive Drugs, 44(2), 93–95. doi:10.1080/02791072.2012.684608 22880536
Smith, J. D., Mittal, D., Chekuri, L., Han, X., & Sullivan, G. (2017) . A comparison of provider attitudes toward serious mental illness across different health care disciplines. Stigma and Health, 2(4), 327–337.
Smith, J. R, & Book, S. W. (2008). Anxiety and substance use disorders: A review. Psychiatric Times, 25(10), 19–23.20640182
Smith, J. R, & Randall, C. L. (2012). Anxiety and alcohol use disorders: Comorbidity and treatment considerations. Alcohol Research, 34(4), 414–431.23584108
Smith, M. W., Stocks, C., & Santora, P. B. (2015). Hospital readmission rates and emergency department visits for mental health and substance abuse conditions. Community Mental Health Journal, 51(2), 190–197. doi:10.1007/s10597-014-9784-x 25563483
Smith, R. J., Jennings, J. L., & Cimino, A. (2010). Forensic continuum of care with Assertive Community Treatment (ACT) for persons recovering from cooccurring disabilities: Long-term outcomes. Psychiatric Rehabilitation Journal, 33(3), 207–218.20061257
Smith, S. M., Goldstein, R. B., & Grant, B. F. (2016). The association between post-traumatic stress disorder and lifetime DSM-5 psychiatric disorders among veterans: Data from the National Epidemiologic Survey on Alcohol and Related Conditions-lll (NESARC III). Journal of Psychiatric Research, 82, 16–22. doi:10.1016/j.jpsychires.2016.06.022 27455424
Sohal, H., Eldridge, S., & Feder, G. (2007). The sensitivity and specificity of four questions (HARK) to identify intimate partner violence: A diagnostic accuracy study in general practice. BMC Family Practice, 8, 49. doi:10.1186/1471-2296-8-49 17727730
Sohn, H. (2017). Racial and ethnic disparities in health insurance coverage: Dynamics of gaining and losing coverage over the life-course. Population Research and Policy Review, 36(2), 181–201. doi:10.1007/s11113-016-9416-y 28366968
Solari, C. D., Morris, S., Shivj'i, A., & Souza, T. D. (2016, October). The 2015 Annual Homeless Assessment Report (AHAR) to Congress. Part 1 - PIT estimates of homelessness in the U.S. Retrieved from https://files.hudexchange.info/resources/documents/2015-AHAR-Part.-1.pdf
Sowers, W. (2016). Level of Care Utilization System for psychiatric and addiction services (LOCUS), Adult version 20. Task Force on Level of Care Determinations of the American Association of Community Psychiatrists (AACP). Dallas, TX: AACP. Retrieved from https://drive.google.com/file/d/0B89glzXJnn4cV1dESWI2eFEzc3M/view
Spinelli, M. A., Ponath, C., Tieu, L., Hurstak, E. E., Guzman, D., & Kushel, M. (2017). Factors associated with substance use in older homeless adults: Results from the HOPE HOME study. Substance Abuse, 38(1), 88–94. doi:10.1080/08897077.2016.1264534 27897965
Stahler, G. J., Mennis, J., & DuCette, J. P. (2016). Residential and outpatient treatment completion for substance use disorders in the U.S.: Moderation analysis by demographics and drug of choice. Addictive Behaviors, 58, 129–135. doi:10.1016/j.addbeh.2016.02.030 26925821
Stefancic, A., Henwood, B. E., Melton, H., Shin, S. M., Lawrence-Gomez, R., &Tsemberis, S. (2013). Implementing housing first in rural areas: Pathways Vermont. American Journal of Public Health, 703(Suppl. 2), S206–S209. doi:10.2105/ajph.2013.301606
Stein, L. I., & Test, M. A. (1980). Alternative to mental hospital treatment: I. Conceptual model, treatment program, and clinical evaluation. Archives of General Psychiatry, 37(4), 392–397.7362425
Sterling, S., Chi, E, & Hinman, A. (2011). Integrating care for people with co-occurring alcohol and other drug, medical, and mental health conditions. Alcohol Research & Health, 33(4), 338–349.23580018
Stice, E., Marti, C. N., & Rohde, P. (2013). Prevalence, incidence, impairment, and course of the proposed DSM-5 eating disorder diagnoses in an 8-year prospective community study of young women. Journal of Abnormal Psychology, 122(2), 445–457. doi:10.1037/a0030679 23148784
Stinson, J. D., Quinn, M. A., & Levenson, J. S. (2016). The impact of trauma on the onset of mental health symptoms, aggression, and criminal behavior in an inpatient psychiatric sample. Child Abuse and Neglect, 61, 13–22. doi:10.1016/j.chiabu.2016.09.005 27693854
Stirman, S. W., Gutner, C. A., Langdon, K., & Graham, J. R. (2016). Bridging the gap between research and practice in mental health service settings: An overview of developments in implementation theory and research. Behavior Therapy, 47(6), 920–936. doi:10.1016/j.beth.2015.12.001 27993341
Stone, D. M., Simon, T. R., Fowler, K. A., Kegler, S. R., Yuan, K., Holland, K. M., … Crosby, A. E. (2018). Vital signs: Trends in state suicide rates — United States, 1999-2016 and circumstances contributing to suicide — 27 states, 2015. Morbidity and Mortality Weekly Report, 67(22), 617–624. doi:10.15585/mmwr.mm6722a1
Stone, E. M., Chen, L. N., Daumit, G. L., Linden, S., & McGinty, E. E. (2019). General medical clinicians’ attitudes toward people with serious mental illness: A scoping review. Journal of Behavioral Health Services & Research, 18. doi:10.1007/S11414-019-09652-w
Stringfellow, E. J., Kim, T. W., Gordon, A. J., Pollio, D. E., Grucza, R. A., Austin, E. L., … Kertesz, S. G. (2016). Substance use among persons with homeless experience in primary care. Substance Abuse, 37(4), 534–541. doi:10.1080/08897077.2016.1145616 26914448
Strom, J. B., Kramer, D. B., Wang, Y., Shen, C., Wasfy, J. H., Landon, B. E., … Yeh, R. W. (2017). Short-term rehospitalization across the spectrum of age and insurance types in the United States. PLoS ONE, 12(7), e0180767. doi:10.1371/journal.pone.0180767 28700736
Subodh, B. N., Sharma, N., & Shah, R. (2018). Psychosocial interventions in patients with dual diagnosis. Indian Journal of Psychiatry, 60(Suppl. 4), S494–S500. doi:10.4103/psychiatry.lndianJPsychiatry_1818 29540920
Substance Abuse and Mental Health Services Administration, (n.d.) Recruitment and Retention Toolkit.
Substance Abuse and Mental Health Services Administration. (2000). Integrating substance abuse treatment and vocational services. Treatment Improvement Protocol (TIP) Series, No. 38. HHS Publication No. (SMA) 12-4216. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2008). Assertive Community Treatment (ACT) Evidence-Based Practices (EBP) KIT. Retrieved from https://store.samhsa.gov/product/Assertive-Communrty-Treatment-ACT-Evldence-Based-Practices-EBP-KIT/sma08-4344
Substance Abuse and Mental Health Services Administration. (2009a). Integrated treatment for cooccurring disorders: training frontline staff. DHHS Pub. No. SMA-08-4366. Rockville, MD: Center for Mental Health Services, Substance Abuse and Mental Health Services Administration, U.S. Department of Health and Human Services.
Substance Abuse and Mental Health Services Administration. (2009b). SAFE-T-Suicide assessment five-step evaluation and triage. Pocket card. Retrieved from https://store.samhsa.gov/system/files/sma09-4432.pdf
Substance Abuse and Mental Health Services Administration. (2009c). Substance abuse treatment: Addressing the specific needs of women. Revised 2013. Treatment Improvement Protocol (TIP) Series 51 (HHS Publication No. (SMA)13-4426). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2011a). Clients with substance use and eating disorders. Advisory, 70(1), 1–11. Retrieved from https://store.samhsa.gov/product/clients-with-substance-use-and-eating-disorders/SMA10-4617
Substance Abuse and Mental Health Services Administration. (2011b). Dual diagnosis capability in mental health treatment toolkit version 4.0. (HHS Publication No. SMA-XX-XXXX). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery. Retrieved from https://store.samhsa.gov/system/files/pepl_2-recdef.pdf
Substance Abuse and Mental Health Services Administration. (2013). Behavioral health services for people who are homeless. (HHS Publication No. (SMA) 13-4734). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2014a). Improving cultural competence. Treatment Improvement Protocol (TIP) Series No. 59 (HHS Publication No. (SMA) 14-4849). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2014b). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. (HHS Publication No. (SMA) 14-4816.). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration (2014c). SAMHSAs concept of trauma and guidance for a trauma-informed approach. HHS Publication No. (SMA) 14-4884. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2014.
Substance Abuse and Mental Health Services Administration. (2015a). Adults with attention deficit hyperactivity disorder and substance use disorders. Advisory 14(3). Retrieved from https://store,samhsa.aov/product/Advisory-Adults-With-Attention-Deficit-Hyperactivity-Disorder-and-Substance-Use-Disorders/SMA15-4925
Substance Abuse and Mental Health Services Administration. (2015b). Screening and assessment of cooccurring disorders in the justice system. (HHS Publication No. (SMA)-1 5-4930). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2015c, March). Women in the mirror: Addressing co-occurring mental health issues and trauma in women with substance use disorders. Retrieved from https://www.samhsa.gov/sites/default/files/programs_campaigns/women_children_families/women-in-mirror.pdf
Substance Abuse and Mental Health Services Administration. (2016). An introduction to bipolar disorder and co-occurring substance use disorders. Advisory, 75(2). Retrieved from https://store.samhsa.gov/svstem/files/sma16-4960.pdf
Substance Abuse and Mental Health Services Administration. (2017). Suicide prevention. Retrieved from https://www.samhsa.gov/suicide-prevention
Substance Abuse and Mental Health Services Administration. (2018a). Behavioral health services for American Indians and Alaska Natives. Treatment Improvement Protocol (TIP) Series 61 (HHS Publication No. (SMA) 18-5070). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2018b). Key substance use and mental health indicators in the United States: Results from the 2017 National Survey on Drug Use and Health (HHS Publication No. SMA 18-5068, NSDUH Series H-53). Rockville, MD: Center for Behavioral Health Statistics and Quality, Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2018c). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63 (HHS Publication No. (SMA) 18-5063FULLDOC). Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2018d). National Mental Health Services Survey (N-MHSS): 2017. Data on mental health treatment facilities. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2018e). National Survey of Substance Abuse Treatment Services (N-SSATS): 2017. Data on substance abuse treatment facilities. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2019a). National Survey of Substance Abuse Treatment Services (N-SSATS): 2018. Data on substance abuse treatment facilities. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2019b). National Mental Health Services Survey (N-MHSS): 2018. Data on mental health treatment facilities. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2019c). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. (SAMHSA Publication No. PEP19-02-01-003). Rockville, MD: Center for Substance Abuse Treatment.
Substance Abuse and Mental Health Services Administration. (2019d). Mental health annual report: 2017. Use of mental health services: National client level data. Rockville, MD: Center for Behavioral Health Statistics and Quality.
Substance Abuse and Mental Health Services Administration, Center for Behavioral Health Statistics and Quality. (2017). Treatment Episode Data Set (TEDS): 2005-2015. National admissions to substance abuse treatment services. BHSIS Series S-91, HHS Publication No. (SMA) 17-5037. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration, Center for Behavioral Health Statistics and Quality. (2019). Treatment Episode Data Set (TEDS): 2017. Admissions to and discharges from publicly-funded substance use treatment. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Sullivan, J. T., Sykora, K., Schneiderman, J., Naranjo, C. A., & Sellers, E. M. (1989). Assessment of alcohol withdrawal: The revised Clinical Institute Withdrawal Assessment for Alcohol scale (CIWA-Ar). British Journal of Addiction, 84(11), 1353–1357.2597811
Sun, A. P. (2012). Helping homeless individuals with cooccurring disorders: The four components. Social Work, 57(1), 23–37.22768626
Sung, Y. K., La Flair, L. N., Mojtabai, R., Lee, L. C., Spivak, S., & Crum, R. M. (2016). The association of alcohol use disorders with suicidal ideation and suicide attempts in a population-based sample with mood symptoms. Archives of Suicide Research, 20(2), 219–232. doi:10.1080/13811118.2015.1004489 25933091
Swann, A. C. (2010). The strong relationship between bipolar and substance-use disorder. Annals of the New York Academy of Sciences, 1187, 276–293. doi:10.1111/j.1749-6632.2009.05146.x 20201858
Swopes, R. M., Davis, J. L., & Scholl, J. A. (2017). Treating substance abuse and trauma symptoms in incarcerated women: An effectiveness study. Journal of Interpersonal Violence, 32(7), 1143–1165. doi:10.1177/0886260515587668 26058977
Szaflarski, M., Bauldry, S., Cubbins, L. A., & Meganathan, K. (2017). Nativity, race-ethnicity, and dual diagnosis among US adults. Research in the Sociology of Health Care, 35, 171–191.29147063
Tang, Z., Claus, R. E., Orwin, R. G., Kissin, W. B., & Arieira, (2012). Measurement of gender-sensitive treatment for women in mixed-gender substance abuse treatment programs. Drug and Alcohol Dependence, 723(1-3), 160–166. doi:10.1016/j.drugalcdep.2011.11.003
Taylor, O. D. (2010). Barriers to treatment for women with substance use disorders. Journal of Human Behavior in the Social Environment, 20(3), 393–409. doi:10.1080/10911351003673310
Teeters, J. B., Lancaster, C. L., Brown, D. G., & Back, S. E. (2017). Substance use disorders in military veterans: Prevalence and treatment challenges. Substance Abuse and Rehabilitation, 8, 69–77. doi:10.2147/sar.S116720 28919834
Test, M. A. (1992). Training in community living. In R. P. Lieberrnan (Ed.), Handbook of psychiatric rehabilitation (pp. 153–170). New York, NY: MacMillan Publishing.
Thiel, N., Hertenstein, E., Nissen, C., Herbst, N., Külz, A. K., & Voderholzer, U. (2013). The effect of personality disorders on treatment outcomes in patients with obsessive-compulsive disorders. Journal of Personality Disorders, 27(6), 697–715. doi:10.1521/pedi_201327104 23795757
Thomson, M., & Sharma, V. (2017). Therapeutics of postpartum depression. Expert Review of Neurotherapeutics, 17(5), 495–507. doi:10.1080/14737175.2017.1265888 27892736
Thronson, L. R., & Pagalilauan, G. L. (2014). Psychopharmacology. Medical Clinics of North America, 98(5), 927–958. doi:10.1016/j.mcna.2014.06.001 25134867
Thurber, S., Wilson, A., Realmuto, G., & Specker, S. (2018). The relationship between the INTERMED patient complexity instrument and Level of Care Utilisation System (LOCUS). International Journal of Psychiatry in Clinical Practice, 22(1), 80–82. doi:10.1080/13651501.2017.1353635 28691596
Tiet, Q. Q., & Schutte, K. K. (2012). Treatment setting and outcomes of patients with co-occurring disorders. Journal of Groups in Addiction & Recovery, 7(1), 53–76. doi:10.1080/1556035X.2012.632330
Timko, C., Sutkowi, A., & Moos, R. (2010). Patients with dual diagnoses or substance use disorders only: 12-step group participation and 1-year outcomes. Substance Use & Misuse, 45(4), 613–627. doi:10.3109/10826080903452421 20141467
Tolliver, B. K., & Anton, R. F. (2015). Assessment and treatment of mood disorders in the context of substance abuse. Dialogues in Clinical Neuroscience, 17(2), 181–190.26246792
Tonigan, J. S., Pearson, M. R., Magill, M., & Hagler, K. J. (2018). AA attendance and abstinence for dually diagnosed patients: A meta-analytic review. Addiction, 773(11), 1970–1981. doi:10.1111/add.14268
Trivedi, R. B., Post, E. P., Sun, H., Pomerantz, A., Saxon, A. J., Piette, J. D., … Nelson, K. (2015). Prevalence, comorbidity, and prognosis of mental health among US veterans. American Journal of Public Health, 705(12), 2564–2569. doi:10.2105/ajph.2015.302836
Trudeau, K. J., Burtner, J., Villapiano, A. J., Jones, M., Butler, S. R, & Joshi, K. (2018). Burden of schizophrenia or psychosis-related symptoms in adults undergoing substance abuse evaluation. Journal of Nervous and Mental Disease, 206(7), 528–536. doi:10.1097/NMD.0000000000000835 29905667
Trull, T. J., Freeman, L. K., Vebares, T. J., Choate, A. M., Helle, A. C. & Wycoff, A. M. (2018). Borderline personality disorder and substance use disorders: An updated review. Borderline Personality Disorder and Emotion Dysregulation, 5, 15. doi:10.1186/S40479-018-0093-9 30250740
Trull, T. J., Jahng, S., Tomko, R. L., Wood, P. K., & Sher, K. J. (2010). Revised NESARC personality disorder diagnoses: Gender, prevalence, and comorbidity with substance dependence disorders. Journal of Personality Disorders, 24(4), 412–426. doi:10.1521/pedi.2010.24.4.412 20695803
Tsai, J. (2018). Lifetime and 1-year prevalence of homelessness in the US population: Results from the National Epidemiologic Survey on Alcohol and Related Conditions-lll. Journal of Public Health (Oxford, England), 40(1), 65–74. doi:10.1093/pubmed/fdx034
Tsai, J., & Cao, X. (2019). Association between suicide attempts and homelessness in a population-based sample of US veterans and non-veterans. Journal of Epidemiology and Community Health, 73(4), 346–352. doi:10.1136/jech-2018-211065 30602531
Tsai, J., Kasprow, W. J., & Rosenheck, R. A. (2014). Alcohol and drug use disorders among homeless veterans: Prevalence and association with supported housing outcomes. Addictive Behaviors, 39(2), 455–460. doi:10.1016/j.addbeh.2013.02.002 23490136
Tsai, J., Lee, C. Y. S., Byrne, T., Pietrzak, R. H., & Southwick, S. M. (2017). Changes in public attitudes and perceptions about homelessness between 1990 and 2016. American Journal of Community Psychology, 60(3-4), 599–606. doi:10.1002/ajcp.12198 29027669
Tsai, J., & Rosenheck, R. A. (2012). Outcomes of a group intensive peer-support model of case management for supported housing. Psychiatric Services, 63(12), 1186–1194.22983658
Tsemberis, S., & Eisenberg, R. F. (2000). Pathways to housing: Supported housing for street-dwelling homeless individuals with psychiatric disabilities. Psychiatric Services, 51(4), 487^(93. doi:10.1176/appi.ps.51.4.487 10737824
Tsemberis, S. J. (2010). Housing First: The Pathways model to end homelessness for people with mental health and substance use disorders. Center City, Minnesota: Hazelden Publishing.
Tsemberis, S. J., Moran, L., Shinn, M., Asmussen, S. M., & Shern, D. L. (2003). Consumer preference programs for individuals who are homeless and have psychiatric disabilities: A drop-in center and a supported housing program. American Journal of Community Psychology, 32(3-4), 305–317.14703266
Turner, S. B., & Stanton, M. P. (2015). Psychiatric case management in the emergency department. Professional Case Management, 20(5), 217–227; quiz 228-219. doi:10.1097/ncm.0000000000000106 26241620
Tyrer, R., Sharfstein, S., O'Reilly, R., Allison, S., & Bastiampillai, T. (2017). Psychiatric hospital beds: An Orwellian crisis. Lancet, 389(10067), 363. doi:10.1016/s0140-6736(17)30149-6
U.S. Department of Health and Human Services (HHS) Office of the Surgeon General and National Action Alliance for Suicide Prevention. (2012, September). 2012 National Strategy for Suicide Prevention: Goals and objectives for action. Washington, DC: HHS.
U.S. Department of Health and Human Services, Office of the Surgeon General. (2016, November). Facing Addiction in America: The Surgeon General's Report on Alcohol, Drugs, and Health. Washington, DC: HHS.
U.S. Department of Housing and Urban Development. (2018). 2018 Continuum of Care Homeless Populations and Subpopulations Report - All states, territories, Puerto Rico, and DC. Washington, DC: Author. Retrieved May 29, 2018, from https://files.hudexchange.info/reports/published/CoC_PopSub_NatITerrDC_2018.pdf
U.S. Interagency Council on Homelessness. (2014, June). Implementing Housing First in Permanent Supportive Housing. Fact Sheet from USICH with assistance from the Substance Abuse and Mental Health Services Administration. Retrieved from www.usich.gov/resources/uploads/assetlibrary/lmplementingHousingFirstinPermanentSupportiveHousing.pdf
U.S. Preventive Services Task Force (USPTSF). (2013). Archived: Intimate partner violence and abuse of elderly and vulnerable adults: Screening. Retrieved from www.uspreventiveservicestaskforce.org/Page/Document/UpdateSummaryFinal/intimate-partner-violence-and-abuse-of-elderlv-and-vulnerable-adults-screening
Udo, T., & Grilo, C. M. (2018). Prevalence and correlates of DSM-5-defined eating disorders in a nationally representative sample of U.S. adults. Biological Psychiatry, 84(5), 345–354. doi:10.1016/j.biopsych.2018.03.014 29859631
Ullman, S. E., Relyea, M., Peter-Hagene, L., & Vasquez, A. K. (2013). Trauma histories, substance use coping, PTSD, and problem substance use among sexual assault victims. Addictive Behaviors, 38(6), 2219–2223. doi:10.1016/j.addbeh.2013.01.027 23501138
University of Michigan Behavioral Health Workforce Research Center. (2018). Scopes of practice and reimbursement patterns of addiction counselors, community health workers, and peer recovery specialists in the behavioral health workforce. Ann Arbor, Ml: University of Michigan School of Public Health.
Upshur, C. C., Jenkins, D., Weinreb, L., Gelberg, L, & Orvek, E. A. (2017). Prevalence and predictors of substance use disorders among homeless women seeking primary care: An 11 site survey. American Journal of Addictions, 26(7), 680–688. doi:10.1111/ajad.12582
Üstün, T. B., & World Health Organization. (2010). Measuring health and disability: Manual for WHO Disability Assessment Schedule WHODAS 2.0. Geneva: World Health Organization.
Vallejo, Z., & Amaro, H. (2009). Adaptation of mindfulness-based stress reduction program for addiction relapse prevention. The Humanistic Psychologist, 37(2), 192–206. doi:10.1080/08873260902892287
van de Glind, G., Van Emmerik-van Oortmerssen, K., Carpentier, P. J., Levin, F. R., Koeter, M. W. J., Barta, C., … van den Brink, W. (2013). The International ADHD in Substance Use Disorders Prevalence (IASP) study: Background, methods and study population. International Journal of Methods in Psychiatric Research, 22(3), 232–244.24022983
Vanderplasschen, W., Colpaert, K., Autrique, M., Rapp, R. C., Pearce, S., Broekaert, E., & Vandevelde, S. (2013). Therapeutic communities for addictions: A review of their effectiveness from a recovery-oriented perspective. Scientific World Journal, 13, 427817. doi:10.1155/2013/427817
Vanderwaal, F. M. (2015). Impact of motivational interviewing on medication adherence in schizophrenia. Issues in Mental Health Nursing, 36(11), 900–904. doi:10.3109/01612840.2015.1058445 26631862
van Emmerik-van Oortmerssen, K., van de Glind, G., van den Brink, W., Smit, F., Crunelle, C. L., Swets, M., & Schoevers, R. A. (2012). Prevalence of attention-deficit hyperactivity disorder in substance use disorder patients: A meta-analysis and meta-regression analysis. Drug and Alcohol Dependence, 722(1-2), 11–19. doi:10.1016/j.drugalcdep.2011.12.007
Vega, W. A., Canino, G., Cao, Z., & Alegría, M. (2009). Prevalence and correlates of dual diagnoses in U.S. Latinos. Drug and Alcohol Dependence, 700(1-2), 32–38. doi:10.1016/j.drugalcdep.2008.08.018
Verges, A., Jackson, K. M., Bucholz, K. K., Trull, T. J., Lane, S. P., & Sher, K. J. (2014). Personality disorders and the persistence of substance use disorders: A reanalysis of published NESARC findings. Journal of Abnormal Psychology, 123(4), 809–820. doi:10.1037/abn0000011 25314264
Vest, B. M., Hoopsick, R. A., Homish, D. L., Daws, R. C., & Hornish, G. G. (2018). Childhood trauma, combat trauma, and substance use in National Guard and reserve soldiers. Substance Abuse, 39(4), 452–460. doi:10.1080/08897077.2018.1443315 29485365
Veterans Administration/Department of Defense (VA/DoD). (2015). VA/DoD clinical practice guideline for the management of substance use disorders. Version 3.0. Retrieved from www.healthquality.va.gov/guidelines/MIH/sud/VADoDSUDCPGRevised22216.pdf
Veterans Administration/Department of Defense. (2017). VA/DoD clinical practice guideline for the management of posttraumatic stress disorder and acute stress disorder. Version 3.0. Retrieved from www.healthquality.va.gov/guidelines/MH/ptsd/VADoDPTSDCPGFinal012418.pdf
Vigod, S. N., Wilson, C. A., & Howard, L. M. (2016). Depression in pregnancy. BMJ (Online), 352. doi:10.1136/bmj.i1547
Volkert, J., Gablonski, T.-C., & Rabung, S. (2018). Prevalence of personality disorders in the general adult population in Western countries: Systematic review and metaanalysis. British Journal of Psychiatry, 213(6), 709–715. doi:10.1192/bjp.2018.202
Volpi-Abadie, J., Kaye, A. M., & Kaye, A. D. (2013). Serotonin syndrome. Ochsner Journal, 13(4), 533–540.24358002
Vorspan, F., Mehtelli, W., Dupuy, G., Bloch, V, & Lépine, J. P. (2015). Anxiety and substance use disorders: Cooccurrence and clinical issues. Current Psychiatry Reports, 17(2). doi:10.1007/s11920-014-0544-y
Vrana, C., Killeen, T., Brant, V., Mastrogiovanni, J., & Baker, N. L. (2017). Rationale, design, and implementation of a clinical trial of a mindfulness-based relapse prevention protocol for the treatment of women with comorbid post traumatic stress disorder and substance use disorder. Contemporary Clinical Trials, 61, 108–114. doi:10.1016/j.cct.2017.07.024 28765006
Vujanovic, A. A., Bonn-Miller, M. O., & Petry, N. M. (2016). Co-occurring posttraumatic stress and substance use: Emerging research on correlates, mechanisms, and treatments—Introduction to the special issue. Psychology of Addictive Behaviors, 30(7), 713–719. doi:10.1037/adb0000222 27786510
Vujanovic, A. A., Meyer, T. D., Heads, A. M., Stotts, A. L., Villarreal, Y. R., & Schmitz, J. M. (2017). Cognitive-behavioral therapies for depression and substance use disorders: An overview of traditional, third-wave, and transdiagnostic approaches. American Journal of Drug and Alcohol Abuse, 43(4), 402–415. doi:10.1080/0095299O.2016.1199697 27494547
Vujanovic, A. A., Smith, L. J., Green, C. E., Lane, S. D., & Schmitz, J. M. (2018). Development of a novel, integrated cognitive-behavioral therapy for co-occurring posttraumatic stress and substance use disorders: A pilot randomized clinical trial. Contemporary Clinical Trials, 65, 123–129. doi:10.1016/j.cct.2017.12.013 29287668
Wakeman, S. E., Rigotti, N. A., Chang, Y., Herman, G. E., Erwin, A., Regan, S., & Metlay, J. P. (2019). Effect of integrating substance use disorder treatment into primary care on inpatient and emergency department utilization. Journal of General Internal Medicine. 34(6), 871–877. doi:10.1007/s11606-018-4807-x 30632103
Walley, A. Y., Palmisano, J., Sorensen-Alawad, A., Chaisson, C., Raj, A., Samet, J. H., & Drainoni, M. L. (2015). Engagement and substance dependence in a primary care-based addiction treatment program for people infected with HIV and people at high-risk for HIV infection. Journal of Substance Abuse Treatment, 59, 59–66. doi:10.1016/j.jsat.2015.07.007 26298399
Walsh, F. P. & Tickle, A. C. (2013). Working towards recovery: The role of employment in recovery from serious mental health problems: A qualitative metasynthesis. International Journal of Psychosocial Rehabilitation, 17(2) 35–49.
Walsh, K., McLaughlin, K. A., Hamilton, A., & Keyes, K. M. (2017). Trauma exposure, incident psychiatric disorders, and disorder transitions in a longitudinal population representative sample. Journal of Psychiatric Research, 92, 212–218. doi:10.1016/j.jpsychires.2017.05.001 28531836
Walter, K. H., Levine, J. A., Highfill-McRoy, R. M., Navarro, L., & Thomsen, C. J. (2018). Prevalence of posttraumatic stress disorder and psychological comorbidities among U.S. active duty service members, 2006-2013. Journal of Traumatic Stress, 31(6), 837–844. doi:10.1002/jts.22337 30398680
Walton, M. T, & Hall, M. T. (2016).). The effects of employment interventions on addiction treatment outcomes: A review of the literature. Journal of Social Work Practice in the Addictions, 16(4), 358–384.
Watkins, K. E., Hunter, S., Hepner, K., Paddock, S., Zhou, A., & de la Cruz, E. (2012). Group cognitive-behavioral therapy for clients with major depression in residential substance abuse treatment. Psychiatric Services, 63(6), 608–611. doi:10.1176/appi.ps.201100201 22638007
Watkins, L. E., Sippel, L. M., Pietrzak, R. H., Hoff, R., & Harpaz-Rotem, I. (2017). Co-occurring aggression and suicide attempt among veterans entering residential treatment for PTSD: The role of PTSD symptom clusters and alcohol misuse. Journal of Psychiatric Research, 87, 8–14. doi:10.1016/j.jpsychires.2016.12.009 27984702
Watson, D. P., Orwat, J., Wagner, D. E., Shuman, V, & Tolliver, R. (2013). The Housing First Model (HFM) fidelity index: Designing and testing a tool for measuring integrity of housing programs that serve active substance users. Substance Abuse Treatment, Prevention, and Policy, 8, 16. doi:10.1186/1747-597x-8-16 23641860
Waye, K. M., Goyer, J., Dettor, D., Mahoney, L., Samuels, E. A., Yedinak, J. L, & Marshall, B. D. L (2019). Implementing peer recovery services for overdose prevention in Rhode Island: An examination of two outreach-based approaches. Addictive Behaviors, 89, 85–91. doi:10.1016/j.addbeh.2018.09.027 30278306
Weathers, F. W., Litz, B. T., Keane, T. M., Palmieri, P. A., Marx, B. R, & Schnurr, P. P. (2013). The PTSD Checklist for DSM-5 (PCL-5) - Standard. Retrieved October 15, 2019, from www.ptsd.va.gov/professional/assessment/docurnents/PCL5Standardform.PDF
Weaver, N., Coffey, M., & Hewitt, J. (2017). Concepts, models and measurement of continuity of care in mental health services: A systematic appraisal of the literature. Journal of Psychiatric and Mental Health Nursing, 24(6), 431–450. doi:10.1111/jpm.12387 28319308
Weil, T. P. (2015). Insufficient dollars and qualified personnel to meet United States mental health needs. Journal of Nervous and Mental Disease, 203(4), 233–240.25816044
Weinstein, Z. M., Wakernan, S. E., & Nolan, S. (2018). Inpatient addiction consult service: Expertise for hospitalized patients with complex addiction problems. Medical Clinics of North America, 102(4), 587–601. doi:10.1016/j.mena.2018.03.001
Weiss, R. D., & Connery, H. S. (2001). Integrated group therapy for bipolar disorder and substance abuse. New York, NY: Guilford Press.
Werner, F. M., & Covenas, R. (2017). Long-term administration of antipsychotic drugs in schizophrenia and influence of substance and drug abuse on the disease outcome. Current Drug Abuse Reviews, 70(1), 19–24. doi:10.2174/1874473710666171020104524
Westmoreland, R., Krantz, M. J., & Mehler, P. S. (2016). Medical complications of anorexia nervosa and bulimia. American Journal of Medicine, 729(1), 30–37. doi:10.1016/j.arnjrned.2015.06.031
White, A. R. (2011). Characteristics of three consumer cohorts in vocational rehabilitation: A comparison of consumers with dual-diagnosis, psychiatric, or substance use related disorders. Journal of Applied Rehabilitation Counseling, 42(1), 15–24.
White, L. M., McGrew, J. H., Salyers, M. R, & Firmin, R. L. (2014). Assertive community treatment for parents with serious mental illnesses: A comparison of “parent-sensitive” assertive community treatment teams versus other teams. Psychiatric Rehabilitation Journal, 37(3), 251–260. doi:10.1037/prj0000050 24564344
WHO ASSIST Working Group. (2002). The Alcohol, Smoking and Substance Involvement Screening Test (ASSIST): Development, reliability and feasibility. Addiction, 97(9), 1183–1194.12199834
Wile, M., & Goodwin, K. (2018, February). The costs and consequences of disparities in behavioral health care. National Conference of State Legislatures. Retrieved from http://www.ncsl.org/research/health/the-costs-and-consequences-of-disparities-in-behavioral-health-care.aspx
Wilens, T., Zulauf, C., Marteion, M., Morrison, N. R., Simon, A., Camellas, N. W., … Anselmo, R. (2016). Nonmedical stimulant use in college students: Association with attention-deficit/hyperactivity disorder and other disorders. Journal of Clinical Psychiatry, 77(7), 940–947. doi:10.4088/JCP.14rn09559
Wilens, T. E., Adler, L. A., Tanaka, Y., Xiao, R., D'Souza, D. M., Gutkin, S. W., & Upadhyaya, H. P. (2011). Correlates of alcohol use in adults with ADHD and comorbid alcohol use disorders: Exploratory analysis of a placebo-controlled trial of atornoxetine. Current Medical Research and Opinion, 27(12), 2309–2320. doi:10.1185/03007995.2011.628648 22029549
Wilens, T. E., & Morrison, N. R. (2011). The intersection of attention-deficit/hyperactivity disorder and substance abuse. Current Opinion in Psychiatry, 24(4), 280–285. doi:10.1097/YCO.0b013e328345c956 21483267
Wilkerson, A. H., Hackman, C. L., Rush, S. E., Usdan, S. L., & Smith, C. S. (2017). “Drunkorexia”: Understanding eating and physical activity behaviors of weight conscious drinkers in a sample of college students. Journal of American College Health, 65(7), 492–501. doi:10.1080/07448481.2017.1344848 28641040
Willison, C. (2017). Shelter from the storm: Roles, responsibilities, and challenges in United States housing policy governance. Health Policy, 121, 1113–1123.28851590
Wise, E. A. (2010). Evidence-based effectiveness of a private practice intensive outpatient program with dual diagnosis patients. Journal of Dual Diagnosis, 6(1), 25–45. doi:10.1080/15504260903498862
Wisner, K. L., Sit, D. K. Y., McShea, M. C., Rizzo, D. M., Zoretich, R. A., Hughes, C. L., … Hanusa, B. H. (2013). Onset timing, thoughts of self-harm, and diagnoses in postpartum women with screen-positive depression findings. JAMA Psychiatry, 70, 490–498.23487258
Wittchen, H. U. (2010). Screening for serious mental illness: Methodological studies of the K6 screening scale. International Journal of Methods in Psychiatric Research, 79(Supp I.1), 1–3. doi:10.1002/mpr.316
Wittchen, H. U., Gloster, A. T., Beesdo-Baurn, K., Fava, G. A., & Craske, M. G. (2010). Agoraphobia: A review of the diagnostic classificatory position and criteria. Depression and Anxiety, 27(2), 113–133. doi:10.1002/da.20646 20143426
Wolff, N., Frueh, B., Shi, J., Gerardi, D., Fabrikant, N., & Schumann, B. (2011). Trauma exposure and mental health characteristics of incarcerated females self-referred to specialty PTSD treatment. Psychiatric Services, 62, 954–958.21807837
Wolff, N., Huening, J., Shi, J., & Frueh, B. C. (2014). Trauma exposure and posttraumatic stress disorder among incarcerated men. Journal of Urban Health, 97(4), 707–719. doi:10.1007/s11524-014-9871-x
Wood, S. R. (2013). Dual severe mental and substance use disorders as predictors of federal inmate assaults. Prison Journal, 93(1), 34–56. doi:10.1177/0032885512467312
Woodhead, E. L., Cowden Hindash, A., & Timko, C. (2013). Dual diagnosis, mutual-help use, and outcomes: A naturalistic follow-up. Journal of Dual Diagnosis, 9(2), 158–164. doi:10.1080/15504263.2013.777986
World Health Organization. (WHO), (n.d.). Constitution. Retrieved from www.who.int/about/who-we-are/constitution
World Health Organization. (2019). Premature death among people with severe mental disorders. Information Sheet. Retrieved from www.who.int/mentalhealth/management/info sheet.pdf
Worley, M. J., Tate, S. R., & Brown, S. A. (2012). Mediational relations between 12-Step attendance, depression and substance use in patients with comorbid substance dependence and major depression. Addiction, 107(11), 1974–1983. doi:10.1111/j.1360-0443.2012.03943.x 22578037
Worley, M. J., Trim, R. S., Tate, S. R., Hall, J. E., & Brown, S. A. (2010). Service utilization during and after outpatient treatment for comorbid substance use disorder and depression. Journal of Substance Abuse Treatment, 39(2), 124–131. doi:10.1016/j.jsat.2010.05.009 20598832
Wu, L. T., McNeely, J., Subramaniam, G. A., Brady, K. T., Sharma, G., VanVeldhuisen, R, … Schwartz, R. P. (2017). DSM-5 substance use disorders among adult primary care patients: Results from a multisite study. Drug and Alcohol Dependence, 179, 42–46. doi:10.1016/j.drugalcdep.2017.05.048 28753480
Xie, H., Drake, R. E., McHugo, G. J., Xie, L, & Mohandas, A. (2010). The 10-year course of remission, abstinence, and recovery in dual diagnosis. Journal of Substance Abuse Treatment, 39(2), 132–140. doi:10.1016/j.jsat.2010.05.011 20598834
Yager, J., Devlin, M. J., Haimi, K. A., Herzog, D. B., Mitchell, J. E., Powers, R, & Zerbe, K. J. (June 2006). Practice guideline for the treatment of patients with eating disorders (3rd ed.). Retrieved from https://psychiatryonline.org/pb/assets/raw/sitewide/practice_guidelines/guidelines/eatingdisorders.pdf
Yager, J., & Feinstein, R. E. (2017). General psychiatric management for suicidal patients, with remarks on chronicity: Contending with the angel of death. Journal of Nervous and Mental Disease, 205(6), 419^126. doi:10.1097/nmd.0000000000000701 28557882
Yanchus, N. J., Periard, D., & Osatuke, K. (2017). Further examination of predictors of turnover intention among mental health professionals. Journal of Psychiatric and Mental Health Nursing, 24(1), 41–56. doi:10.1111/jpm.12354 27928857
Young, M. S., Barrett, B., Engelhardt, M. A., & Moore, K. A. (2014). Six-month outcomes of an integrated assertive community treatment team serving adults with complex behavioral health and housing needs. Community Mental Health Journal, 50(4), 474–479. doi:10.1007/s10597-013-9692-5 24346225
Young, S. (2015). Understanding substance abuse counselor turnover due to burnout: A theoretical perspective. Journal of Human Behavior in the Social Environment, 25(6), 675–686. doi:10.1080/10911359.2015.1013658
Young, S., & Sedgwick, O. (2015). Attention deficit hyperactivity disorder and substance misuse: An evaluation of causal hypotheses and treatment considerations. Expert Review of Neurotherapeutics, 15(9), 1005–1014. doi:10.1586/14737175.2015.1059756 26289485
Yu, R., Geddes, J. R., & Fazel, S. (2012). Personality disorders, violence, and antisocial behavior: A systematic review and meta-regression analysis. Journal of Personality Disorders, 26(5), 775–792. doi:10.1521/pedi.2012.26.5.775 23013345
Yudko, E., Lozhkina, O., & Fouts, A. (2007). A comprehensive review of the psychometric properties of the Drug Abuse Screening Test. Journal of Substance Abuse Treatment, 32(2), 189–198. doi:10.1016/j.jsat.2006.08.002 17306727
Yuodelis-Flores, C., & Ries, R. K. (2015). Addiction and suicide: A review. American Journal on Addictions, 24(2), 98–104. doi:10.1111/ajad.12185 25644860
Zetterqvist, M. (2015). The DSM-5 diagnosis of nonsuicidal self-injury disorder: A review of the empirical literature. Child and Adolescent Psychiatry and Mental Health, 9, 31. doi:10.1186/s13034-015-0062-7 26417387
Zgierska, A., Amaza, I. P., Brown, R. L., Mundt, M., & Fleming, M. F. (2014). Unhealthy drug use: How to screen, when to intervene. Journal of Family Practice, 63(9), 524–530.25353031
Zhu, H., & Wu, L. T. (2018). National trends and characteristics of inpatient detoxification for drug use disorders in the United States. BMC Public Health, 18(1), 1073. doi:10.1186/s12889-018-5982-8 30157815
Zilm, D. H., & Sellers, E. M. (1978). The quantitative assessment of physical dependence on opiates. Drug and Alcohol Dependence, 3(6), 419–428.720211
Zubkoff, L., Shiner, B. & Watts, B. V. (2016). Staff perceptions of substance use disorder treatment in VA primary care-mental health integrated clinics. Journal of Substance Abuse Treatment, 70, 44–49. doi:10.1016/j.jsat.2016.07.011 27692187
Zugai, J. S., Stein-Parbury, J., & Roche, M. (2015). Therapeutic alliance in mental health nursing: An evolutionary concept analysis. Issues in Mental Health Nursing, 36(4), 249–257. doi:10.3109/01612840.2014.969795 25988275
Zukkoor, S. (2015). The safety of stimulant medication use in cardiovascular and arrhythmia patients. Retrieved from https://www.acc.org/latest-in-cardioloay/articles/2015/04/28/10/06/the-safety-of-stimulant-medication-use-in-cardiovascular-and-arrhythmia-patients
Zulauf, C. A., Sprich, S. E., Safren, S. A., & Wilens, T. E. (2014). The complicated relationship between attention deficit/hyperactivity disorder and substance use disorders. Current Psychiatry Reports, 76(3), 436. doi:10.1007/s11920-013-0436-6
Zur, J., & Mojtabai, R. (2013). Medicaid expansion initiative in Massachusetts: Enrollment among substance-abusing homeless adults. American Journal of Public Health, 703(11), 2007–2013. doi:10.2105/ajph.2013.301283
Zweben, J. E., & Ashbrook, S. (2012). Mutual-help groups for people with co-occurring disorders. Journal of Groups in Addiction and Recovery, 7(2-4), 202–222. doi:10.1080/1556035X.2012.705700