# Appendix H: Field Reviewers

Note: The information given indicates each participant's affiliation during the time the review was conducted and may no longer reflect the individual's current affiliation.

Rosie Anderson-Harper
Mental Health Manager/Treatment
Coordinator
Division of Alcohol and Drug Abuse
Missouri Department of Mental Health
Jefferson City, Missouri

Nancy Bateman, LCSW-C, CAC
Senior Staff Associate
Division of Professional Development and Advocacy
National Association of Social Workers
Washington, DC

Michele W. Beck, M.S.W., LSBCAC, ICRC
Acting Director of Treatment
Office for Addictive Disorders
State of Louisiana
Baton Rouge, Louisiana

Marion A. Becker, R.N., Ph.D.
Associate Professor
Department of Community Health
Louis de la Parte Florida Mental Health
Institute
Tampa, Florida

Janice S. Bennett, M.S., CSAC
Program Coordinator
Hawaii Drug Court Program
Honolulu, Hawaii

Elmore T. Briggs, CCDC, NCAC II
Program Manager
Adolescent Recovery Center
Vanguard Services Unlimited
Arlington, Virginia

David W. Brook, M.D., CGP
Department of Community and Preventive Medicine
Mount Sinai Medical Center
New York, New York

Nina W. Brown, Ed.D.
President
Mid-Atlantic Group Psychotherapy Society
Virginia Beach, Virginia

Barry S. Brown, Ph.D.
Professor (Adjunct)
University of North Carolina at Wilmington
Carolina Beach, North Carolina

Maxine F. Carpenter, M.S.
President/Chief Executive Officer
McKinley Group, Inc.
Atlanta, Georgia

Bruce Carruth, Ph.D., LCSW
Private Practice
Boulder, Colorado

Annabelle Casas, B.A.
Family Drug Court Coordinator
65th District Court Family Drug Court Program
El Paso, Texas

Magdalen Chang
Center Manager
Bill Pone Memorial Unit
Haight Ashbury Free Clinic
San Francisco, California

Sharon D. Chappelle, Ph.D., M.S.W., LCSW
President/Chief Executive Officer
Chappelle Consulting and Training Services, Inc.
Middletown, Connecticut

David E. Cooper, Ph.D.
Psychologist/Psychoanalyst
Former Director of the Lodge Day Program
Chestnut Lodge Hospital
Private Practice
Chevy Chase, Maryland

Cathi Coridan, M.A.
Senior Director for Substance Abuse Programs and Policy
National Mental Health Association
Alexandria, Virginia

Eric Denner
Clinical Social Worker
San Francisco General Hospital
San Francisco, California

Janice M. Dyehouse, Ph.D., R.N., M.S.N.
Professor and Department Head
College of Nursing
University of Cincinnati
Cincinnati, Ohio

Marty Estrada
Career Services Specialist General Relief Team
Ventura Intake and Eligibility Center
Ventura, California

Arthur C. Evans, Ph.D.
Deputy Commissioner
Connecticut Department of Mental Health and Addiction Services
Hartford, Connecticut

Kathleen J. Farkas, Ph.D., LISW, ASCW
Associate Professor
Case Western Reserve University
Cleveland, Ohio

Saul Feldman, Ph.D.
Chairman/Chief Executive Officer
United Behavioral Health
San Francisco, California

Philip J. Flores, Ph.D., COP, FAGPA
Adjunct Clinical Supervisor
Department of Psychology
Georgia State University
Atlanta, Georgia

Marilyn Joan Freimuth, Ph.D.
Bedford, New York

Byron N. Fujita, Ph.D.
Senior Psychologist
Clackamas County Mental Health Center
Oregon City, Oregon

Michael Galer, D.B.A., M.B.A., M.F.A.
Westminster, Massachusetts

Charles Garvin, Ph.D.
Professor of Social Work
School of Social Work
University of Michigan Ann Arbor, Michigan

Jeffrey M. Georgi, M.Div., CGP, CSAC, LPC, CCS
Clinical Director
Department of Behavioral Science
Duke School of Nursing and Duke University Medical Center
Senior Clinician
Duke Addictions Program
Duke University Medical Center
Durham, North Carolina

Mary M. Gillespie, Psy.D., CASAC
Psychologist
Private Practice
Saratoga Springs, New York

Paolo Giudici, LPCC, LADAC
Clinical Director
AYUDANTES, INC.
Santa Fe, New Mexico

Paula R. James, M.A.
Department of Psychiatry
Community Support Services
Bellevue Hospital Center
New York, New York

Kathryn P. Jett
Director
California Department of Alcohol and Drug Programs
Sacramento, California

Michael W. Kirby, Jr., Ph.D.
Chief Executive Officer
Arapahoe House, Inc.
Thornton, Colorado

Ford H. Kuramoto, D.S.W.
National Director
National Asian Pacific American Families Against Substance Abuse
Los Angeles, California

Ting-Fun May Lai, M.S.W., CSW, CASAC
Director
Chinatown Alcoholism Services
Hamilton-Madison House
New York, New York

Marlana Lalli
Program Manager
Ft. Des Moines OWI Program
Des Moines, Iowa

Barry Levy
Executive Director
Community Resource Council
Long Beach, California

Margaret Mattson, Ph.D.
Staff Collaborator
National Institute on Alcohol Abuse and Alcoholism
Bethesda, Maryland

Robert Meyer
Chief Executive Officer/President
Rainbow Recovery Center, Inc.
Des Moines, Iowa

Stacia Murphy
President
National Council on Alcoholism and Drug Dependence, Inc.
New York, New York

Ethan Nebelkopf, Ph.D., MFCC
Clinic Director
Family and Child Guidance Center
Native American Health Center
Oakland, California

Thomas E. Nightingale
Director
Bureau of Addiction Treatment Centers
New York State Office of Alcoholism and Substance Abuse Services
Albany, New York

Marlene O'Connell, R.N., M.S.N., LCPC, NCC, CCDC
Manager
Behavioral Health Services Benefits Healthcare
Great Falls, Montana

Gwen M. Olitsky, M.S.
Chief Executive Officer
The Self-Help Institute for Training and Therapy
Lansdale, Pennsylvania

Jerry M. Owens, M.S., LMHC, LMFT
Wadle and Associates
Des Moines, Iowa

Thomas A. Peltz, M.Ed., LMHC, CAS
Therapist
Private Practice
Beverly Farms, Massachusetts

Nancy A. Piotrowski, Ph.D.
Associate Scientist
Alcohol Research Group
Berkeley, California

Jeffrey David Roth, M.D., FASAM, FAGPA
Independent Consultant
Chicago, Illinois

Marvena A. Simmonds, M.P.A.
Public Health Advisor
Division of State and Community Assistance
Center for Substance Abuse Treatment
Rockville, Maryland

Darren C. Skinner, Ph.D., LSW, CAC
Director
Gaudenzia, Inc.
Gaudenzia House West Chester
West Chester, Pennsylvania

Antony P. Stephen, Ph.D.
Executive Director
Mental Health and Behavioral Sciences
New Jersey Asian American Association for Human Services, Inc.
Elizabeth, New Jersey

Richard T. Suchinsky, M.D.
Associate Chief for Addictive Disorders and Psychiatric Rehabilitation
Mental Health and Behavioral Sciences Services
Department of Veterans Affairs Washington, DC

Judith S. Tellerman, Ph.D., M.Ed., MAT, CGP
Assistant Clinical Professor
College of Medicine
University of Illinois
Chicago, Illinois

Jocelyn Thevenote, B.A.
Outreach Director
Office for Addictive Disorders
Pineville Alexandria Clinic
Pineville, Louisiana

Ernie Turner
Director
Division of Alcoholism and Drug Abuse
Alaska Department of Health and Social Services
Juneau, Alaska

Judy Tyson, Ph.D., CGP
Mid-Atlantic Group Psychotherapy Society
Bethesda, Maryland

Karen Urbany
Public Health Advisor
Treatment and Systems Improvement Branch
Division of Practice and Systems Development
Center for Substance Abuse Treatment
Rockville, Maryland

Marsha Lee Vannicelli, Ph.D., FAGPA
Associate Clinical Professor
Department of Psychiatry
Harvard Medical School
Belmont, Massachusetts

Ralph Varela, M.S.W.
Chief Executive Officer
Pinal Hispanic Council
Eloy, Arizona

Albert J. Villapiano, Ed.D.
Director of Substance Abuse Product Line Inflexxion
Newton, Massachusetts

Iris Wilkinson, Ed.D.
Associate Professor
Human Services Department
School of Applied Studies
Washburn University
Topeka, Kansas

William H. Williams, Jr., M.A., LCADC
Substance Abuse Program Manager
Clinical Plans and Management
Bureau of Medicine and Surgery
Department of Navy
Washington, DC

Ednita Wright, Ph.D., M.S.W., CSW
Independent Consultant/Counselor Therapist
Garnett Health Center, Counseling Psychological Service
Cornell University
Ithaca, New York

Janet Zwick
Deputy Director
Division of Substance Abuse and Health Promotion
Iowa Department of Public Health
Des Moines, Iowa