# Appendix G: Cultural Competency and Diversity Network Participants

Note: The information given indicates each participant's affiliation during the time the network was convened and may no longer reflect the individual's current affiliation.

Elmore T. Briggs, CCDC, NCAC II
Program Manager
Adolescent Recovery Center
Vanguard Services, Unlimited
Arlington, Virginia
African American Work Group

Maxine F. Carpenter, M.S.
President/Chief Executive Officer
McKinley Group, Inc.
Atlanta, Georgia
African American Work Group

Magdalen Chang
Center Manager
Bill Pone Memorial Unit
Haight Ashbury Free Clinic
San Francisco, California
Asian and Pacific Islanders Work Group

Marty Estrada
Career Services Specialist
General Relief Team
Ventura Intake and Eligibility Center
Ventura, California
Hispanic/Latino Workgroup

Adelaida Hernandez, M.S., LCDC
M.U.H.E.R.E.S. Program Director
S.C.A.N., Inc.
Laredo, Texas
Hispanic/Latino Workgroup

Ford H. Kuramoto, D.S.W.
National Director
National Asian Pacific American Families
Against Substance Abuse
Los Angeles, California
Asian and Pacific Islanders Work Group

Frank Lemus, Jr., M.A.
Clinical Director
SageWind (Oikos, Inc.)
Reno, Nevada
Hispanic/Latino Workgroup

Ting-Fun May Lai, M.S.W., CSW, CASAC
Director
Chinatown Alcoholism Center
Hamilton-Madison House
New York, New York
Asian and Pacific Islanders Work Group

Tam K. Nguyen, M.D., LMSW, CCJS, DVC, MAC
President
Employee & Family Resources
Polk City, Iowa
Asian and Pacific Islanders Work Group

Rick Rodriguez
Manager/Counselor
Services United
Santa Paula, California
Hispanic/Latino Work Group

Candace Shelton, M.S., CADAC
Clinical Director
Native American Connections, Inc.
Tucson, Arizona
Lesbian, Gay, Bisexual, and Transgender Workgroup

Mariela C. Shirley, Ph.D.
Assistant Professor
Department of Psychology
University of North Carolina at Wilmington
Wilmington, North Carolina Hispanic/Latino Workgroup

Antony P. Stephen, Ph.D.
Executive Director
Mental Health & Behavioral Sciences
New Jersey Asian American Association for Human Services, Inc.
Elizabeth, New Jersey
Asian and Pacific Islanders Workgroup

Ednita Wright, Ph.D., M.S.W., CSW
Independent Consultant/Counselor Therapist
Garnett Health Center, Counseling
Psychological Service
Ithaca, New York
Lesbian, Gay, Bisexual, and Transgender Workgroup