# Appendix F: Resource Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

Candace Baker
Clinical Affairs Manager
Lesbian, Gay, Bisexual, and Transgender
Special Interest Group
National Association of Alcohol and Drug
Abuse Counselors
Alexandria, Virginia

Nancy Bateman, LCSW-C, CAC
Senior Staff Associate
Division of Professional Development and Advocacy
National Association of Social Workers
Washington, DC

Carole Chrvala, Ph.D.
Senior Program Officer
Board on Neuroscience and Behavioral Health
Institute of Medicine
Washington, DC

Peggy Clark, M.S.W., M.P.A.
Center for Medicaid and State Operations
Centers for Medicare and Medicaid Services
Baltimore, Maryland

Sandra M. Clunies, M.S., ICADC
Derwood, Maryland

Cathi Coridan, M.A.
Senior Director for Substance Abuse
Programs and Policy
National Mental Health Association
Alexandria, Virginia

Edwin M. Craft, Dr.P.H.
KAP Alternate Project Officer
Office of Evaluation, Scientific Analysis and Synthesis
Center for Substance Abuse Treatment Rockville, Maryland

Christina Currier
Public Health Analyst
Office of Evaluation, Scientific Analysis and Synthesis
Center for Substance Abuse Treatment
Rockville, Maryland

Dorynne Czechowicz, M.D.
Medical Officer
Treatment Development Branch
Division of Treatment Research and Development
National Institute on Drug Abuse
Bethesda, Maryland

Jennifer Fiedelholtz
Public Health Analyst
Office of Policy and Program Coordination
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Hendree E. Jones, Ph.D.
Assistant Professor
Department of Psychiatry and Behavioral Sciences
Johns Hopkins University Center
Baltimore, Maryland

Edith Jungblut
Project Officer
Center for Substance Abuse Treatment
Rockville, Maryland

Tom Leibfried, M.P.A.
Vice President of Government Relations National Council for Community
Behavioral Healthcare
Rockville, Maryland

Emeline Otey, Ph.D.
Program Official
Adult Psychotherapy and Prevention Resource Branch
National Institute of Mental Health
Bethesda, Maryland

Anne Pritchett, M.P.A.
Policy Analyst
Executive Office of the President
Office of National Drug Control Policy
Washington, DC

Elizabeth Rahdert, Ph.D.
Program Administrator
National Institute on Drug Abuse
Bethesda, Maryland

Stanley Smith, M.A., TEP
Clinical Director
Mid-Atlantic Chapter
American Society of Group Psychotherapy and Psychodrama
c/o Adolescence and Family Growth Center, Inc.
Springfield, Virginia

Richard T. Suchinsky, M.D.
Associate Chief for Addictive Disorders and Psychiatric Rehabilitation
Mental Health and Behavioral Sciences Services
Department of Veterans Affairs
Washington, DC

Jan Towers, Ph.D., CRNP
Director
Health Policy
American Academy of Nurse Practitioners
Washington, DC