# Appendix E: Association for Specialists in Group Work Best Practice Guidelines

Approved by the ASGW Executive Board, March 29, 1998

Prepared by: Lynn Rapin and Linda Keel, ASGW Ethics Committee Co-Chairs

The Association for Specialists in Group Work (ASGW) is a division of the American Counseling Association whose members are interested in and specialize in group work. We value the creation of community; service to our members, clients, and the profession; and leadership as a process to facilitate the growth and development of individuals and groups.

The Association for Specialists in Group Work recognizes the commitment of its members to the Code of Ethics and Standards of Practice (as revised in 1995) of its parent organization, the American Counseling Association (ACA), and nothing in this document shall be construed to supplant that code. These Best Practice Guidelines are intended to clarify the application of the ACA Code of Ethics and Standards of Practice to the field of group work by defining Group Workers' responsibility and scope of practice involving those activities, strategies, and interventions that are consistent and current with effective and appropriate professional ethical and community standards. ASGW views ethical process as being integral to group work and views Group Workers as ethical agents. Group Workers, by their very nature in being responsible and responsive to their group members, necessarily embrace a certain potential for ethical vulnerability. It is incumbent upon Group Workers to give considerable attention to the intent and context of their actions because the attempts of Group Workers to influence human behavior through group work always have ethical implications. These Best Practice Guidelines address Group Workers' responsibilities in planning, performing, and processing groups.

## Section A: Best Practice in Planning

### A.1. Professional Context and Regulatory Requirements

Group Workers actively know, understand, and apply the ACA Code of Ethics and Standards of Best Practice, the ASGW Professional Standards for the Training of Group Workers, these ASGW Best Practice Guidelines, the ASGW diversity competencies, the ACA Multicultural Guidelines, relevant State laws, accreditation requirements, relevant National Board for Certified Counselors Codes and Standards, their organizations' standards, and insurance requirements impacting the practice of group work.

### A.2. Scope of Practice and Conceptual Framework

Group Workers define the scope of practice related to the core and specialization competencies defined in the ASGW Training Standards. Group Workers are aware of personal strengths and weaknesses in leading groups. Group Workers develop and are able to articulate a general conceptual framework to guide practice and a rationale for use of techniques that are to be used. Group Workers limit their practice to those areas for which they meet the training criteria established by the ASGW Training Standards.

### A.3. Assessment

a. Assessment of self. Group Workers actively assess their knowledge and skills related to the specific group(s) offered. Group Workers assess their values, beliefs, and theoretical orientation and how these impact upon the group, particularly when working with a diverse and multicultural population.
b. Ecological assessment. Group Workers assess community needs, agency or organization resources, sponsoring organization mission, staff competency, attitudes regarding group work, professional training levels of potential group leaders regarding group work, client attitudes regarding group work, and multicultural and diversity considerations. Group Workers use this information as the basis for making decisions related to their group practice, or to the implementation of groups for which they have supervisory, evaluation, or oversight responsibilities.

### A.4. Program Development and Evaluation

a. Group Workers identify the type(s) of group(s) to be offered and how they relate to community needs.
b. Group Workers concisely state in writing the purpose and goals of the group. Group Workers also identify the role of the group members in influencing or determining the group goals.
c. Group Workers set fees consistent with the organization's fee schedule, taking into consideration the financial status and locality of prospective group members.
d. Group Workers choose techniques and a leadership style appropriate to the type(s) of group(s) being offered.
e. Group Workers have an evaluation plan consistent with regulatory, organization and insurance requirements, where appropriate.
f. Group Workers take into consideration current professional guidelines when using technology, including but not limited to Internet communication.

### A.5. Resources

Group Workers coordinate resources related to the kind of group(s) and group activities to be provided, such as: adequate funding; the appropriateness and availability of a trained co-leader; space and privacy requirements for the type(s) of group(s) being offered; marketing and recruiting; and appropriate collaboration with other community agencies and organizations.

### A.6. Professional Disclosure Statement

Group Workers have a professional disclosure statement which includes information on confidentiality and exceptions to confidentiality, theoretical orientation, information on the nature, purpose(s) and goals of the group, the group services that can be provided, the role and responsibility of group members and leaders, qualifications to conduct the specific group(s), specific licenses, certifications and professional affiliations, and address of licensing/credentialing body.

### A.7. Group and Member Preparation

a. Group Workers screen prospective group members if appropriate to the type of group being offered. When selection of group members is appropriate, Group Workers identify group members whose needs and goals are compatible with the goals of the group.
b. Group Workers facilitate informed consent. Group Workers provide in oral and written form to prospective members (when appropriate to group type): the professional disclosure statement; group purpose and goals; group participation expectations including voluntary and involuntary membership; role expectations of members and leader(s); policies related to entering and exiting the group; policies governing substance use; policies and procedures governing mandated groups (where relevant); documentation requirements; disclosure of information to others; implications of out-of-group contact or involvement among members; procedures for consultation between group leader(s) and group member(s); fees and time parameters; and potential impacts of group participation.
c. Group Workers obtain the appropriate consent forms for work with minors and other dependent group members.
d. Group Workers define confidentiality and its limits (for example, legal and ethical exceptions and expectations, waivers implicit with treatment plans, documentation and insurance usage). Group Workers have the responsibility to inform all group participants of the need for confidentiality, potential consequences of breaching confidentiality and that legal privilege does not apply to group discussions (unless provided by State statute).

### A.8. Professional Development

Group Workers recognize that professional growth is a continuous, ongoing, developmental process throughout their career.

a. Group Workers remain current and increase knowledge and skill competencies through activities such as continuing education, professional supervision, and participation in personal and professional development activities.
b. Group Workers seek consultation and/or supervision regarding ethical concerns that interfere with effective functioning as a group leader. Supervisors have the responsibility to keep abreast of consultation, group theory, process, and adhere to related ethical guidelines.
c. Group Workers seek appropriate professional assistance for their own personal problems or conflicts that are likely to impair their professional judgment or work performance.
d. Group Workers seek consultation and supervision to ensure appropriate practice whenever working with a group for which all knowledge and skill competencies have not been achieved.
e. Group Workers keep abreast of group research and development.

### A.9. Trends and Technological Changes

Group Workers are aware of and responsive to technological changes as they affect society and the profession. These include but are not limited to changes in mental health delivery systems; legislative and insurance industry reforms; shifting population demographics and client needs; and technological advances in Internet and other communication and delivery systems. Group Workers adhere to ethical guidelines related to the use of developing technologies.

## Section B: Best Practice in Performing

### B.1. Self Knowledge

Group Workers are aware of and monitor their strengths and weaknesses and the effects these have on group members.

### B.2. Group Competencies

Group Workers have a basic knowledge of groups and the principles of group dynamics, and are able to perform the core group competencies, as described in the ASGW Professional Standards for the Training of Group Workers. Additionally, Group Workers have adequate understanding and skill in any group specialty area chosen for practice (psychotherapy, counseling, task, psychoeducation, as described in the ASGW Training Standards).

### B.3. Group Plan Adaptation

a. Group Workers apply and modify knowledge, skills, and techniques appropriate to group type and stage, and to the unique needs of various cultural and ethnic groups.
b. Group Workers monitor the group's progress toward the group goals and plan.
c. Group Workers clearly define and maintain ethical, professional, and social relationship boundaries with group members as appropriate to their role in the organization and the type of group being offered.

### B.4. Therapeutic Conditions and Dynamics

Group Workers understand and are able to implement appropriate models of group development, process observation, and therapeutic conditions.

### B.5. Meaning

Group Workers assist members in generating meaning from the group experience.

### B.6. Collaboration

Group Workers assist members in developing individual goals and respect group members as co-equal partners in the group experience.

### B.7. Evaluation

Group Workers include evaluation (both formal and informal) between sessions and at the conclusion of the group.

### B.8. Diversity

Group Workers practice with broad sensitivity to client differences including but not limited to ethnic, gender, religious, sexual, psychological maturity, economic class, family history, physical characteristics or limitations, and geographic location. Group Workers continuously seek information regarding the cultural issues of the diverse population with whom they are working both by interaction with participants and from using outside resources.

### B.9. Ethical Surveillance

Group Workers employ an appropriate ethical decisionmaking model in responding to ethical challenges and issues and in determining courses of action and behavior for self and group members. In addition, Group Workers employ applicable standards as promulgated by ACA, ASGW, or other appropriate professional organizations.

## Section C: Best Practice in Group Processing

### C.1. Processing Schedule

Group Workers process the workings of the group with themselves, group members, supervisors, or other colleagues, as appropriate. This may include assessing progress on group and member goals, leader behaviors and techniques, group dynamics and interventions, developing understanding, and acceptance of meaning. Processing may occur both within sessions and before and after each session, at time of termination, and later follow up, as appropriate.

### C.2. Reflective Practice

Group Workers attend to opportunities to synthesize theory and practice and to incorporate learning outcomes into ongoing groups. Group Workers attend to session dynamics of members and their interactions and also attend to the relationship between session dynamics and leader values, cognition, and affect.

### C.3. Evaluation and Follow-Up

a. Group Workers evaluate process and outcomes. Results are used for ongoing program planning, improvement and revisions of current group, and/or to contribute to professional research literature. Group Workers follow all applicable policies and standards in using group material for research and reports.
b. Group Workers conduct follow-up contact with group members, as appropriate, to assess outcomes or when requested by a group member(s).

### C.4. Consultation and Training With Other Organizations

Group Workers provide consultation and training to organizations in and out of their setting, when appropriate. Group Workers seek out consultation as needed with competent professional persons knowledgeable about group work.

Source:ASGW 1998. Reprinted with permission.