# Appendix D: Glossary

AA: Alcoholics Anonymous, the best known of the 12-Step self-help organizations.

ASAM: The American Society of Addiction Medicine is a national specialty society of the American Medical Association and is dedicated to educating physicians and improving the treatment of individuals with alcoholism and other addictions. ASAM publishes the Patient Placement Criteria for the Treatment of Substance-Related Disorders: ASAM PPC-2R (2001), a widely used system of criteria for placing clients in appropriate treatment settings.

Basic teaching skills: Organizing the content to be taught, planning for participant involvement in the learning process, and delivering information in a culturally relevant and meaningful way.

Cognitive-behavioral groups: Groups formed to change learned patterns of thinking and behavior that lead to substance abuse or other psychological and interpersonal disorders.

Cognitive therapy: Attempts to modify maladaptive behavior by influencing a client's beliefs, schemas, self-statements, and problemsolving strategies. Assumes that emotional problems are largely caused by irrational or maladaptive thinking and that restructuring these cognitions will be therapeutic.

Cohesion: A positive quality of groups denoting a sense of enthusiastic solidarity within the group; Yalom (1995, p. 48) notes that cohesive groups “have a higher rate of attendance, participation, and mutual support,” and that members “will defend the group standards much more than groups with less esprit de corps.”

Communal and culturally specific groups: Groups formed to use the sense of belonging to a culture to reduce or eliminate drug abuse and other negative behaviors.

Conflict: A basic dynamic in groups in which members have opposing views, beliefs, or emotions; conflict can be constructive by (1) assisting members to consider and respect other opinions, (2) generating energy and investment in the group, and (3) creating a variety of options for change; conflict is detrimental when (1) it distracts members' attention or allows them to avoid issues in the group, (2) any group member feels his or her beliefs or world views are not understood or viewed as valid, or (3) the conflict leads to destructive behaviors, such as denigration or other verbal abuse.

Confrontation: A form of intervention that literally means “coming face to face” or “pointing out inconsistencies” that keep clients from facing unpleasant realities (CSAT 1999b, p. 10).

Content: Information and feelings expressed in group; its complement is process.

Culture: Integrated patterns of human behavior that include the language, thoughts, communications, actions, customs, beliefs, values, and institutions of a racial, ethnic, religious, or social group (Giachello 1995; Office of Minority Health 2001).

Eco-map, or sociogram: A graphic that clients construct to represent their important social relationships.

Expressive groups: Groups formed to use some kind of creative activity (such as painting, dance, play therapy, or psychodrama) to help clients explore their substance abuse, its origins and effects, and new coping options; expressive groups may be especially effective for clients who have difficulty verbalizing thoughts and feelings.

Diversity: As used in this TIP, diversity refers to any difference that distinguishes one individual from another and that affects how clients identify themselves and are identified by others.

Emotional contagion: Rapid and intense escalation of excitement in a group, which if uncontrolled, can threaten boundaries and an individual's sense of well-being, potentially leading to premature termination of treatment.

Fixed membership groups: Relatively small group with a set number of members who stay together over a long period of time; people in time-limited fixed membership groups start and stay together, while ongoing fixed membership groups bring in new members if a vacancy occurs.

Gestalt therapy: Developed by Friedrich S. and Laura Perls, gestalt therapy aims to enhance clients' awareness, which frees them to grow in their own consciously guided ways. It seeks to reestablish stalled growth processes by helping clients become aware of feelings they have disowned but that are a genuine part of them, and recognize feelings and values that they think are a genuine part of them but are borrowed from other people.

Group agreement: A contract between provider and client stipulating the responsibilities of clients and their expectations of other group members, the leader, and the group; group agreements typically specify grounds for exclusion from group, expectations of confidentiality, restrictions on physical contact, consequences for returns to substance use, boundaries on contact outside the group, expectations for participation in group, financial responsibilities, and procedures for termination (leaving the group).

Group dynamics: Forces at work among small groups of interacting people; collectively, group dynamics are a complex amalgam of individual personalities and actions combined with the overarching properties of the group as a whole; put another way, group dynamics are the collective impact of individual members on the group and the impact the group has on each individual.

Group process: How events take place in group, in contrast to content, which is what takes place; if, for example, a question is raised, a process-oriented group leader might silently note circumstances such as voice quality, facial expression, what came before and after the question, and how the question was directed (to the leader? the group? to an individual? away from someone?); overall, process concerns include (1) the impact and quality of interaction among group members, (2) the impact of group on individuals, and (3) the life phases of the group.

Heterogeneous groups: Groups made up of a mixture of clients whose only similarity is the need they share for a particular kind of group.

Homogeneous groups: Groups made up of clients who are alike in some respect other than a common substance use problem; homogeneous groups may include, for example, only women, only adolescents or elderly people, or only people from a certain cultural heritage.

IPGP: Interpersonal process group psychotherapy, shortened in this TIP to interpersonal process groups.

Interpersonal process groups: Formed to use group interactions to promote change and healing; such groups are used after abstinence is well established; they delve into major developmental issues that contribute to addiction and interfere with recovery; the primary interest is how clients recreate past experiences in the here-and-now microcosm of the group; interpersonal process groups attend more to process (how people act and talk) and less to content (what people do and say).

Interpersonal relationship dynamics: How people relate to one another in group settings and how one individual can influence the behavior of others in group, such as by giving and receiving feedback from each other.

Interventions: Words or actions with a therapeutic purpose; interventions may clarify what is happening in group, redirect energy, stop unhelpful processes, or present the group with a choice.

Intrapsychic: Relating to events occurring within the psyche, mind, or personality; that is, internally without reference to any external factors.

Leadership skills: Include helping the group get started in a session, managing (though not necessarily eliminating) conflict between group members, helping withdrawn members of the group become more active, and making sure that all group members have a roughly equal chance to participate.

Problem-focused groups: Groups formed to address a particular problem that contributes to substance abuse or limits recovery options; problem-focused groups also look at the process of problemsolving so members can generalize their experience in group to other life areas.

Process: How members interact in the group; its complement is content.

Process-oriented therapy: An approach to group therapy that emphasizes group interaction as the healing agent; the role of the leader is the promotion of interaction among group members.

Projective identification: Involves projecting one's disowned attributes onto another person (Yalom 1995).

Psychodynamic emphases: The dynamic interplay of psychological forces conceptualized using psychodynamic theories. Within an individual these forces influence behavior, interaction with others, and emotions.

Psychodynamic therapy, psychodynamic approach: An approach to psychological growth and change that emphasizes the evolution and adaptation of the psychological structure within an individual. Psychodynamic therapy often focuses on changing behavior in the present by re-examining and revising a person's understandings and reactions to events in the past.

Psychotherapy (or therapy) groups: Groups formed to reduce or eliminate substance abuse or other problematic behaviors by changing long-standing relational and intrapsychic difficulties. Psychotherapy groups differ from other groups traditionally used for substance abuse treatment, such as problem-solving or support groups, in that the group (1) has a relatively long-term contract; (2) focuses more on psychodynamic issues (rather than education, support, or problem solving); (3) begins in later stages of treatment and recovery; (4) tolerates the expression of more emotion; and (5) stresses process over content.

Psychoeducational groups: Groups formed to educate clients about substance abuse, related behaviors, and the behavioral, medical, and psychological consequences of use, abuse, and dependency; psychoeducational groups provide information important for achieving abstinence and maintaining recovery.

Reality therapy: Developed by William Glasser, the basic principle of reality therapy is that we are responsible for what we choose to do. Reality therapy focuses on solving problems and on coping with the demands of reality in society by making more effective choices.

Redecision therapy: Is aimed at helping people challenge themselves to discover ways in which they perceive themselves in victimlike roles and to take charge of their lives by deciding for themselves how they will change.

Relapse prevention groups: Groups formed to help clients maintain abstinence or minimize the impact and duration of relapse.

Resistance to therapy: An often subconscious defense against the pain of examining one's own behavior, perceptions, beliefs, and feelings; resistance can appear in many disguises: continual claims to be too upset to work on issues in group, missing group or coming late, or aversion to strong emotions, such as anger. Resistance is a natural part of any change process, but if it is not dealt with, it impedes growth and blocks the progress of individuals and groups.

Revolving membership groups: Somewhat larger than fixed membership groups, revolving membership groups acquire new members when they become ready for its services; time-limited revolving membership groups keep a member for a specified period of time, while ongoing revolving membership groups may have clients who (1) stay as long as they wish, (2) enter a group with a repeating cycle of topics and stay until they have completed all the topics, or (3) attend for a set time (either consecutively or nonconsecutively).

Skills development groups: Groups formed to bring about or improve the skills needed to achieve and maintain abstinence; such skills may relate directly to substance abuse (such as ways to refuse drugs or cope with urges to use them), or they may be designed to reduce or eliminate general life problems that imperil recovery (such as inadequate anger management or an inability to relax).

Splitting: A divide-and-conquer tactic used to come between cotherapists (Yalom 1995).

Stages of change: Prochaska and DiClemente's (1984) continuum that describes the stages a client moves through to achieve lasting recovery: precontemplation, contemplation, preparation, action, maintenance, and recurrence (for definitions, see chapter 2); the stage a client is in helps to determine what group treatment models and methods are appropriate for that person.

Stages (or phases) of group development: In the beginning phase, the group is prepared to begin its work. Tasks in this period involve introductions, a review of the group agreement, and the establishment of a safe environment and healthy norms. The middle phase, or actual work of the group, is the time for here-and-now interactions that help clients rethink behaviors and undertake changes. The end phase is a mixture of recognition and celebration of work done and goals achieved, mourning for the loss of the attachments formed in group, and reorientation toward the future.

Stages of recovery: In early recovery, clients establish abstinence. During this period, they are fragile and highly prone to relapse. In middle recovery, abstinence becomes stable enough so that the client can begin to work on life problems. In late recovery, clients continue working to maintain abstinence and make life changes, but may also confront and modify deeply ingrained relational problems and other psychological issues. A client's stage of recovery is one determinant of placement.

Stages of treatment: In early treatment, clients are ambivalent about relinquishing substance abuse, so heavy emphasis is placed on drawing clients into a culture of recovery and helping them get through each day without substances. Strong challenges to the mental and emotional state are set aside until later in treatment. In the middle stage, clients' mental and emotional condition improves, but they have an acute need for satisfying new directions that can fulfill the role that substance abuse once played in their lives. In late treatment, clients sustain earlier gains, but learn to anticipate temptations and triggers for relapse. Also, the client may need to address issues like poor self-image, relationship problems, shame, or trauma.

Support groups: Groups formed to (1) develop and strengthen clients' abilities to manage their own thinking and emotions (2) improve interpersonal skills, (3) manage day-to-day life more effectively, and (4) boost self-esteem and self-confidence.

Transactional analysis: Is both a theory of personality and an organized system of interactional therapy. Its basic assumption is that people make current decisions based on past premises that were at one time appropriate to survival but may no longer be valid. Transactional analysis emphasizes the cognitive, rational, and behavioral aspects of the therapeutic process.

Transference and countertransference: Transference is a perceptual distortion in which the characteristics of one person are attributed to another; in other words, parts of past relationships are projected onto relationships in the present; if, for example, group member A reminds member B of a dour, narrow-minded father, member B may transfer the attributes of his father to member A and react to him in group with extraordinary and irrational hostility. In a narrow sense, countertransference occurs when clients' transference evokes (often unconscious) emotional responses in therapists. In recent years, the concept has widened to include any emotional reaction in a therapist brought on by a client.

12-Step programs: Self-help programs that are based on mastering a set of steps to achieve and maintain abstinence; they are often loosely organized around a drug of abuse: Alcoholics Anonymous (alcohol), Narcotics Anonymous (opioids and illicit drugs), Cocaine Anonymous.