# Appendix C: Sample Group Agreement

## Appleton Outpatient Psychotherapy Group Ground Rules

The following is excerpted from Vannicelli 1992, pp. 295–296.

The behavior and feelings of members of the therapy group mirror in important ways behavior and feelings in other important relationships. Consequently, the group provides a setting in which to examine patterns of behavior in relationships. The group also provides a context in which members learn to identify, understand, and express their feelings. The therapist's role is to facilitate this group process.

To foster these goals, we believe that several group ground rules are important. These are as follows:

1. Members joining long-term groups remain as long as they find the group useful in working on important issues in their lives. We recommend at least a year. Members are required to make an initial 3-month commitment in order to determine the usefulness of this particular group for them.
2. Regular and timely attendance at all sessions is expected. As a member, it is your responsibility to notify the group in advance when you know that you will be away or late for group. In the event of an unexpected absence, you should notify the group at least 24 hours in advance to avoid being charged for the missed session.
3. Members of Appleton substance abuse groups are committed to maintaining abstinence. If a relapse does occur, it must be discussed promptly in the group—as must thoughts or concerns about resuming drug/alcohol use. Members of ACOA (Adult Children of Alcoholics) and family groups are asked to be reflective about their own substance use and to bring up changes in patterns of use or concerns that may be associated with use.
4. Members will notify the group if they are considering leaving the group. Because leaving the group is a process, just as joining is, members are expected to see this process through for at least 3 weeks following notification of termination.
5. Members will have a commitment to talk about important issues in their lives that cause difficulty in relating to others or in living life fully.
6. Members will also have a commitment to talk about what is going on in the group itself as a way of better understanding their own interpersonal dynamics.
7. Members will treat matters that occur in the group with utmost confidentiality. To that end, members are expected not to discuss what happens in the group with people who are not members of the group.
8. Outside-of-group contact often has considerable impact on the group's therapeutic effectiveness. Therefore, any relevant interactions between members which occur outside the group should be brought back into the next meeting and shared with the entire group.
9. What you share in the group will be shared with other members of the treatment team when we feel that it is important to your treatment to do so.
10. Payments for group are due at the last meeting of the month unless other arrangements are discussed and explicitly worked out in the group. If for any reason timely payment becomes problematic, members are expected to discuss this in the group.