# Appendix B: Adult Patient Placement Criteria

Adult Patient Placement Criteria For the Treatment of Psychoactive Substance Use Disorders
Levels of Care Criteria → ↓ | Dimensions | Level I Outpatient Treatment | Level II Intensive Outpatient Treatment | Level III Medically Monitored Intensive Inpatient Treatment
1 Acute Intoxication and/or Withdrawal Potential | Level IV | Medically Managed Intensive Inpatient Treatment | No withdrawal risk. | Minimal withdrawal risk.
2 Biomedical Conditions and Complications | Severe withdrawal risk but manageable in Level III. | Severe withdrawal risk. | None or very stable. | None or nondistracting from addiction treatment and manageable in Level II.
3 Emotional and Behavioral Conditions and Complications | Requires medical monitoring but not intensive treatment. | Requires 24-hour medical, nursing care. None or very stable. | Mild severity with potential to distract from recovery. | Moderate severity needing a 24-hour structured setting.
4 Treatment Acceptance and Resistance | Severe problems requiring 24-hour psychiatric care with concomitant addiction treatment. | Willing to cooperate but needs motivating and monitoring strategies. | Resistance high enough to require structured program, but not so high as to render outpatient treatment ineffective. | Resistance high despite negative consequences and needs intensive motivating strategies in 24-hour structure.
Levels of Care Criteria → Dimensions ↓ | Level I Outpatient Treatment | Level II Intensive Outpatient Treatment | Level III Medically Monitored Intensive Inpatient Treatment | Level IV Medically Managed Intensive Inpatient Treatment
5 Relapse Potential | Able to maintain abstinence and recovery goals with minimal support. | Intensification of addiction symptoms and high likelihood of relapse without close monitoring and support. | Unable to control use despite active participation in less intensive care and needs 24-hour structure. | Problems in this dimension do not qualify patient for Level IV treatment.
6 Recovery Environment | Supportive recovery environment and/or patient has skills to cope. | Environment unsupportive but with structure or support, the patient can cope. | Environment dangerous for recovery necessitating removal from the environment; logistical impediments to outpatient treatment. | Problems in this dimension do not qualify patient for Level IV treatment.

Source:American Society of Addiction Medicine 2001.