# Appendix A: Bibliography

Addington, J., and el-Guebaly, N. Group treatment for substance abuse in schizophrenia. Canadian Journal of Psychiatry 43(8):843–845, 1998.9806092
Agazarian, Y.M. Contemporary theories of group psychotherapy: A systems approach to the group-as-a-whole. International Journal of Group Psychotherapy 42(2):177–203, 1992.1572781
Alcoholics Anonymous World Services. The AA Member—Medications and Other Drugs: A Report from a Group of Physicians in AA. New York: Alcoholics Anonymous World Services, 1984.
Alonso, A. Training for group psychotherapy. In: Alonso, A. and Swiller, H. Group Therapy in Clinical Practice. Washington, DC: American Psychiatric Press, 1993. pp. 521–532.
Alonso, A., and Rutan, J.S. The experience of shame and the restoration of self-respect in group therapy. International Journal of Group Psychotherapy 38(1):3–27, 1988.3350614
American Psychiatric Association. Diagnostic and Statistical Manual of Mental Disorders. 4th Text Revision ed. Washington, DC: American Psychiatric Association, 2000.
American Society of Addiction Medicine. Patient Placement Criteria for the Treatment of Substance-Related Disorders: ASAM PPC-2R. 2d. Revised ed. Chevy Chase, MD: American Society of Addiction Medicine, 2001.
Annis, H.M., and Davis, C.S. Self-efficacy and the prevention of alcoholic relapse: Initial findings from a treatment trial. In: Baker, T.B., and Cannon, D.S., eds. Assessment and Treatment of Addictive Disorders. New York: Praeger, 1988. pp. 88–112.
Association for Specialists in Group Work. Principles for Diversity-Competent Group Workers. Alexandria, VA: Association for Specialists in Group Work, 1998.
Association for Specialists in Group Work. Best Practice Guidelines. Alexandria, VA: Association for Specialists in Group Work, 1998.
Association for Specialists in Group Work. Professional Standards for the Training of Group Workers. Alexandria, VA: Association for Specialists in Group Work, 2002.
Atkinson, D.R., and Lowe, S.M. The role of ethnicity, cultural knowledge and conventional techniques in counseling and psychotherapy. In: Ponterotto, J.G., Casas, J.M., Suzuki, L.A., and Alexander, C.M., eds. Handbook of Multiracial Counseling. Thousand Oaks, CA: Sage, 1995. pp. 387–414.
Beck, A.T. Cognitive Therapy and the Emotional Disorders. New York: International Universities Press, 1976.
Beck, A.T., Wright, F.D., Newman, C.F., and Liese, B.F. Cognitive Therapy of Substance Abuse. New York: Guilford Press, 1993.
Bion, W.R. Experiences in Groups and Other Papers. New York: Basic Books, 1961.
Bowlby, J. Attachment and Loss. Vol. 2, Separation: Anxiety and Anger. New York: Basic Books, 1973.
Bowlby, J. The Making and Breaking of Affectional Bonds. New York: Routledge, 1979.
Bradford, L.P., Gibb, J.R., and Benne, K.D., eds. T-Group Theory and Laboratory Method: Innovation in Re-Education. New York: Wiley, 1964.
Brook, D.W., Gordon, C., and Meadow, H. Ethnicity, culture, and group psychotherapy. Group 22(2):53–80, 1998.
Brown, D. Assessment and selection for groups. In: Roberts, J.P., and Pines, M., eds. The Practice of Group Analysis. London: Tavistock/Routledge, 1991. pp. 55–72.
Brown, N.W. Psychoeducational Groups. Philadelphia, PA: Accelerated Development, 1998.
Brown, S. Treating the Alcoholic: A Developmental Model of Recovery. New York: John Wiley and Sons, 1985.
Brown, S., and Yalom, I.D. Interactional group therapy with alcoholics. Journal of Studies on Alcohol 38(3):426–456, 1977.859331
Burns, D.D. The Feeling Good Handbook. Rev. ed. New York: Plume, 1999.
Carroll, K.M. Relapse prevention as a psychosocial treatment: A review of controlled clinical trials. Experimental & Clinical Psychopharmacology 4(1):46–54, 1996.
Center for Substance Abuse Treatment. Intensive Outpatient Treatment for Alcohol and Other Drug Abuse. Treatment Improvement Protocol (TIP) Series 8. HHS Publication No. (SMA) 99–3306. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1994a.
Center for Substance Abuse Treatment. Simple Screening Instruments for Outreach for Alcohol and Other Drug Abuse and Infectious Diseases. Treatment Improvement Protocol (TIP) Series 11. HHS Publication No. (SMA) 94–2094. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1994b.
Center for Substance Abuse Treatment. Checklist for Monitoring Alcohol and Other Drug Confidentiality Compliance. Technical Assistance Publication Series 18. HHS Publication No. (SMA) 99–3321. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1996.
Center for Substance Abuse Treatment. A Guide to Substance Abuse Services for Primary Care Clinicians. Treatment Improvement Protocol (TIP) Series 24. HHS Publication No. (SMA) 97–3139. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1997a.
Center for Substance Abuse Treatment. Substance Abuse Treatment and Domestic Violence. Treatment Improvement Protocol (TIP) Series 25. HHS Publication No. (SMA) 97–3163. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1997b.
Center for Substance Abuse Treatment. Addiction Counseling Competencies: The Knowledge, Skills, and Attitudes of Professional Practice. Technical Assistance Publication Series 21. HHS Publication No. (SMA) 98–3171. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1998a.
Center for Substance Abuse Treatment. Substance Use Disorder Treatment for People With Physical and Cognitive Disabilities. Treatment Improvement Protocol (TIP) Series 29. HHS Publication No. (SMA) 98–3249. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1998b.
Center for Substance Abuse Treatment. Brief Interventions and Brief Therapies for Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 34. HHS Publication No. (SMA) 99–3354. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1999a.
Center for Substance Abuse Treatment. Enhancing Motivation for Change in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series 35. HHS Publication No. (SMA) 99–3354. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1999b.
Center for Substance Abuse Treatment. Screening and Assessing Adolescents for Substance Use Disorders. Treatment Improvement Protocol (TIP) Series 31. HHS Publication No. (SMA) 99–3282. Rockville, MD: Substance Abuse and Mental Health Services Administration, 1999c.
Center for Substance Abuse Treatment. Integrating Substance Abuse Treatment and Vocational Services. Treatment Improvement Protocol (TIP) Series 38. HHS Publication No. (SMA) 00–3470. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2000.
Center for Substance Abuse Treatment. A Provider's Introduction to Substance Abuse Treatment for Lesbian, Gay, Bisexual, and Transgender Individuals. HHS Publication No. (SMA) 01–3498. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2001.
Center for Substance Abuse Treatment. Substance Abuse Treatment and Family Therapy. Treatment Improvement Protocol (TIP) Series 39. HHS Publication No. (SMA) 04–3957. Rockville, MD: Substance Abuse and Mental Health Services Administration, 2004.
Center for Substance Abuse Treatment. Improving Cultural Competence in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development a.
Center for Substance Abuse Treatment. Substance Abuse Treatment: Addressing the Specific Needs of Women. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development b.
Center for Substance Abuse Treatment. Substance Abuse Treatment for Adults in the Criminal Justice System. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration, in development c.
Chang, P. Treating Asian/Pacific American addicts and their families. In: Krestan, J.-A., ed. Bridges to Recovery: Addiction, Family Therapy, and Multicultural Treatment. New York: Free Press, 2000. pp. 192–218.
Chappel, J.N. Relapse prevention. In: Miller, N.S., ed. Treating Coexisting Psychiatric and Addictive Disorders. Center City, MN: Hazelden, 1994.
Cohen, E., and Goode, T.D. Rationale for Cultural Competence in Primary Health Care. Washington, DC: National Center for Cultural Competence, 1999.
Cohen, S.L. Working with resistance to experiencing and expressing emotions in group therapy. International Journal of Group Psychotherapy 47(4):443–458, 1997.9314697
Committee on Opportunities in Drug Abuse Research—Division of Neuroscience and Behavioral Health - Institute of Medicine. Pathways of Addiction: Opportunities in Drug Abuse Research. Washington, DC: National Academy Press, 1996.
Cooper, D.E. The role of group psychotherapy in the treatment of substance abusers. American Journal of Psychotherapy 41(1):55–67, 1987.3578607
Culbreth, J.R. Clinical supervision of substance abuse counselors: Current and preferred practices. Journal of Addictions and Offender Counseling 20(1):15–25, 1999.
Culbreth, J.R. Substance abuse counselors with and without a personal history of chemical dependency: A review of the literature. Alcoholism Treatment Quarterly 18(2):67–82, 2000.
Daley, D.C. Relapse Prevention: Treatment Alternatives and Counseling Aids. Blue Ridge Summit, PA: Tab Books, 1989.
Dimeff, L., and Marlatt, G.A. Relapse prevention. In: Hester, R.K., and Miller, W.R., eds. Handbook of Alcoholism Treatment Approaches. 2d ed. New York: Pergamon Press, 1995. pp. 176–194.
Dodes, L.M. The psychology of combining dynamic psychotherapy and Alcoholics Anonymous. Bulletin of the Menninger Clinic 52(4):283–293, 1988.3042066
Donovan, D.M., and Chaney, E.F. Alcoholic relapse prevention and intervention: Models and methods. In: Marlatt, G.A., and Gordon, J.R., eds. Relapse Prevention: Maintenance Strategies in the Treatment of Addictive Behaviors. New York: Guilford Press, 1985. pp. 351–416.
Drug Facts and Comparisons 2002. St. Louis, MO: Facts and Comparisons, 2002.
Dugo, J.M., and Beck, A.P. Significance and complexity of early phases in the development of the co-therapy relationship. Group Dynamics 1(4):294–305, 1997.
Durkin, H.E. The Group in Depth. New York: International Universities Press, 1964.
Easton, C., Swan, S., and Sinha, R. Motivation to change substance use among offenders of domestic violence. Journal of Substance Abuse Treatment 19:1–5, 2000.10867294
Ellis, A. REBT and its application to group therapy. In: Yankura, J., and Dryden, W., eds. Special Applications of REBT: A Therapist's Casebook. New York: Springer Publishing, 1997. pp. 131–161.
Ellis, A., and MacLaren, C. Rational Emotive Behavior Therapy: A Therapist's Guide. San Luis Obispo, CA: Impact Publishers, 1998.
Emrick, C.D. A review of psychologically oriented treatment of alcoholism: I. The use and interrelationships of outcome criteria and drinking behavior following treatment. Journal of Studies on Alcohol 35(Pt A):523–549, 1974.
Emrick, C.D. A review of psychologically oriented treatment of alcoholism: II. The relative effectiveness of different treatment approaches and the effectiveness of treatment versus no treatment. Journal of Studies on Alcohol 36(1):88–108, 1975.238080
Falkowski, W. Group therapy and the addictions. In: Edwards, G., and Dare, C., eds. Psychotherapy, Psychological Treatments and the Addictions. Cambridge: Cambridge University Press, 1996. pp. 206–219.
Flores, P.J. Group Psychotherapy with Addicted Populations. New York: The Haworth Press, 1988.
Flores, P.J. Group Psychotherapy with Addicted Populations: An Integration of Twelve-Step and Psychodynamic Theory. 2d ed. New York: The Haworth Press, 1997.
Flores, P. Addiction as an attachment disorder: Implications for group therapy. International Journal of Group Psychotherapy 51(1):63–81, 2001.11191596
Flores, P.J., and Mahon, L. The treatment of addiction in group psychotherapy. International Journal of Group Psychotherapy 43(2):143–156, 1993.8473058
Foote, J., DeLuca, A., Magura, S., Warner, A., Grand, A., Rosenblum, A., and Stahl, S. Group motivational treatment for chemical dependency. Journal of Substance Abuse Treatment 17(3):181–192, 1999.10531624
Freimuth, M. Integrating group psychotherapy and 12-step work: A collaborative approach. International Journal of Group Psychotherapy 50(3):297–314, 2000.10883547
Friedman, W.H. Practical Group Therapy: A Guide for Clinicians. San Francisco: Jossey-Bass, 1989.
Galanter, M., Castaneda, R., and Franco, H. Group therapy, self-help groups, and network therapy. In: Frances, R.J., and Miller, S.I., eds. Clinical Textbook of Addictive Disorders. 2d ed. New York: The Guilford Press, 1998. pp. 521–546.
Gans, J.S., and Alonso, A. Difficult patients: Their construction in group therapy. International Journal of Group Psychotherapy 48(3):311–325, 1998.9661312
Gans, J.S., and Weber, R.L. The detection of shame in group psychotherapy: Uncovering the hidden emotion. International Journal of Group Psychotherapy 50(3):381–396, 2000.10883551
Garvin, C. Contemporary Group Work. 3d ed. Boston: Allyn and Bacon, 1997.
Garvin, C. Group Treatments for Persons Who Abuse Drugs. Unpublished manuscript submitted to the National Institute on Drug Abuse, 2001.
Garvin, C., and Seabury, B. Interpersonal Practice in Social Work: Promoting Competence and Social Justice. Boston: Allyn and Bacon, 1997.
Giachello, A.L. Cultural diversity and institutional inequality. In: Adams, D.L., ed. Health Issues for Women of Color: A Cultural Diversity Perspective. Thousand Oaks, CA: Sage Publications, 1995. pp. 5–26.
Glasser, W. Reality Therapy: A New Approach to Psychiatry. New York: Harper and Row, 1965.
Glasser, W. Reality Therapy in Action. New York: Harper Collins, 2000.
Glatzer, H.T. Working through in analytic group psychotherapy. International Journal of Group Psychotherapy 19(3):292–306, 1969.5807844
Glover, N.M. Play therapy and art therapy for substance abuse clients who have a history of incest victimization. Journal of Substance Abuse Treatment 16(4):281–287, 1999.10349600
Goldberg, E.V., and Simpson T. Challenging stereotypes in treatment of the homeless alcoholic and addict: Creating freedom through structure in large groups. Social Work With Groups 18(2/3):79–93, 1995.
Goodison, L., and Schafer, H. Drug addiction therapy: A dance to the music of time. The Health Service Journal 109(5677):28–29, 1999.
Gorski, T.T., and Miller, M. Counseling for Relapse Prevention. Hazel Crest, IL: Alcoholism Systems Associates, 1979.
Gorski, T.T., and Miller, M. Counseling for Relapse Prevention. Independence, MO: Herald House/Independence Press, 1982.
Graham, A.W., Schultz, T.K., and Mayo-Smith, M.F., Ries, R.F., and Wilford, B.B., eds. Principles of Addiction Medicine. 3d ed. Chevy Chase, MD: American Society of Addiction Medicine, 2003.
Greenberger, D., and Padesky, C.A. Mind Over Mood: A Cognitive Therapy Treatment Manual for Clients. New York: Guilford Press, 1995.
Grella, C.E. Women in residential drug treatment: Differences by program type and pregnancy. Journal of Health Care for the Poor and Underserved 10(2):216–229, 1999.10224827
Greif, G.L. Ten common errors beginning substance abuse workers make in group treatment. Journal of Psychoactive Drugs 28(3):297–299, 1996.8895114
Hartman, A. Diagrammatic assessment of family relationships. Social Casework 59(8):465–476, 1978.
Hodgins, D.C., El-Guebaly, N., and Addington, J. Treatment of substance abusers: Single or mixed gender programs? Addiction 92(7):805–812, 1997.9293039
Hoffman, L. Preparing the patient for group psychotherapy. In: Price, J.R., and Hescheles, D.R., eds. A Guide to Starting Psychotherapy Groups. San Diego, CA: Academic Press, 1999. pp. 25–42.
Ivey, A., Ivey, M., and Simek-Morgan, L. Counseling and Psychotherapy: A Multicultural Perspective. Boston: Allyn and Bacon, 1993.
Johnson, V.E. I'll Quit Tomorrow. New York: Harper & Row, 1973.
Kahn, E.W. Coleadership gender issues in group psychotherapy. In: DeChant, B., ed. Women and Group Psychotherapy: Theory and Practice. New York: Guilford Press, 1996. pp. 442–462.
Kanas, N. Alcoholism and group psychotherapy. In: Pattison, E., and Kauffman, E., eds. Encyclopedic Handbook of Alcoholism. New York: Gardner Press, 1982. pp. 1011–1021.
Kanas, N., and Barr, M.A. Homogeneous group therapy for acutely psychotic schizophrenic inpatients. Hospital and Community Psychiatry 34(3):257–259, 1983.6832730
Kemker, S.S., Kibel, H.D., and Mahler, J.C. On becoming oriented to inpatient addiction treatment: Inducting new patients and professionals to the recovery movement. International Journal of Group Psychotherapy 43(3):285–301, 1993.8394289
Khantzian, E.J., Halliday, K.S., Golden, S.J., and McAuliffe, W.E. Modified group therapy for substance abusers: A psychodynamic approach to relapse prevention. American Journal on Addictions 1(1):67–76, 1992.
Khantzian, E.J., Halliday, K.S., and McAuliffe, W.E. Addiction and the Vulnerable Self: Modified Dynamic Group Therapy for Substance Abusers. New York: Guilford Press, 1990.
Kinzie, J.D., Leung, P., Bui, A., Ben, R., Keopraseuth, K.O., Riley, C., Fleck, J., and Ades, M. Group therapy with Southeast Asian refugees. Community Mental Health Journal 24(2):157–166, 1988.3402200
Kleinberg, J.L. The supervisory alliance and the training of psychodynamic group psychotherapists. International Journal of Group Psychotherapy 49(2):159–179, 1999.10198551
Kohut, H. The Restoration of the Self. New York: International Universities Press, 1977a.
Kohut, H. Preface. In: Blaine, J.D., and Julius, D.A., eds. Psychodynamics of Drug Dependence. NIDA Research Monograph 12. Washington, DC: Superintendent of Documents, U.S. Government Printing Office, 1977b. pp. vii–ix.
Kymissis, P., and Halperin, D.A., eds. Group Therapy with Children and Adolescents. Washington, DC: American Psychiatric Press, 1996.
Lakin, M. Ethical challenges of group and dyadic therapies: A comparative approach. Professional Psychology: Research and Practice 17(5):454–461, 1986.
La Salvia, T.A. Enhancing addiction treatment through psychoeducational groups. Journal of Substance Abuse Treatment 10(5):439–444, 1993.8246317
Lash, S.J., and Blosser, S.L. Increasing adherence to substance abuse aftercare group therapy. Journal of Substance Abuse Treatment 16(1):55–60, 1999.9888122
Lawson, G., and Lawson, A.W., eds. Adolescent Substance Abuse: Etiology, Treatment, Prevention. Gaithersburg, MD: Aspen Publishers, 1992.
Leahy, R.L. Cognitive Therapy: Basic Principles and Applications. Northvale, NJ: Jason Aronson, 1996.
Leshner, A.I. Understanding drug addiction: Implications for treatment. Hospital Practice: Office Edition 31(10):47–49, 1996.
Leshner, A.I. Introduction to the special issue: The National Institute on Drug Abuse's (NIDA's) Drug Abuse Treatment Outcome Study (DATOS). Psychology of Addictive Behaviors 11(4):211–215, 1997.
Levy, M. Group therapy in addictive and psychiatric disorders. In: Miller, N.S., ed. Principles and Practice of Addictions in Psychiatry. Philadelphia, PA: W.B. Saunders Company, 1997. pp. 384–391.
Loden, M., and Rosener, J.B. Workforce America! Managing Employee Diversity as a Vital Resource. Homewood, IL: Business One Irwin, 1991.
London, E.D., Bonson, K.R., Ernst, M., and Grant, S. Brain imaging studies of cocaine abuse: Implications for medication development. Critical Reviews in Neurobiology 13(3):227–242, 1999.10803636
Lopez, F. Confidentiality of Patient Records for Alcohol and Other Drug Treatment. Technical Assistance Publication Series 13. HHS Publication No. (SMA) 99–3321. Rockville, MD: Center for Substance Abuse Treatment, 1994.
Loughlin, N. A trial of the use of psychodrama for women with alcohol problems. Nursing Practice 5(3):14–19, 1992.1625760
Majewska, M.D. Cocaine addiction as a neurological disorder: Implications for treatment. In: Majewska, M.D., ed. Neurotoxicity and Neuropathology Associated with Cocaine Abuse. NIDA Research Monograph 163. NIH Publication No. 96–4019. Rockville, MD: National Institute on Drug Abuse, 1996. pp. 1–26.
Margolis, R.D., and Zweben, J.E. Treating Patients with Alcohol and Other Drug Problems: An Integrated Approach. Washington, DC: American Psychological Association, 1998.
Marlatt, G.A. Relapse prevention: A self-control program for the treatment of addictive behaviors. In: Stuart, R.B., ed. Adherence, Compliance, and Generalization in Behavioral Medicine. New York: Brunner/Mazel, 1982. pp. 329–378.
Martin, K., Giannandrea, P., Rogers, B., and Johnson, J. Group intervention with pre-recovery patients. Journal of Substance Abuse Treatment 13(1):33–41, 1996.8699541
Marziali, E., Munroe-Blum, H., and McCleary, L. The contribution of group cohesion and group alliance to the outcome of group psychotherapy. International Journal of Group Psychotherapy 47(4):475–497, 1997.9314699
Matano, R.A., and Yalom, I.D. Approaches to chemical dependency: Chemical dependency and interactive group therapy. A synthesis. International Journal of Group Psychotherapy 41(3):269–293, 1991.1885248
Matano, R.A., Yalom, I.D., and Schwartz, K. Interactive group therapy for substance abusers. In: Spira, J.L., ed. Group Therapy for Medically Ill Patients. New York: Guilford Press, 1997. pp. 296–325.
Matsukawa, L.A. Group therapy with multiethnic members. In: Tseng, W., and Streltzer, J., eds. Culture and Psychotherapy: A Guide to Clinical Practice. Washington, DC: American Psychiatric Press, 2001. pp. 243–261.
McAuliffe, W.E., and Ch'ien, J.M. Recovery training and self help: A relapse-prevention program for treated opiate addicts. Journal of Substance Abuse Treatment 3(1):9–20, 1986.3016290
McKay, J.R., Alterman, A.I., Cacciola, J.S., Rutherford, M.J., O'Brien, C.P., and Koppenhaver, J. Group counseling versus individualized relapse prevention aftercare following intensive outpatient treatment for cocaine dependence: Initial results. Journal of Consulting and Clinical Psychology 65(5):778–788, 1997.9337497
Milgram, D., and Rubin, J.S. Resisting resistance: Involuntary substance abuse group therapy. Social Work With Groups 15(1):95–110, 1992.
Millan, F., and Ivory, L.I. Group therapy with the multiply oppressed: Treating Latino, HIV-infected injecting drug users. Group 18(3):154–166, 1994.
Miller, J.B. Toward a New Psychology of Women. 2d ed. Boston: Beacon Press, 1986.
Miller, N.S., and Chappel, J.N. History of the disease concept. Psychiatric Annals 21(4):196–205, 1991.
Miller, W.R., and Rollnick, S. Motivational Interviewing: Preparing People to Change Addictive Behavior. New York: Guilford Press, 1991.
Miller, W.R., and Sanchez, V.C. Motivating young adults for treatment and lifestyle change. In: Howard, G.S., and Nathan, P.E., eds. Alcohol Use and Misuse by Young Adults. Notre Dame, IN: Notre Dame University Press, 1994. pp. 55–81.
Minkoff, K., and Drake, R.E. Homelessness and dual diagnosis. In: Lamb, H.R., and Bachrach, L.L., eds. Treating the Homeless Mentally Ill: A Report of the Task Force on the Homeless Mentally Ill. Washington, DC: American Psychiatric Association, 1992. pp. 221–247.
Najavits, L.M., Weiss, R.D., and Liese, B. Group cognitive-behavioral therapy for women with PTSD and substance use disorder. Journal of Substance Abuse Treatment 13(1):13–22, 1996.8699538
Nakkab, S., and Hernandez, M. Group psychotherapy in the context of cultural diversity. Group 22(2):95–103, 1998.
Nelson-Zlupko, L., Dore, M.M., Kauffman, E., and Kaltenbach, K. Women in recovery: Their perceptions of treatment effectiveness. Journal of Substance Abuse Treatment 13(1):51–59, 1996.8699543
Nunes-Dinis, M., and Barth, R.P. Cocaine treatment and outcome. Social Work 38(5):611–617, 1993.8211320
Office of Minority Health. National Standards for Culturally and Linguistically Appropriate Services in Health Care: Final Report. Washington, DC: Office of Minority Health, 2001.
Organista, P.B., Chun, K.M., and Marin, G., eds. Readings in Ethnic Psychology. New York: Routledge, 1998.
Ormont, L.R. The Group Psychotherapy Experience: From Theory to Practice. New York: St. Martin's Press, 1992.
Ouimette, P.C., Moos, R.H., and Finney, J.W. Influence of outpatient treatment and 12-step group involvement on one-year substance abuse treatment outcomes. Journal of Studies on Alcohol 59(5):513–522, 1998.9718103
Page, R.C., and Berkow, D.N. Group work as facilitation of spiritual development for drug and alcohol abusers. Journal for Specialists in Group Work 23(3):285–297, 1998.
Parker, J., Clevenger, J.E., and Sherman, J. The psychotherapist-patient privilege in group therapy. Journal of Group Psychotherapy, Psychodrama & Sociometry 49(4):157–161, 1997.
Paulus, M.P., Hozack, N.E., Zauscher, B.E., Frank, L., Brown, G.G., Braff, D.L., and Schuckit, M.A. Behavioral and functional neuroimaging evidence for prefrontal dysfunction in methamphetamine-dependent subjects. Neuropsychopharmacology 26(1):53–63, 2002.11751032
Pfeiffer, W., Feuerlein, W., and Brenk-Schulte, E. The motivation of alcohol dependents to undergo treatment. Drug and Alcohol Dependence 29(1):87–95, 1991.1797522
Physicians' Desk Reference. 56th ed. Oradell, NJ: Medical Economics, 2002.
Pollack, H.B., and Slan, J.B. Reflections and suggestions on leadership of psychotherapy groups. International Journal of Group Psychotherapy 45(4):507–519, 1995.7558504
Pollack, L.E., and Stuebben, G. Addiction education groups for inpatients with dual diagnoses. Journal of the American Psychiatric Nurses Association 4(4):121–127, 1998.
Powell, D.J. Clinical Supervision in Alcohol and Drug Abuse Counseling: Principles, Models, Methods. San Francisco: Jossey-Bass, 1993.
Pressman, M.A., Kymissis, P., and Hauben, R. Group psychotherapy for adolescents comorbid for substance abuse and psychiatric problems: A relational constructionist approach. International Journal of Group Psychotherapy 51(1):83–100, 2001.11191597
Prochaska, J.O., and DiClemente, C.C. The Transtheoretical Approach: Crossing Traditional Boundaries of Therapy. Homewood, IL: Dow Jones-Irwin, 1984.
Project MATCH Research Group. Matching Alcoholism Treatments to Client Heterogeneity: Project MATCH posttreatment drinking outcomes. Journal of Studies on Alcohol 58(1):7–29, 1997.8979210
Rasmussen, B. Joining group psychotherapy: Developmental considerations. International Journal of Group Psychotherapy 49(4):513–528, 1999.10530048
Rawson, R.A., Obert, J.L., McCann, M.J., and Smith, D.P. Neurobehavioral treatment for cocaine dependency. Journal of Psychoactive Drugs 22(2):159–171, 1990.2197392
Reed, B.G., Newman, P.A., Suarez, Z.E., and Lewis, E.A. Interpersonal practice beyond diversity and toward social justice: The importance of critical consciousness. In: Garvin, C., and Seabury, B., eds. Interpersonal Practice in Social Work. 3d ed. Boston: Allyn and Bacon, 1997. pp. 44–78.
Reilly, P.M., and Shopshire, M.S. Anger management group treatment for cocaine dependence: Preliminary outcomes. American Journal of Drug and Alcohol Abuse 26(2):161–177, 2000.
Rice, A.K. Learning for Leadership: Interpersonal and Intergroup Relations. London: Tavistock Publications, 1965.
Roberts, A. Battered Women and Their Families: Intervention Strategies and Treatment Programs. New York: Springer, 1998.
Rosenthal, L. The thermostatic function of the group analyst: Regulating the degree of stimulation in the group. Modern Psychoanalysis 24(2):157–164, 1999a.
Rosenthal, L. Group supervision of groups: A modern analytic perspective. International Journal of Group Psychotherapy 49(2):197–213, 1999b.10198553
Rutan, J.S., and Stone, W.N. Psychodynamic Group Psychotherapy. 3d ed. New York: Guilford Press, 2001.
Salvendy, J.T. Ethnocultural considerations in group psychotherapy. International Journal of Group Psychotherapy 49(4):429–464, 1999.10530045
Sampl, S., and Kadden, R. Motivational Enhancement Therapy and Cognitive Behavioral Therapy for Adolescent Cannabis Users: 5 Sessions. Cannabis Youth Treatment Series: Vol. 1. (SMA) 01–3486. Rockville, MD: Center for Substance Abuse Treatment, 2001.
Scheidlinger, S. The group psychotherapy movement at the millennium: Some historical perspectives. International Journal of Group Psychotherapy 50(3):315–339, 2000.10883548
Schmitz, J.M., Oswald, L.M., Jacks, S.D., Rustin, T., Rhoades, H.M., and Grabowski, J. Relapse prevention treatment for cocaine dependence: Group vs. individual format. Addictive Behaviors 22(3):405–418, 1997.9183510
Shapiro, E. Empathy and safety in group: A self psychology perspective. Group 15(4):219–224, 1991.
Silverstein, R. Bending the conventional rules when treating the ultra-Orthodox in the group setting. International Journal of Group Psychotherapy 45(2):237–249, 1995.7759182
Singer, D.L., Astrachan, B.M., Gould, L.J., and Klein, E.B. Boundary management in psychological work with groups. Journal of Applied Behavioral Science 11(2):137–176, 1975.
Spitz, H.I. Group psychotherapy of substance abuse in the era of managed mental health care. International Journal of Group Psychotherapy 51(1):21–41, 2001.11191593
Stevens, S.J., Arbiter, N., and Glider, P. Women residents: Expanding their role to increase treatment effectiveness. International Journal of Addictions, 24(5):425–434, 1989.
Straussner, S.L.A., ed. Clinical Work With Substance-Abusing Clients. New York: Guilford Press, 1993.
Straussner, S.L.A. Group treatment with substance abusing clients: Model of treatment during the early phases of outpatient group therapy. Journal of Chemical Dependency Treatment 7(1/2):67–80, 1997.
Strickland, T.L., Mena, I., Villanueva-Meyer, J., Miller, B.L., Cummings, J., Mehringer, C.M., Satz, P., and Myers, H. Cerebral perfusion and neuropsychological consequences of chronic cocaine use. Journal of Neuropsychiatry and Clinical Neurosciences 5(4):419–427, 1993.
Swiller, H.I., Lang, E.A., and Halperin, D.A. Process groups for training psychiatric residents. In: Alonso, A., and Swiller, H.I., eds. Group Therapy in Clinical Practice. Washington, DC: American Psychiatric Press, 1993. pp. 533–545.
Takeuchi, D.T., Sue, S., and Yeh, M. Return rates and outcomes from ethnicity-specific mental health programs in Los Angeles. American Journal of Public Health 85(5):638–643, 1995.7733422
Taylor, J., and Jackson, B. Factors affecting alcohol consumption in black women: Part II. International Journal of the Addictions 25(12):1415–1427, 1990.
Thornton, C., and Carter, J. Treating the black female alcoholic: Clinical observation of black therapists. Journal of the National Medical Association 80(6):644–647, 1988.3292775
Tonigan, J.S., Toscova, R., and Miller, W.R. Meta-analysis of the literature on Alcoholics Anonymous: Sample and study characteristics moderate findings. Journal of Studies on Alcohol 57(1):65–72, 1996.8747503
Torres-Rivera, E., Wilbur, M.P., Roberts-Wilbur, J., and Phan, L. Group work with Latino clients: A psychoeducational model. Journal for Specialists in Group Work 24(4):383–404, 1999.
Toseland, R.W., and Siporin, M. When to recommend group treatment: A review of the clinical and the research literature. International Journal of Group Psychotherapy 36(2):171–201, 1986.3733290
Trepper, T.S., Nelson, T.S., McCollum, E.E., and McAvoy, P. Improving substance abuse service delivery to Hispanic women through increased cultural competencies: A qualitative study. Journal of Substance Abuse Treatment 14(3):225–234, 1997.9306298
Tseng, W., and Streltzer, J., eds. Culture and Psychotherapy: A Guide to Clinical Practice. Washington, DC: American Psychiatric Press, 2001.
Tylim, I. Group psychotherapy with Hispanic patients: The psychodynamics of idealization. International Journal of Group Psychotherapy 32(3):339–350, 1982.7129713
Vannicelli, M. Group therapy aftercare for alcoholic patients. International Journal of Group Psychotherapy 38(3):337–353, 1988.2846450
Vannicelli, M. Removing the Roadblocks: Group Psychotherapy with Substance Abusers and Family Members. New York: Guilford Press, 1992.
Vannicelli, M. Leader dilemmas and countertransference considerations in group psychotherapy with substance abusers. International Journal of Group Psychotherapy 51(1):43–62, 2001.11191594
Volkow, N.D., Hitzemann, R., Wang, G.J., Fowler, J.S., Wolf, A.P., Dewey, S.L., and Handlesman, L. Long-term frontal brain metabolic changes in cocaine abusers. Synapse 11(3):184–190, 1992.1636149
Volkow, N.D., Mullani, N., Gould, K.L., Adler, S., and Krajewski, K. Cerebral blood flow in chronic cocaine users: A study with positron emission tomography. British Journal of Psychiatry 152:641–648, 1988.
Walitzer, K.S., Dermen, K.H., and Connors, G.J. Strategies for preparing clients for treatment: A review. Behavior Modification 23(1):129–151, 1999.9926524
Wallace, J. Working with the preferred defense structure of the recovering alcoholic. In: Zimberg, S., Wallace, J., and Blume, S., eds. Practical Approaches to Alcoholism Psychotherapy. New York: Plenum Press, 1978. pp. 19–29.
Wallace, J. New disease model of alcoholism. Western Journal of Medicine 152(5):502–505, 1990.
Wallace, J., and Blume, S., eds. Practical Approaches to Alcoholism Psychotherapy. New York: Plenum Press, 1978. pp. 19–29.
Washton, A.M. Structured outpatient group therapy with alcohol and substance abusers. In: Lowinson, J.H., Ruiz, P., Millman, R.B., and Langrod, J.G., eds. Substance Abuse: A Comprehensive Textbook. 2d ed. Baltimore: Williams & Wilkins, 1992. pp. 508–519.
Weinberg, H. Community Unconscious on the Internet (Draft). Special Issue of Group Analysis (March 2002) “Group Analysis in the New Millennium” Ben Davidson - Guest Editor. United Kingdom: GroupInterVisual Ltd., 2002.
Weinberg, H. Group process and group phenomena on the Internet. International Journal of Group Psychotherapy 51(3):361–378, 2001.11447785
Westermeyer, J. Cultural aspects of substance abuse and alcoholism: Assessment and management. Cultural Psychiatry 18(3):589–605, 1995.
Wheelan, S.A. Co-therapists and the creation of a functional psychotherapy group: A group dynamics perspective. Group Dynamics 1(4):306–310, 1997.
Whitaker, D.S., and Lieberman, M.A. Psychotherapy Through the Group Process. New York: Atherton Press, 1965.
Wilbur, M.P., and Roberts-Wilbur, J. Group work with men's beliefs. Journal for Specialists in Group Work 19(2):65–82, 1994.
Winkelman, M. Ethnic Sensitivity in Social Work. Dubuque, IA: Eddie Bowers Publishing, 1995.
Wolf, A., and Schwartz, E.K. Psychoanalysis in Groups. New York: Grune and Stratton, 1962.
Yalom, I.D. The Theory and Practice of Group Psychotherapy. 2d ed. New York: Basic Books, 1975.
Yalom, I.D. The Theory and Practice of Group Psychotherapy. 4th ed. New York: Basic Books, 1995.
Yeh, M., Takeuchi, D.T., and Sue, S. Asian American children in the mental health system: A comparison of parallel and mainstream outpatient service centers. Journal of Clinical Child Psychology 23:5–12, 1994.
Zweben, J.E. Integrating psychotherapy and 12-step approaches. In: Washton, A.M., ed. Psychotherapy and Substance Abuse: A Practitioner's Handbook. New York: Guilford Press, 1995. pp. 124–140.