# 7 Training and Supervision

In This Chapter…

Training

Training Opportunities

Training Opportunities in Types of Group Therapy

Supervision

The Supervisor's Essential Skills

The Supervisory Alliance

Funding for Training and Supervision Programs

## Overview

Substance abuse counselors come to the field from a variety of backgrounds, education, and experience. Many have not had specific training and supervision in the special skills needed to be an effective group therapist. Counselors may be promoted to positions of supervision without the additional training in the skills needed to perform supervisory tasks, which are

• Administrative
• Evaluative
• Clinical
• Supportive

This chapter describes the skills group therapy clinicians need, the purpose and value of clinical supervision, and how to get the training necessary to be a top-flight group clinician or supervisor of clinicians.

## Training

In a brief article, Geoffrey Greif lists “Ten Common Errors Beginning Substance Abuse Workers Make in Group Treatment.” He contends that these errors are common because people who abuse substances are supremely adept at helping group leaders make mistakes. Some of these are

• Impatience with the clients' slow pace of dealing with change
• Inability to drop the mask of professionalism
• Failure to recognize countertransference issues
• Not clarifying group rules
• Conducting individual therapy rather than using the entire group effectively
• Failure to integrate new members effectively into the group (Greif 1996)

Training and education for group therapists working in the substance abuse field can alleviate or eliminate such errors. Simultaneously, additional training is becoming even more critical because (1) the traditionally separate fields of mental health and substance abuse counseling increasingly overlap, requiring more and more cross-knowledge; and (2) an ever younger pool of clients is presenting with more cognitive deficits, abuse issues, and co-occurring disorders.

A group leader for people in substance abuse treatment requires competencies in both areas: group work and addiction. For example, facilitators should understand group process, group dynamics, and the stages of group development; they need to understand that group therapy is not individual therapy in a group setting. Further, facilitators should be aware that although Alcoholics Anonymous (AA) or other 12-Step programs are complementary to substance abuse treatment, these modalities are distinct from group therapy.

A group leader for people in substance abuse treatment requires competencies in both group work and addiction.

As trends move toward integrated mental and substance abuse treatment, counselors already adept at working with groups of clients with substance abuse problems may need specific training to manage mental disorders such as depression, which often co-occur with substance abuse. Further, counselors in recovery may be familiar with the stages of addiction treatment but lack a background in group therapy.

On the other hand, group counselors who have treated clients without addictions may not always have sufficient skills to combat addiction and its effect on a group therapy situation.

Therapists need to become well versed in the substance abuse treatment philosophy, its terminology, and techniques of recovery, including the self-help approaches (Kemker et al. 1993).

A group therapist with roots in the mental health field planning to become more competent in group work for the treatment of substance abuse will need to make a number of adjustments. First, the therapist working with clients with substance use disorders should be able to screen and assess for substance abuse problems. On this subject, see TIP 11, Simple Screening Instruments for Outreach for Alcohol and Other Drug Abuse and Infectious Diseases (Center for Substance Abuse Treatment [CSAT] 1994b); TIP 24, A Guide to Substance Abuse Services for Primary Care Clinicians (CSAT 1997a); and TIP 31, Screening and Assessing Adolescents for Substance Use Disorders (CSAT 1999c). Second, the therapist will need to recognize the importance of abstinence. Third, the therapist will need to be sensitive to a client's anxiety and shame, especially in early stages of treatment for substance abuse. In a modified interpersonal process group, for example, the group leader should create a safe, supportive environment free from the stigma of addiction while promoting a client's attachment to other group members, self-help groups, therapy, and the entire healing community of which the group is a part.

Group therapists who move into the treatment of clients who are chemically dependent typically need staff development in:

• Theories and techniques. Theories may include traditional psychodynamic methods, cognitive—behavioral modes, and systems theory. From such theoretical bases are drawn applications that pertain to a wide variety of settings and particular client populations.
• Observation. The observer can sit in on group therapy sessions, study videotapes of senior therapists leading group sessions (ordinarily followed by a discussion), or watch groups live through one-way mirrors as experienced therapists lead groups.
• Experiential learning. With this approach, a therapist may participate in a training group offered by an agency, become a member of a personal therapy group (these are often process-oriented), or join in group experiences at conferences, such as those offered at the Institute of the American Group Psychotherapy Association's annual conference. (For more on experiential training, see the section on “Experiential Learning” later in this chapter.)
• Supervision. A large part of this type of training is ongoing work with groups under the supervision of an experienced therapist. Supervision may be dyadic, that is, supervisor and supervisee, but while simple and easy, this setting does not allow opportunities for actual group work. Supervision of group therapists ideally is conducted in a supervisory group format. Supervision in a group enables therapists to obtain first-hand experience and helps them better understand what is happening in groups that they will eventually lead. Several other important benefits accrue as well. The supervisory group creates a safe place for trainees to reveal themselves and the skills they need to develop. It provides support from peers and a chance to learn from their experience. It stimulates dialog around theory and technique and encourages a healthy kind of competition. It expands the capacity for empathy (Alonso 1993). Finally, this kind of supervision provides an opportunity for trainees to explore sensitive issues, such as child abuse, sexual abuse, and prostitution. (For more on supervisory groups, see the “Supervision” section later in this chapter.)

Before leaving the matter of what group leaders treating substance abuse should know, it is desirable to assess the importance of the group facilitator's being a person who is in recovery. There is some tension around this issue. Culbreth (2000) reviewed 16 relevant studies and concluded that while clients do not perceive differences in treatment related to a therapist being in recovery or not, and no differences in treatment outcomes could be discerned, recovering and nonrecovering therapists do not perceive substance abuse problems the same way, use different methods to treat substance abuse, and differ in personality and attitudinal traits.

Some people dismiss the notion that all people with addictions prefer to work with a group leader who is in recovery. They insist that, on the contrary, some people with addictions prefer not to work with recovering leaders, fearing that leaders in recovery will share the issues and problems of people with addictions and thus will not be in a position to help them with these issues.

Others say that a staff of group leaders should include people in recovery. Those holding this point of view reason that people with addictions are highly skilled at manipulating people and situations. With both recovering and nonrecovering group leaders, a clinical team will be best positioned to see and treat the whole client—and not be duped by agreeable, but false, façades.

In group therapy with clients with substance use disorders, it can be challenging to establish and maintain credibility with all group clients. Facilitators not in recovery will need to anticipate and respond to group members' questions about their experience with substances and will need skills to handle group dynamics focused on this issue. On the other hand, leaders who are in recovery may tend to focus too much on themselves. Group leaders emotionally invested in acting as models of recovering perfection are easy marks for clients.

Supervision in a group enables therapists to obtain first-hand experience.

Of course, the main issue is not whether the leader is in recovery. What matters most is whether the counselor knows the fields of group therapy and addiction treatment and has good judgment and leadership skills (see Figure 7-1). Helping the group explore why the recovery status of the group leader is important can be discussed if and when the issue is raised.

Figure 7-1 How Important Is It for a Substance Abuse Group Leader To Be In Recovery?

A leader who is in recovery will probably elicit trust more quickly from group members, especially people with hard-core addictive backgrounds, because such clients often assume—correctly or not—that a person in recovery can empathize with the pain of addiction. Such group leaders, as success stories, have the added advantage of serving as role models for group members struggling against temptations and cravings in the early stages of recovery.

A leader having personally recovered, however, does not automatically make that person an effective therapist. Many counselors in recovery cannot make the switch from self- to client-centered approaches and hold rigid views of how to manage the recovery process.

Source: Consensus Panel.

### Training Opportunities

National professional organizations are a rich source of training. Through conferences or regional chapters, national associations provide training—both experiential and direct instruction—geared to the needs of a wide range of professionals, from the novice to the highly experienced therapist. More training options are usually available in large urban areas. It is likely, however, that online training will make some types of professional development accessible to a greater number of counselors in remote areas. A number of professional organizations that provide a variety training settings are listed below. Inclusion in the list does not imply endorsement by the Substance Abuse and Mental Health Services Administration (SAMHSA). Note that not all of these organizations approach substance abuse treatment through group therapy.

#### Professional associations

##### American Group Psychotherapy Association (AGPA)

AGPA, founded in 1942, has more than 4,000 members and 33 local and regional affiliate societies, which provide a broad range of professional, educational, and social support for group therapists in the United States and abroad. The organization publishes The International Journal of Group Psychotherapy and The Group Circle.

AGPA's Special Interest Groups (SIGs) share ideas and knowledge through interaction with colleagues. Some SIGs focus on substance abuse; children and adolescents; cotherapy; diversity; gay, lesbian, and bisexual clients; the medically ill; the severe and persistent mentally ill; and women in group therapy. SIGs are open to nonmembers of AGPA.

At its annual conferences, AGPA offers training institutes for individuals. Three of these institutes focus on substance abuse training. The association can also provide in-house training to agency staff at a very low cost. Further, AGPA has developed basic and advanced core courses. They tend to be practical in nature, and they contribute to certification. The certified group therapy program is available through the regional affiliates.

##### American Psychiatric Association (APA)

The American Psychiatric Association is a medical specialty society recognized world-wide. Its more than 35,000 U.S. and international member physicians work together to ensure humane care and effective treatment for all persons with mental disorder, including mental retardation and substance-related disorders. To its members, the APA offers board certification and continuing medical education from online sources as well as at annual meetings.

##### American Psychological Association (APA)

The APA College of Professional Psychology offers a Certificate of Proficiency in the Treatment of Alcohol and Other Psychoactive Substance Use Disorders. This certificate is a uniform nationally recognized credential offered exclusively to licensed psychologists who meet specific criteria related to experience in substance abuse treatment, including completion of an APA examination.

Two of APA's 55 subgroups may be of special interest. Division 49, Group Psychology and Group Psychotherapy, serves psychologists' interest in research, teaching, and the practice of group psychology and group therapy. Division 50, Addictions, centers on research, professional training, and clinical practice dealing with a broad range of addictive behaviors. Both divisions publish a newsletter and journal, and both have annual meetings and award programs.

APA has extensive resources on cultural diversity and ethnic/racial issues related to therapy, including online brochures, a quarterly journal, Cultural Diversity and Ethnic Minority Psychology, and an Office of Ethnic Minority Affairs that provides publications and information. Recent APA books on this topic describe relationships among Asian-American women and health-promoting and health-compromising behaviors among minority adolescents.

##### American Society of Addiction Medicine (ASAM)

One of ASAM's goals is educating health professionals about addiction. The organization develops credentialing guidelines and publishes the comprehensive and influential volume, Principles of Addiction Medicine (Graham et al. 2003), among other books and journals. The society has also developed patient placement criteria called PPC-2R (published in 2001), as well as screening and assessment tools. Each year, ASAM hosts several conferences and training meetings on various aspects of addiction medicine. ASAM offers audiotapes of its conferences for continuing medical education credit. Physicians certified by the society in addiction medicine are listed in an ASAM directory.

##### Association for the Advancement of Social Work with Groups (AASWG)

This international professional organization has developed standards that reflect the distinguishing features of group work, as well as the unique perspective that social workers bring to their practice with groups. These standards are applicable to the types of groups that social workers encounter in the various settings in which they practice and allow the practitioner to apply a variety of relevant group work models. AASWG has also collected a 29-page bibliography of books, monographs, and videos available for practitioners, educators, and researchers.

##### Association for Specialists in Group Work (ASGW)

A division of the American Counseling Association, the ASGW was founded to promote high quality in group work training, practice, and research, both nationally and internationally. The organization has developed Best Practice Guidelines, Principles for Diversity-Competent Group Workers, and Professional Standards for the Training of Group Workers. These criteria are available on the organization's Web site: http://asgw.org. The Web site also provides resources, including products, institutes, and links to other Web pages, along with a calendar describing upcoming conferences and professional development activities of interest to a broad spectrum of group leaders.

##### National Association of Alcohol and Drug Abuse Counselors (NAADAC)

NAADAC is the largest national organization for alcoholism and drug abuse professionals across the country. The association offers opportunities for professional development, such as workshops, seminars, and education programs for members. In addition to a bimonthly magazine, The Counselor, NAADAC provides an Educational Resources Guide that lists colleges and universities offering degree and certification programs in addiction counseling and a listing of approved education providers for trainers in each State. Through its national certification program, including the National Certified Addiction Counselor and the Masters Addiction Counselor designation, NAADAC recognizes counselors with advanced skill levels.

##### National Association of Black Social Workers (NABSW)

NABSW offers national and international education conferences, as well as projects and mentoring programs to support the work of African-American social workers.

##### National Association of Social Workers (NASW)

NASW is the world's largest organization of professional social workers. The association has developed practice standards and clinical indicators, a credentialing program, continuing education courses on national and State levels, and numerous publications for members and nonmembers.

Distance learning courses are listed on NASW's Web site. Many topics are relevant to addiction counselors, such as Chemical Dependency and the African American: Counseling Strategies and Community Issues, Dual Diagnosis, HIV/AIDS and Substance Abuse, and Multicultural Counseling—The New Paradigm for Substance Abuse Professionals.

##### National Registry of Certified Group Psychotherapists

In an effort to maintain the highest standards for group therapy practice, the National Registry certifies group therapists according to nationally accepted criteria and promotes these criteria among mental health professionals, employers, insurers, education personnel, and clients. The registry has developed guidelines that are clinically based, client-focused service indicators to be used in discussions with accrediting organizations regarding appropriate standards of quality. The guidelines also apply in discussions with employers regarding delivery of mental health services in groups, as well as managed care and health maintenance organizations. The registry's newsletter, The Group Solution, provides up-to-date information on the use of group therapy in the current behavioral health care atmosphere.

Frequent continuing education seminars are given by local affiliate societies and at the annual meeting of the parent group, AGPA.

#### Other sources of training

Many agencies mandate a certain number of trainings each year and provide in-house training that draws on the resources of credentialed senior management. Each of the States has a department of alcohol and drug abuse services, and some may provide substance abuse training for group therapy. Training in mental health issues is often available through the mental health division of government agencies, professional associations, and psychological and psychiatric organizations. Most colleges, universities, and community colleges offer relevant courses, many of them certified by professional organizations.

Several Federal entities offer resources for training. SAMHSA provides a number of resources, including publications for substance abuse treatment professionals. These include the Technical Assistance Publication (TAP) series. TAP 21 is relevant to training: Addiction Counselor Competencies: The Knowledge, Skills, and Attitudes of Professional Practice (CSAT 1998a).

In addition, SAMHSA's Treatment Improvement Protocol (TIP) series includes more than 40 publications to assist therapists and counselors in treating people with substance abuse problems. To view TAPs and TIPs online, go to http://www.kap.samhsa.gov (https://www.samhsa.gov/kap) and click on “Publications.”

These publications also are available free through the SAMHSA Store at 1-877-726-4727. The SAMHSA Store can also provide a catalog of other resources and publications on addiction counseling and treatment. One of them, for example, is the National Institute on Drug Abuse, which provides information on research and treatment.

The National Mental Health Information Center (NMHIC) at SAMHSA provides a wealth of information for the public and for treatment professionals. A search for “training” on its Web site resulted in a list of numerous opportunities for training and technical assistance on a variety of topics as well as bibliographies, publications, and links.

### Training Opportunities in Types of Group Therapy

#### Experiential learning

For the therapist in training, the experience of being in a group is particularly important for both the development of skills and the level of comfort with one's developing leadership style. Whether this experience is acquired through a process group, a supervision group, or experiences offered through organizations like the AGPA, experiential opportunities afford learners not only insight into their personal growth, but a first-person appreciation for the healing power of group therapy.

Experienced group therapists are able to lead process groups because training in this area is part of the preparation program for mental health professionals. In these groups, members study their own behavior to learn about group dynamics, individual dynamics, boundaries, and interpersonal communications. In addition, leadership of process groups provides one of the best continuing education tools available to senior clinicians (Swiller et al. 1993). One experienced supervisor of training groups for therapists in training has found that “one of the most striking aspects of the supervision of group therapists in the group setting is its effectiveness in bringing about the identification, emotional recognition, and resolution of…untherapeutic behaviors, which we term counterresistances” (Rosenthal 1999b, p. 201).

SAMHSA provides a number of resources, including publications for substance abuse professionals.

A great many institutions and individuals offer workshops and courses in conducting group therapy. One of these is the A.K. Rice Institute and its affiliate societies, which provides group relations training based on the Tavistock model, which originated at the Tavistock Institute in England. The training, offered in weekend or longer conferences, is a model of experiential training that focuses exclusively on group-level dynamics.

The A.K. Rice Institute

Anne-Marie Kirkpatrick, R.N., Administrator

P.O. Box 1776

Jupiter, Florida 33468-1776

Phone: (561) 744-1350

Fax: (561) 744-5998

#### Expressive therapies

A wide range of expressive therapies (therapy based on an artist's working process) is often used in substance abuse treatment. Expressive therapy groups may use dance, music, art, writing, psychodrama, drama, role playing, adventure, and gestalt. Training in these areas is available through AGPA, ASGW, and APA. The Gestalt Institute has training centers in most large cities and offers a certification in psychodrama.

The National Institute of Expressive Psychotherapy offers a 2-year online program for those who have participated annually in the institute's 2-day residency. Professionals are required to participate as a member of a role-playing or drama group before attending classes in techniques and learning how to apply them with a population that has substance abuse problems. The National Expressive Therapy Association offers conferences, professional education, and in affiliation with the National Institute of Expressive Therapy, continuing education units, credentialing, and board certification.

#### Cross-training

Though group therapists work in the field of mental health, they generally have little training in the specifics of substance abuse treatment. This situation will have to change if the fields of substance abuse treatment and mental health are to integrate their activities.

To supplement courses that professional organizations offer individuals, agencies can use a case study approach. Case studies that include educational materials on diagnosis, symptoms, and treatment serve as a good foundation for cross-training. The cases that cause counselors to struggle the most could be analyzed. What strategies were used? What were the outcomes? What alternatives did other staff recommend? Case conferences can be conducted at weekly staff development sessions, as part of regular meetings, or (more quickly) at morning feedback meetings on clinical topics. A case conference might involve counselors, social workers, and psychologists.

#### Legal issues

It is important for therapists to know Federal regulations and the laws of their States, especially those concerning “duty to warn” stipulations regarding the abuse of children or elders, commitment procedures for psychiatric clients, and confidentiality laws pertaining to HIV/AIDS, adolescents, and managed care. Practitioners should be familiar with the Federal confidentiality regulation, 42 C.F.R. Part 2, Confidentiality of Alcohol and Drug Abuse Patient Records. In addition, there are State laws that also guide the confidentiality of alcohol and drug abuse information, and whichever is more restrictive (i.e., State law or Federal law) governs. Professional and legal organizations usually address these topics in their coursework. It is best to find such courses at the regional or State level, so that attendees can grasp the laws governing residents in their specific geographical areas.

#### Videos

While impersonal media cannot replace the relationships between supervisors and trainees, videos can be used to explain theoretical principles, provide information on various types of drugs, and support skills-building activities.

#### Distance learning

Distance learning systems, which often communicate via cable or satellite, can assist with explaining concepts, theories, and case studies. Like videos, distance learning may lack the close personal relationship with a supervisor, but interactive forms of distance learning do permit questions, comments, and requests for clarification.

Group therapy for trainees using an online chat room is an interesting possibility and could be especially helpful to people in remote settings. Licensing boards, however, would first need to resolve any potential legal issues regarding confidentiality. Also, some critics have worried that computerized communication would interfere with attachment (one of the most powerful therapeutic factors). This problem does not seem to occur in educational seminars conducted online (see Figure 7-2 on p. 132).

Figure 7-2 Does Online Communication Impede Attachment?

As a faculty member with the Fielding Graduate Institute, a distance learning program, I teach psychology in both on- and offline formats. In many of the online seminars, students post their papers and comment on the contributions of others. The students are dispersed around the country, so few (if any) know each other prior to the seminar.

Even though the students' interactions are asynchronous (that is, not in real time; a lag separates comment and response), a group of learners develops that is indistinguishable from learners sitting in the same room together. Alliances develop between students who share similar ideas, and disagreements take place between opposing positions. The attachments that develop through the written word outside of real time seem as genuine as any other relationships.

In the online seminars, some students find in cyberspace a safer format than traditional classes. Not having to confront all the verbal cues that may distract people in a face-to-face conversation, learners are freer to be genuine. Several of my students who were involved in a seminar with in-person and online components were more interactive and spontaneous in the online segment.

I don't see why these dynamics would be different in supervisory groups. I don't know of any online therapy groups, but some AA meetings are conducted online.

Further, Haim Weinberg operates a discussion list that includes about 400 group therapists from more than 30 countries. This arena for exchanging ideas about group therapy behaves very much like any large group, with a few surprising departures. Among them:

• In this highly diverse group representing many schools of thought, conflicts do not arise over differing theoretical stances or the appropriateness of interventions. Instead, “word wars,” (commonly called “flaming”) break out due to impatience or personal attitudes and exchanges. One member wrote, for example, “I thought you either have to be very young and inexperienced or very rude and insulting.” Some of the flaming seems to stem from misunderstandings that in turn result from having only words as cues. What is meant in jest, for example, may be taken seriously (Weinberg 2002).
• Traditionally, the larger the group, the more impersonal it was, but Weinberg finds startling self-disclosure and intimacy over the Internet. For example, a man whose newborn son had died wrote, “My heart is broken. Words can't convey the grief, and I realize only now that the depth of this pain is beyond comprehension. I feel waves of horrible sadness and utter bewilderment.” Messages of condolence flooded back to the distraught father (Weinberg 2002).

Source: A Consensus Panel member.

Every State has a credentialing process for substance abuse treatment professionals, and NAADAC lists all the particulars at http://www.NAADAC.org. At the same address, NAADAC posts training calendars and a great deal of other information on training opportunities.

The 14 regional Addiction Technology Transfer Centers (ATTCs), launched by SAMHSA's CSAT in 1993, connect substance abuse treatment professionals to a wide variety of useful information. ATTCs

• Provide State-by-State credentialing information
• Post news in the field
• List new resources, including publications
• Translate technical and academic journal articles into easy-to-read language
• List alcohol and other drug treatment programs in each State
• Provide a worldwide catalog of online courses

To tap into ATTC's lode of professional development information, log onto http://www.nattc.org (https://attcnetwork.org/).

## Supervision

Supervisory oversight is a significant training requirement for group therapists. Powell (1993) defines clinical supervision as “a disciplined, tutorial process wherein principles are transformed into practical skills with four overlapping foci—administrative, evaluative, clinical, and supportive.” Powell's description points out that the clinical supervisor has an administrative task, namely the development of an appropriate supervision plan for clinician trainees. This task includes planning, coordination, and delegation of responsibilities; determining appropriate staff assignments; and helping to define administrative polcies and procedures.

Every State has a credentialing process for substance abuse treatment professionals.

In addition, the clinical supervisor has duties in the sphere of evaluation. As the skills and knowledge of new group facilitators begin to grow, they need consistent, useful feedback that will direct their work and will support professional growth. In the early stages of group facilitation, answers to the question, “How am I doing?” are extremely important, but unfortunately, the question often goes unanswered. Appropriate clinical supervision will not only keep this question in mind, but also provide clear, cogent responses to trainees. Figure 7-3 gives an example of group experiential training.

Figure 7-3 Group Experiential Training

Through the Mountain Area Health Education Center in Asheville, North Carolina, I conducted an 18-month intensive group training and supervision experience, which is one of many ways to provide clinicians with an expanded knowledge base and the opportunity to sense the power of group therapy. The group met one Saturday a month from 9:00 a.m. to 6:00 p.m.

The model had three main components. The first, conducted in a direct instruction format, communicated basic, intermediate, and eventually advanced group skills. It also highlighted the role of failed attachment in the expression of addictive disease and the theoretical means by which groups address these concerns.

The trainees' experiential group process, the second component, took place three times throughout the day. In these 1-hour sessions, trainees participated in a training group. From the outset, it was made clear that this training group was not therapy. Although personal information inevitably was shared, the primary purpose of the experience was trainees' encounter with the here-and-now aspects of interpersonal group process, while being exposed to the same anxieties, excitement, and achievements that clients feel within the context of group. At the end of each experiential group process, trainees evaluated not only the group process, but also reflected on aspects of the supervisor's leadership style, commenting on its facilitation of the process or difficulties it presented.

The third aspect of this training and supervision experience was an in-depth evaluation of the clinical experiences of the trainees. At each session, group members brought in clinical issues that occurred in their practice for comment, discussion, and review. They received information not only from the group supervisor, but also from peers. This opportunity enabled trainees to integrate a theory base with practice, thus satisfying one of Powell's key components of clinical supervision, that is, “a tutorial process wherein principles are transformed into practical skills” (Powell 1993).

After leading this intensive experience, as well as many less intensive 30-hour training courses in group therapy, the need for such continuing training opportunities is clear to us. We can say with some authority that the continued advancement of one's personal skills is essential, from initiation into the field throughout the trajectory of a professional's career.

Source: A Consensus Panel member.

The clinical function that the supervisor fulfills is the development of a basic core of knowledge and skills, which includes an in-depth understanding of addictive disease, an integrated model of group process, group dynamics, and the stages of group development.

The interaction between supervisory personnel and trainees has a supportive function, which is vital to the growth of trainees. When they begin to apply their newly acquired knowledge is the time that they need the most support and the most discerning supervision.

The supervisory alliance is needed to teach the trainee the skills and knowledge required to lead groups effectively.

Clinical supervision, as it pertains to group therapy, often is best carried out within the context of group supervision. Group dynamics and group process facilitate learning by setting up a microcosm of a larger social environment. Each group member's style of interaction will inevitably show up in the group transactions. Given enough time, all the people in the supervisory group will interact with group members just as they interact with others in wider social and clinical spheres, and every person will create in the group the same interpersonal universe inhabited outside the group. As this process unfolds, group members, guided by the supervisor, learn to model effective behavior in an accepting group context.

For the beginning counselor, supervisory groups reduce, rather than escalate, the level of threat that can accompany supervision. In place of isolation and alienation, group participation gives counselors a sense of community. They find that others share their worries, fears, frustrations, temptations, and ambivalence. This reassurance is especially beneficial to novice counselors. Further,

• Group disclosure increases the potential for self-disclosure and confirmation, creating opportunities for growth.
• Empathy and sharing of interests are available to a greater extent than in individual supervision.
• Working together over time, a group can reinforce its members' personal growth.
• Alternative clinical approaches and methods of helping are available to a far greater extent than in dyadic supervision. As a result, group members acquire a broad perspective on counseling styles.
• Each counselor can do reality testing, presenting perceptions for peer scrutiny, and possibly, validation.
• The potential for critique is greatly expanded (Powell 1993).

For treatment facilities, group supervision is attractive in its efficiency and effectiveness:

• It provides a cost-effective way of supervising more people in the same amount of time.
• The diversity of people in the group increases opportunities for learning. The number of group members (up to the desired limit of four to six members) exponentially expands the range of learning opportunities.
• Group supervision creates a working alliance among counselors, engendering a sense of psychological safety and reducing self-defeating behavior (Powell 1993).

### The Supervisor's Essential Skills

A supervisor should be competent in several content areas, including substance abuse treatment, group training, cultural competence, and diagnosis of co-occurring conditions. A supervisor may be an administrator, an in-house trainer, or a therapist from another agency.

A recent survey of members of NAADAC indicates that many counselors receive and are satisfied with weekly clinical supervision. However, a significant percentage of the respondents (who were not differentiated as to whether they work with individuals or groups) indicated they receive no clinical supervision (Culbreth 1999). This finding is disturbing considering the benefits of clinical supervision for the delivery of high-quality service to clients and the professional development of counselors. Other findings from the NAADAC survey have clear implications for supervisory training. For example, respondents preferred a supervisor who is a knowledgeable professional in the field and supervision that is more proactive and intentional than reactive (Culbreth 1999).

### The Supervisory Alliance

Some training experts believe the key to effective group therapy supervision is the development of the supervisory alliance. This positive working relationship between the supervisor and trainee is a unique and appropriate setting within which a new therapist can develop skills in group analysis and refine an ability to develop appropriate treatment strategies.

The supervisory alliance is needed to teach the trainee the skills and knowledge required to lead groups effectively and to make sure that the group accomplishes its purpose. The supervisor helps by establishing an open and collaborative climate, identifying the unique learning needs and styles of the supervisory group members, formulating a responsive supervisory contract, and pinpointing any problems that emerge within the alliance (Kleinberg 1999). Supervision also includes encouraging and mentoring students from specific cultural groups, since it is difficult to locate well-trained therapists to treat certain populations.

#### Assessment of trainee skills

The supervisor should be able to assess the various domains that trainees are required to master.

• Clinical skills (from selecting prospective group members and designing treatment strategies to planning and managing termination)
• Comprehensive knowledge of substance abuse, which, depending upon the treatment setting, could entail broad general knowledge of, or a thorough facility with, a particular field
• Knowledge of the preferred theoretical approach
• Knowledge of psychodynamic theory
• Knowledge of group dynamics theory
• Knowledge of the institution's preferred theoretical approaches
• Diagnostic skills for determining co-occurring disorders
• Capacity for self-reflection, such as recognizing one's own vulnerability and, when this problem arises, the ability to monitor and govern behavioral and emotional reactions
• Consultation skills, such as the ability to consult with a referring therapist, provide feedback, and coordinate treatment in both individual and group modes
• Capacity to be supervised; for example, openness in supervision, setting goals for training, and discussing with supervisor one's learning style and preferences (Kleinberg 1999)

#### Planning ways to train new counselors

In planning a training approach, a supervisor needs to consider the characteristics of the supervisory team, that is, the supervisor plus the trainees. Variables to be considered include

• The sophistication of trainees' knowledge and skills
• The supervisory setting
• The characteristics of the client population
• The nature of the supervised treatment
• The personality fit of the members on the supervisory team
• The format of the supervision
• The theoretical compatibility of the supervisory team (Kleinberg 1999)

After weighing all these variables, the supervisor discusses the focus and goals of the work with the team. The particulars will take shape as the supervisory contract. The necessary mastery of specified clinical subjects, as well as the skills associated with them, can be developed through reading assignments, video presentations, written assessments, and both direct and indirect supervision.

### Funding for Training and Supervision Programs

Given the time and financial resources needed to create formal academic preparation programs, it is a challenge to provide extended training (beyond 1- and 2-day seminars) that is well grounded in theory and application and that addresses the needs of substance abuse counselors, especially those leading therapy groups. The best way to fund such training is to incorporate it into an agency or organization budget. These outlays should be viewed as investments that pay handsome dividends. For instance, opportunities for training can help attract new, highly motivated employees.

It is a challenge to provide extended training that is well grounded in theory and application.

One alternative source of funding is a Federal or State grant. Such funds are often available, though frequently they require a great deal of administrative work and strict adherence to specific guidelines for project direction, staffing, and evaluation. Grants are also available to agencies and individuals through certain professional and training organizations. For example, AGPA gives scholarships to students who wish to attend its annual meetings and training conferences.

Other options can be found through the Foundation Center, a nonprofit library system that

• Collects and disseminates information on sources of funding
• Conducts and promotes research on trends in philanthropy
• Provides education on grant seeking
• Publishes The Foundation Directory, available on CD-ROM through The Foundation Center

The five foundation libraries (located in Atlanta, Cleveland, New York, San Francisco, and Washington) provide many resources with information on grants for projects related to health and education. The center has recently designed a virtual classroom to assist in

• Researching philanthropy
• Writing proposals
• Identifying nearby corporations, government agencies, and other sources of funds in specific geographical areas
• Training in fundraising
• Online fundraising

The Foundation Center can be reached at http://www.fdncenter.org (https://fconline.foundationcenter.org/). The Frequently Asked Questions section on this Web site is a useful introduction to the center's services.

As with training, an inherent cost is associated with high-quality clinical supervision, both in financial commitment and clinical time. Despite the positive returns that stem from good, better, or best clinical supervision, staff resources, agency or organizational requirements, and the needs of the leader in training often dictate the specific type of supervision available.

Every agency providing services to clients abusing substances should take clinical supervision seriously and direct appropriate resources toward constant improvement through the clinical supervision process.