# Consensus Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

## Chair

Philip J. Flores, Ph.D., COP, FAGPA
Adjunct Clinical Supervisor
Department of Psychology
Georgia State University
Atlanta, Georgia

## Co-Chair

Jeffrey M. Georgi, M.Div., CGP, CSAC, LPC, CCS
Clinical Director
Department of Behavioral Science
Duke School of Nursing and Duke University Medical Center
Senior Clinician
Duke Addictions Program
Duke University Medical Center
Durham, North Carolina

## Workgroup Leaders

David W. Brook, M.D., CGP
Department of Community and Preventive Medicine
Mount Sinai Medical Center
New York, New York

Frederick Bruce Carruth, Ph.D., LCSW
Private Practice
Boulder, Colorado

Sharon D. Chappelle, Ph.D., M.S.W., LCSW
President
Chief Executive Officer
Chappelle Consulting and Training Services, Inc.
Middletown, Connecticut

David E. Cooper, Ph.D.
Psychologist/Psychoanalyst
Chestnut Lodge Hospital
Chevy Chase, Maryland

Charles Garvin, Ph.D.
Professor of Social Work
School of Social Work
University of Michigan
Ann Arbor, Michigan

## Panelists

Marilyn Joan Freimuth, Ph.D.
Psychologist/Faculty Member
The Fielding Institute
Bedford, New York

Barbara Hardin-Perez, Ph.D.
Director
Student Health and Mental Health Services
St. Mary's University
San Antonio, Texas

Frankie D. Lemus, Jr., M.A.
Clinical Director
SageWind (Oikos, Inc.)
Reno, Nevada

Marilynn Morrical, CCDN, NCACII
(Deceased 2002)
Alcohol, Tobacco, and Drug Consultant
Marilynn Morrical Consulting and Rehabilitation
Reno, Nevada

Tam K. Nguyen, M.D., LMSW, CCJS, DVC, MAC
President
Employee & Family Resources
Polk City, Iowa

Candace M. Shelton, M.S., CADAC
Clinical Director
Native American Connections, Inc.
Tucson, Arizona

Darren C. Skinner, Ph.D., LSW, CAC
Director
Gaudenzia, Inc.
Gaudenzia House West Chester
West Chester, Pennsylvania

Judith S. Tellerman, Ph.D., MAT, M.Ed., CGP
Assistant Clinical Professor
College of Medicine
University of Illinois
Chicago, Illinois

Marsha Lee Vannicelli, Ph.D., FAGPA
Associate Clinical Professor
Department of Psychiatry
Harvard Medical School
Belmont, Massachusetts