# TIP Development Participants

Note: The information given indicates participants’ affiliations at the time of their participation in this TIP's original development and may no longer refect their current affiliations.

## Consensus Panel

Each TIP consensus panel is a group of primarily nonfederal addiction-focused clinical, research, administrative, and recovery support experts with deep knowledge of the TIP's topic. With the Substance Abuse and Mental Health Services Administration's Knowledge Application Program team, members of the consensus panel develop each TIP via a consensus-driven, collaborative process that blends evidence-based, best, and promising practices with the panel members’ expertise and combined wealth of experience.

### Chair

Edward Kaufman, M.D.
Editor in Chief, American Journal of Drug and Alcohol Abuse, Dana Point, California

### Co-Chair

Marianne R.M. Yoshioka, Ph.D., M.S.W.
Associate Professor, Columbia University, School of Social Work, New York, New York

### Workgroup Leaders

Mary M. Gillespie, Psy.D., CASAC
Professor, Hudson Valley Community College, Saratoga Springs, New York

Gloria Grijalva-Gonzales
Certified Sr. Substance Abuse Case Manager/Counselor, San Joaquin County - Office of Substance Abuse Allies Project, Stockton, California

I. Andrew Hamid, Ph.D., M.S.W., MFT, CSW
Professor, Columbia University, School of Social Work New York, New York

David Rosenthal, Ph.D.
Executive Director, Lower East Side Harm Reduction Center, New York, New York

Daniel Santisteban, Ph.D.
Research Associate Professor, University of Miami, School of Medicine, Miami, Florida

Carol Shapiro, M.S.W.
Executive Director, Family Justice Center, New York, New York

### Panelists

Fred U. Andes, D.S.W., M.S.W., M.P.A., LCSW
Assistant Professor of Sociology, New Jersey City University, Jersey City, New Jersey

Paul Curtin, M.A., CAC, NCAC II
President, Alcohol Services, Inc., Syracuse, New York

Jo-Ann Krestan, M.A., MFT, LADC
Family Therapist/Writer, Private Practice, Surry, Maine

Eric E. McCollum, Ph.D., LCSW, LMFT
Professor and Clinical Director, Virginia Tech Falls Church, Marriage and Family Therapy Program, Falls Church, Virginia

Margaret McMahon, M.T.S., M.S., M.S.W.
Clinician, Private Practice, Washington, DC

Greer McSpadden, M.S.W., LISW
Director, BHS, First Nations Community Health Source, Albuquerque, New Mexico

William Francis Northey, Jr., Ph.D.
Research Specialist, American Association for Marriage and Family Therapy, Alexandria, Virginia

Marlene F. Watson, Ph.D.
Director, Programs in Couple and Family Therapy, Drexel University, Philadelphia, Pennsylvania

Loretta Young Silvia, Ph.D., M.Ed.
Associate Professor of Psychiatry, Wake Forest University School of Medicine, Department of Psychiatry and Behavioral Medicine, Winston-Salem, North Carolina

## KAP Expert Panel and Federal Government Participants

Barry S. Brown, Ph.D.
Adjunct Professor, University of North Carolina at Wilmington, Carolina Beach, North Carolina

Jacqueline Butler, M.S.W., LISW, LPCC, CCDC III, CJS
Professor of Clinical Psychiatry, College of Medicine, University of Cincinnati, Cincinnati, Ohio

Deion Cash
Executive Director, Community Treatment and Correction Center, Inc., Canton, Ohio

Debra A. Claymore, M.Ed.Adm.
Owner/Chief Executive Officer, WC Consulting, LLC, Loveland, Colorado

Carlo C. DiClemente, Ph.D.
Chair, Department of Psychology, University of Maryland Baltimore County, Baltimore, Maryland

Catherine E. Dube, Ed.D.
Independent Consultant, Brown University, Providence, Rhode Island

Jerry P. Flanzer, D.S.W., LCSW, CAC
Chief, Services, Division of Clinical and Services Research, National Institute on Drug, Abuse Bethesda, Maryland

Michael Galer, D.B.A., M.B.A., M.F.A.
Independent Consultant, Westminster, Massachusetts

Renata J. Henry, M.Ed.
Director, Division of Alcoholism, Drug Abuse, and Mental Health, Delaware Department of Health and Social Services, New Castle, Delaware

Joel Hochberg, M.A.
President, Asher & Partners, Los Angeles, California

Jack Hollis, Ph.D.
Associate Director, Center for Health Research, Kaiser Permanente, Portland, Oregon

Mary Beth Johnson, M.S.W.
Director, Addiction Technology Transfer Center, University of Missouri-Kansas City, Kansas City, Missouri

Eduardo Lopez
Executive Producer, EVS Communications, Washington, DC

Holly A. Massett, Ph.D.
Academy for Educational Development, Washington, DC

Diane Miller
Chief, Scientific Communications Branch, National Institute on Alcohol Abuse and Alcoholism, Bethesda, Maryland

Harry B. Montoya, M.A.
President/Chief Executive Officer, Hands Across Cultures, Espanola, New Mexico

Richard K. Ries, M.D.
Director/Professor, Outpatient Mental Health Services, Dual Disorder Programs, Seattle, Washington

Gloria M. Rodriguez, D.S.W.
Research Scientist, Division of Addiction Services, NJ Department of Health and Senior Services, Trenton, New Jersey

Everett Rogers, Ph.D.
Center for Communications Programs, Johns Hopkins University, Baltimore, Maryland

Jean R. Slutsky, P.A., M.S.P.H.
Senior Health Policy Analyst, Agency for Healthcare Research and Quality, Rockville, Maryland

Nedra Klein Weinreich, M.S.
President, Weinreich Communications, Canoga Park, California

Clarissa Wittenberg
Director, Office of Communications and Public Liaison, National Institute of Mental Health, Kensington, Maryland

## Consulting Members

Paul Purnell, M.A.
Vice President, Social Solutions, L.L.C., Potomac, Maryland

Scott Ratzan, M.D., M.P.A., M.A.
Academy for Educational Development, Washington, DC

Thomas W. Valente, Ph.D.
Director, Master of Public Health Program, Department of Preventive Medicine, School of Medicine, University of Southern California, Alhambra, California

Patricia A. Wright, Ed.D.
Independent Consultant, Baltimore, Maryland

## Field Reviewers

Field reviewers represent each TIP's intended target audiences. They work in addiction, mental health, primary care, and adjacent fields. Their direct frontline experience related to the TIP's topic allows them to provide valuable input on a TIP's relevance, utility, accuracy, and accessibility. Additional advisors to this TIP include members of a resource panel and an editorial advisory board.

Stephanie Abbott, M.A.
Adjunct Professor, Marymount University, Arlington, Virginia

Raymond P. Adams, M.P.S., CAP
Drug Court Substance Abuse Counselor, Florida 16th Judicial Circuit Court, Marathon, Florida

David Bergman, J.D.
Director of Legal and Government Affairs, American Association for Marriage and Family Therapy, Alexandria, Virginia

James Bertone, LCSW, LADC
Rehabilitation Specialist II, Bureau of Alcohol and Drug Abuse, Carson City, Nevada

Thomas W. Blume, Ph.D., LPC, LMFT, NCC
Associate Professor, Doctoral Program Coordinator, Oakland University Rochester, Michigan

Lane Brigham, Ph.D.
Thibodaux, Louisiana

Susanne Caviness, Ph.D. (CAPT, USPHS)
Senior Program Management Officer, Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services Administration, Rockville, Maryland

Paula Corey
Senior Vice President, Palladia, Inc., New York, New York

Janice M. Dyehouse, Ph.D., M.S.N., R.N.
Professor of Nursing, University of Cincinnati College of Nursing, Cincinnati, Ohio

Jo-an M. Fox
Nashville, Tennessee

Joel Frank
Milwaukee, Wisconsin

Anne M. Herron, M.S.
Director, New York State Office of Alcoholism and Substance Abuse Services Albany, New York

M. Kay Keller, M.P.A., SSW
Senior Human Services Program Specialist, Contract Manager Program, Department of Children and Family Services, Substance Abuse Program Office, Tallahassee, Florida

Malcolm V. King
Substance Abuse Program Manager, Virginia Department of Juvenile, Justice Richmond, Virginia

G. Richard Kinsella
Vice President, Syracuse Behavioral Healthcare, Syracuse, New York

Michael Warren Kirby, Jr., Ph.D., M.A., CAC III
Chief Executive Officer, Arapahoe House, Inc., Thornton, Colorado

Janet M. Lerner, D.S.W., RCSW
Administrator, Narco Freedom, Inc., New York, New York

Ruby J. Martinez, Ph.D., R.N., CS
Assistant Professor, University of Colorado, Denver, Colorado

Dan A. McRight
Nashville CPE Partnership, Nashville, Tennessee

Jerry Moe, M.A.
National Director, Betty Ford Center's Children's Program, Rancho Mirage, California

Fariha Niazi, LMHC
Brief Therapy Institute, NOVA Southeastern University, Fort Lauderdale, Florida

William (Bill) Francis Northey, Jr., Ph.D.
Research Specialist, American Association for Marriage and Family Therapy, Alexandria, Virginia

Gwen M. Olitsky, M.S.
Founder and C.E.O., The Self-Help Institute for Training and Therapy Lansdale, Pennsylvania

Randall W. Phillips, LMFT, LPC/MHSP
Union City Medical Center, Counseling and Consulting Services, Union City, Tennessee

Gerard J. Schmidt, M.A., LPC, MAC
Clinical Affairs Consultant, NAADAC, The Association for Addiction, Professionals, Morgantown, West Virginia

Thomas L. Sexton, Ph.D.
Professor and Director, Center for Adolescent and Family Studies, Counseling Psychology Program, Indiana University-Bloomington, Bloomington, Indiana

Meri Shadley, Ph.D., MFT, LADC
Associate Professor, Center for the Application of Substance Abuse Technologies, University of Nevada, Reno, Reno, Nevada

Mary K. Shilton
Executive Director, National Treatment Accountability for Safer Communities, Washington, DC

Robert Walker, M.S.W., LCSW
Assistant Professor, University of Kentucky, Center on Drug and Alcohol Research, Lexington, Kentucky

Sis Wenger
Executive Director, National Association for Children of Alcoholics, Rockville, Maryland

Kerry W. Wicks, LAC
Program Director, North Dakota Department of Human Services, Jamestown, North Dakota

Ann S. Yabusaki, Ph.D.
Substance Abuse Director, Psychologist, Coalition for a Drug-Free Hawaii, Substance Abuse Programs and Training, Kaneohe, Hawaii

## Resource Panel

Shirley Beckett, NCAC II
Certification Administrator, NAADAC, The Association for Addiction Professionals, Alexandria, Virginia

Susanne Caviness, Ph.D. (CAPT, USPHS)
Senior Program Management Officer, Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services Administration, Rockville, Maryland

Frank Canizales, M.S.W.
Management Analyst, Alcohol Program, Indian Health Service, Rockville, Maryland

Peggy Clark, M.S.W., M.P.A.
Center for Medicaid and State Operations, Centers for Medicare and Medicaid Services, Baltimore, Maryland

Christina Currier
Public Health Analyst, Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services, Administration, Rockville, Maryland

James Gil Hill
Director, Office of Evaluation, Scientific Analysis and Synthesis, Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services, Administration, Rockville, Maryland

Hendree E. Jones, Ph.D.
Assistant Professor, CAP Research Director, Johns Hopkins University Center, Baltimore, Maryland

William (Bill) Francis Northey, Jr., Ph.D.
Research Specialist, American Association for Marriage and Family Therapy, Alexandria, Virginia

Hector Sanchez, M.S.W.
Team Leader, Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services Administration, Rockville, Maryland

Karen Urbany
Public Health Advisor, Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services, Administration, Rockville, Maryland

Steve Wing
Senior Advisor for Drug Policy, Office of Policy and Program Coordination, Substance Abuse and Mental Health Services, Administration, Rockville, Maryland

## Cultural Competency and Diversity Network Participants

Elmore T. Briggs, CCDC, NCAC II
President/CEO, SuMoe Partners, Germantown, Maryland, African American Work Group

Frank Canizales, M.S.W.
Management Analyst, Alcohol Program, Indian Health Service Rockville, Maryland Native American Work Group

Ting-Fun May Lai, M.S.W., CSW, CASAC
Director, Chinatown Alcoholism Center, Hamilton-Madison House, New York, New York, Asian Work Group

Hector Sanchez, M.S.W.
Center for Substance Abuse Treatment, Substance Abuse and Mental Health Services, Administration, Rockville, Maryland, Hispanic/Latino Work Group

Ann S. Yabusaki, Ph.D.
Kaneohe, Hawaii, Asian Work Group