# Appendix—Bibliography

Adkison-Johnson, C. (2015). Child discipline and African American parents with adolescent children: A psychoeducational approach to clinical mental health counseling. Journal of Mental Health Counseling, 37(3), 221–233. doi:10.17744/mehc.37.3.03
Akram, Y., & Copello, A. (2013). Family-based interventions for substance misuse: A systematic review of reviews. The Lancet, 382, S24. doi:10.1016/S0140-6736(13)62449-6
Al-Anon Family Group Headquarters, Inc. (n.d.). The Legacies. Retrieved August 13, 2019, from https://al-anon.org/for-members/the-legacies/
Al-Anon Family Group Headquarters, Inc. (2016). Al-Anon: Then and now: A brief history [Brochure].
Alexander, J., & Parsons, B. V. (1982). Functional family therapy. Monterey, CA: Brooks/Cole Publishing Company.
Ali, M. M., Dean, D., Jr., & Hedden, S. L. (2016). The relationship between parental mental illness and/or substance use disorder on adolescent substance use disorder: Results from a nationally representative survey. Addictive Behaviors, 59, 35–41. doi:10.1016/j.addbeh.2016.03.019 27070095
Allwright, K., Goldie, C., Almost, J., & Wilson, R. (2019). Fostering positive spaces in public health using a cultural humility approach. Public Health Nursing, 64(4), 551–556. doi:10.1111/phn.12613
Alonzo, D., Thompson, R. G., Stohl, M., & Hasin, D. (2014). The influence of parental divorce and alcohol abuse on adult offspring risk of lifetime suicide attempt in the United States. American Journal of Orthopsychiatry, 84(3), 316–320. doi:10.1037/h0099804 24827026
Amato, P. R., King, V., & Thorsen, M. L. (2016). Parent-child relationships in stepfather families and adolescent adjustment: A latent class analysis. Journal of Marriage and Family, 78(2), 482–497. doi:10.1111/jomf.12267 27022199
American Association for Marriage and Family Therapy. (n.d.-a). Medicaid. Retrieved April 6, 2020, from www.aamft.org/Advocacy/Medicaid.aspx
Association for Marriage and Family Therapy. (n.a.-b). MFT Licensing Boards. Retrieved August 13, 2019, from www.aamft.org/Directories/MFTLicensing Boards.aspx?WebsiteKey=8e8c9bd6-0b71-4cd1-a5ab-013b5f855b01
American Association for Marriage and Family Therapy. (2019). Approved supervision designation: Standards handbook. Version 5. Retrieved March 30, 2020, from www.aamft.org/documents/Supervision/2020AS Documents/ASHandbook02-2020edits.pdf
American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Arlington, VA: Author.
Areba, E. M., Eisenberg, M. E., & McMorris, B. J. (2018). Relationships between family structure, adolescent health status and substance use: Does ethnicity matter? Journal of Community Psychology, 46(1), 44–57. doi:10.1002/jcop.21915
Aromin, R. A., Jr. (2016). Substance abuse prevention, assessment, and treatment for lesbian, gay, bisexual, and transgender youth. Pediatric Clinics of North America, 63(6), 1057–1077. doi:10.1016/j.pcl.2016.07.007 27865333
Association for Counselor Education and Supervision. (2011, January 18). Best practices in clinical supervision: ACES task force report. Retrieved April 7, 2020, from www.apsu.edu/mscounseling/pdfs/ACESBestPracticesSupervision.pdf
Association for Family Therapy and Systemic Practice. (n.d.). Guidance on caseload and clinical activity for family and systemic psychotherapists in the NHS. Retrieved March 30, 2020, from www.aft.org.uk/SpringboardWebApp/userfiles/aft/file/Members/GuidanceonCaseloadandClinicalActivityforFamilySystemicPsychotherapists.pdf
Ast, L. (2018). Developing alternative stories with partners of illicit substance users. Journal of Family Psychotherapy, 29(3), 201–222. doi:10.1080/08975353.2017.1410768
Awosan, C. I., Sandberg, J. G., & Hall, C. A. (2011). Understanding the experience of Black clients in marriage and family therapy. Journal of Marital and Family Therapy, 37(2), 153–168. doi:10.1111/j.1752-0606.2009.00166.x 21457281
Bai, G. J., Leon, S. C., Garbarino, J., & Fuller, A. K. (2016). The protective effect of kinship involvement on the adjustment of youth in foster care. Child Maltreatment, 21(4), 288–297. doi:10.1177/1077559516669043 30209968
Baldwin, S. A., Christian, S., Berkeljon, A., & Shadish, W. R. (2012). The effects of family therapies for adolescent delinquency and substance abuse: A meta-analysis. Journal of Marital and Family Therapy, 38(1), 281–304. doi:10.1111/j.1752-0606.2011.00248.x 22283391
Barfield-Cottledge, T. (2015). The triangulation effects of family structure and attachment on adolescent substance use. Crime and Delinquency, 61(2), 297–320. doi:10.1177/0011128711420110
Barlow, Α., Mullany, B„, Neault, N„ Goklish, N„ Billy, T., Hastings, R., … Walkup, J. T. (2015). Paraprofessional-delivered home-visiting intervention for American Indian teen mothers and children: 3-year outcomes from a randomized controlled trial. American Journal of Psychiatry, 172(2), 154–162. doi:10.1176/appi.ajp.2014.14030332 25321149
Barsky, A. (2018). Cultural competence, awareness, sensitivity, humility, and responsiveness: What's the difference? New Social Worker, 25(4), 4–5.
Bartle-Haring, S„ Pratt, K„ & Knerr, M. C. (2019). Policies and procedures manual for the Ph.D. specialization in couple and family therapy. Retrieved August 9, 2019, from https://ehe.osu.edu/sites/ehe.osu.edu/files/files/couple-and-family-therapy-policies-and-procedures.pdf
Bartle-Haring, S„ Slesnick, N„ & Murnan, A. (2018). Benefits to children who participate in family therapy with their substance-using mother. Journal of Marital and Family Therapy, 44(4), 671–686. doi:10.1111/jmft.12280 28950404
Barton, A. W„ Beach, S. R. H„ Wells, A. C„ Ingels, J. B„ Corso, P. S„ Sperr, M. C., … Brody, G. H. (2018). The Protecting Strong African American Families Program: A randomized controlled trial with rural African American couples. Prevention Science, 79(7), 904–913. doi:10.1007/s11121-018-0895-4
Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9. doi:10.1016/j.jsat.2016.01.003 26882891
Beach, S. R„ Barton, A. W„ Lei, M. K„ Mandara, J., Wells, A. C„ Kogan, S. M„ & Brody, G. H. (2016). Decreasing substance use risk among African American youth: Parent-based mechanisms of change. Prevention Science, 77(5), 572–583. doi:10.1007/s11121-016-0651-6
Beck, Α., Buche, J., Page, C., Rittman, D. & Gaiser, M. (2018). Scopes of practice and reimbursement patterns of addiction counselors, community health workers, and peer recovery specialists in the behavioral health workforce. Ann Arbor: University of Michigan School of Public Health, Behavioral Workforce Research Center.
Becvar, R. J., & Becvar, D. S. (2018). Systems theory and family therapy: A primer (3rd ed.). Lanham, MD: Hamilton Books.
Belone, L., Orosco, Α., Damon, E., Smith-McNeal, W., Rae, R„ Sherpa, M. L., … Wallerstein, Ν. (2017). The piloting of a culturally centered American Indian family prevention program: A CBPR partnership between Mescalero Apache and the University of New Mexico. Public Health Reviews, 38, 30. doi:10.1186/s40985-017-0076-1 29375178
Berg, I. K„ & Miller, S. D. (1992). Working with the problem drinker: A solution-focused approach. New York, NY: Norton & Co.
Birkeland, B„ Foster, K„ Selbekk, A. S„ Hoie, Μ. M„ Ruud, T., & Weimand, B. (2018). The quality of life when a partner has substance use problems: A scoping review. Health and Quality of Life Outcomes, 76(1), 219. doi:10.1186/s12955-018-1042-4
Bischof, G., Iwen, J., Freyer-Adam, J., & Rumpf, H. J. (2016). Efficacy of the community reinforcement and family training for concerned significant others of treatment-refusing individuals with alcohol dependence: A randomized controlled trial. Drug and Alcohol Dependence, 163, 179–185. doi:10.1016/j.drugalcdep.2016.04.015 27141840
Black, C. (2018). Unspoken legacy: Addressing the impact of trauma and addiction within the family. Las Vegas, NV: Central Recovery Press.
Blum, K., Febo, M., Badgaiyan, R. D., Demetrovics, Z., Simpatico, T., Fahlke, C., … Gold, M. S. (2017). Common neurogenetic diagnosis and meso-limbic manipulation of hypodopaminergic function in reward deficiency syndrome (RDS): Changing the recovery landscape. Current Neuropharmacology, 75(1), 184–194. doi:10.2174/1570159X13666160512150918
Boswell, J. F., Kraus, D. R., Miller, S. D., & Lambert, M. J. (2013). Implementing routine outcome monitoring in clinical practice: Benefits, challenges, and solutions. Psychotherapy Research, 25(1), 6–19. doi:10.1080/10503307.2013.817696 23885809
Bowen, M. (1978). Family therapy in clinical practice. New York, NY: Jason Aronson, Inc.
Boyle, R„ & McDowell-Burns, M. (2016). Modalities of marriage and family therapy supervision. In J. Karin (Ed.) Couple, marriage, and family therapy supervision (pp. 51–69). New York, NY: Springer Publishing Co.
Bradshaw, S. D., Shumway, S. T., Wang, E. W., Harris, K. S„ Smith, D. B„ & Austin-Robillard, H. (2016). Family functioning and readiness in family recovery from addiction. Journal of Groups in Addiction and Recovery, 77(1), 21–41. doi:10.1080/1556035X.2015.1104644
Braitman, A. L., & Kelley, M. L. (2016). Initiation and retention in couples outpatient treatment for parents with drug and alcohol use disorders. Experimental and Clinical Psychopharmacology, 24(3), 174–184. doi:10.1037/pha0000072 27064819
Bregman, O. C., & White, C. M. (2011). Bringing systems thinking to life: Expanding the horizons for Bowen family systems theory. New York, NY: Brunner-Routledge.
Brody, G. H„ Chen, Y. F., Kogan, S. M., Murry, V. M„ & Brown, A. C. (2010). Long-term effects of the Strong African American Families Program on youths’ alcohol use. Journal of Consulting and Clinical Psychology, 78(2), 281–285. doi:10.1037/a0018552 20350039
Brody, G. H., Chen, Y. F., Kogan, S. M., Yu, T., Molgaard, V. K., DiClemente, R. J., & Wingood, G. M. (2012). Family-centered program deters substance use, conduct problems, and depressive symptoms in Black adolescents. Pediatrics, 129(1), 108–115. doi:10.1542/peds.2011-0623 22157131
Brown, S., Tracy, E. M., Jun, M., Park, H., & Min, M. O. (2015). Personal network recovery enablers and relapse risks for women with substance dependence. Qualitative Health Research, 25(3), 371–385. doi:10.1177/1049732314551055 25231945
Burrow-Sánchez, J. J., Minami, T., & Hops, H. (2015). Cultural accommodation of group substance abuse treatment for Latino adolescents: Results of an RCT. Cultural Diversity and Ethnic Minority Psychology, 21(4), 571–583. doi:10.1037/cdp0000023 25602465
Burstein, M., Stanger, C., & Dumenci, L. (2012). Relations between parent psychopathology, family functioning, and adolescent problems in substance-abusing families: Disaggregating the effects of parent gender. Child Psychiatry and Human Development, 43(4), 631–647. doi:10.1007/s10578-012-0288-z 22392413
Calhoun, S., Conner, E., Miller, M., & Messina, N. (2015). Improving the outcomes of children affected by parental substance abuse: A review of randomized controlled trials. Substance Abuse and Rehabilitation, 6, 15–24. doi:10.2147/sar.s46439 25670915
Canfield, M., Radcliffe, P., Marlow, S., Boreham, M., & Gilchrist, G. (2017). Maternal substance use and child protection: A rapid evidence assessment of factors associated with loss of child care. Child Abuse and Neglect, 70, 11–27. doi:10.1016/j.chiabu.2017.05.005 28551458
Carlson, R. G., & Lambie, G. W. (2012). Systemic-developmental supervision: Clinical supervisory approach for family counseling student interns. Family Journal, 20(1), 29–36. doi:10.1177/1066480711419809
Carr, A., & Stratton, P. (2017). The SCORE family assessment questionnaire: A decade of progress. Family Process, 56(2), 285–301. doi:10.1111/famp.12280 28205204
Cavaiola, A. A., Fulmer, B. A., & Stout, D. (2015). The impact of social support and attachment style on quality of life and readiness to change in a sample of individuals receiving medication-assisted treatment for opioid dependence. Substance Abuse, 36(2), 183–191. doi:10.1080/08897077.2015.1019662 25839214
Center for Behavioral Health Statistics and Quality. (2020). Results from the 2019 National Survey on Drug Use and Health: Detailed tables. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved September 14, 2020, from https://www.samhsa.gov/data/
Center for Substance Abuse Treatment. (2006a). Addiction counseling competencies: The knowledge, skills, and attitudes of professional practice. Technical Assistance Publication (TAP) Series 21. HHS Publication No. (SMA) 06-4171. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2006b). Counselor's family education manual: Matrix Intensive Outpatient Treatment for People With Stimulant Use Disorders. HHS Publication No. (SMA) 13-4153. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Center for Substance Abuse Treatment. (2006c). Counselor's treatment manual: Matrix Intensive Outpatient Treatment for People With Stimulant Use Disorders. HHS Publication No. (SMA) 13-4152. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Chang, J. S., Sorensen, J. L., Masson, C. L., Shopshire, M. S., Hoffman, K., McCarty, D., & Iguchi, M. (2017). Structural factors affecting Asians and Pacific Islanders in community-based substance use treatment: Treatment provider perspectives. Journal of Ethnicity in Substance Abuse, 16(4), 479–494.29236627
Chartier, K. G., Carmody, T., Akhtar, M., Stebbins, M. B., Walters, S. T., & Warden, D. (2015). Hispanic subgroups, acculturation, and substance abuse treatment outcomes. Journal of Substance Abuse Treatment, 59, 74–82. doi:10.1016/j.jsat.2015.07.008 26362001
Cheung, S. (2014, October). Family therapy with Asian Americans: Principles and practice. Paper presented at the 20th Annual Asian American Mental Health Training Conference, Alhambra, CA.
Chuang, S. S., Glozman, J., Green, D. S., & Rasmi, S. (2018). Parenting and family relationships in Chinese families: A critical ecological approach. Journal of Family Theory and Review, 10(2), 367–383. doi:10.1111/jftr.12257
Commission on Accreditation for Marriage and Family Therapy Education. (2014, July 15). Accreditation standards: Graduate & post-graduate marriage and family therapy training programs (Version 12.0). Retrieved April 7, 2020, from www.coamfte.org/documents/COAMFTE/Accreditation%20Resources/2018%2QCOAMFTE%20Accreditation%20Standards%20Version%2012%20May.pdf
Cordova, D., Heinze, J., Mistry, R., Hsieh, H. F., Stoddard, S., Salas-Wright, C. P., & Zimmerman, M. A. (2014). Family functioning and parent support trajectories and substance use and misuse among minority urban adolescents: A latent class growth analysis. Substance Use and Misuse, 49(14), 1908–1919. doi:10.3109/10826084.2014.935792 25033377
Cordova, D., Huang, S., Pantin, H., & Prado, G. (2012). Do the effects of a family intervention on alcohol and drug use vary by nativity status? Psychology of Addictive Behaviors, 26(3), 655–660. doi:10.1037/a0026438 22141423
Corless, J., Mirza, K. A. H., & Steinglass, P. (2009). Family therapy for substance misuse: The maturation of a field. Journal of Family Therapy, 31(2), 109–114. doi:10.1111/j.1467-6427.2009.00457.x
Cosden, M., & Koch, L. M. (2015). Changes in adult, child, and family functioning among participants in a family treatment drug court. Child Welfare, 94(5), 89–106.26827466
Cranford, J. A. (2014). DSM-IV alcohol dependence and marital dissolution: Evidence from the National Epidemiologic Survey on Alcohol and Related Conditions. Journal of Studies on Alcohol and Drugs, 75(3), 520–529. doi:10.15288/jsad.2014.75.520 24766764
Cross, C. J. (2018). Extended family households among children in the United States: Differences by race/ethnicity and socio-economic status. Population Studies, 72(2), 235–251. doi:10.1080/00324728.2018.1468476 29770726
Cruz, R. A., King, K. M., Cauce, A. M., Conger, R. D., & Robins, R. W. (2017). Cultural orientation trajectories and substance use: Findings from a longitudinal study of Mexican-origin youth. Child Development, 88(2), 555–572. doi:10.1111/cdev.12586 27364380
Cuadrado, M. (2018). Roman Catholic priests as referral sources and treatment aides for Hispanics with substance misuse/abuse problems. Journal of Religion and Health, 57(2), 609–621. doi:10.1007/s10943-017-0464-3 28766248
Cunningham, P. B., Foster, S. L., & Warner, S. E. (2010). Culturally relevant family-based treatment for adolescent delinquency and substance abuse: Understanding within-session processes. Journal of Clinical Psychology, 66(8), 830–846. doi:10.1002/jclp.20709 20564683
Dahlgren, A., Wargelius, H. L., Berglund, K. J., Fahlke, C., Blennow, K., Zetterberg, H., … Balldin, J. (2011). Do alcohol-dependent individuals with DRD2 A1 allele have an increased risk of relapse? A pilot study. Alcohol and Alcoholism, 46(5), 509–513. doi:10.1093/alcalc/agr045 21613303
Dakof, G. A., Henderson, C. E., Rowe, C. L., Boustani, M., Greenbaum, P. E., Wang, W., … Liddle, H. A. (2015). A randomized clinical trial of family therapy in juvenile drug court. Journal of Family Psychology, 29(2), 232–241. doi:10.1037/fam0000053 25621927
Danso, R. (2018). Cultural competence and cultural humility: A critical reflection on key cultural diversity concepts. Journal of Social Work, 18(4), 410–430. doi:10.1177/1468017316654341
De Jong, P., & Berg, I. K. (1998). Interviewing for solutions. Pacific Grove, CA: Brooks/Cole Publishing Company.
de Shazer, S. (1988). Clues: Investigating solutions in brief therapy. New York, NY: Norton & Co.
Diamond, G. M., & Shpigel, M. S. (2014). Attachment-based family therapy for lesbian and gay young adults and their persistently nonaccepting parents. Professional Psychology: Research and Practice, 45(4), 258–268. doi:10.1037/a0035394
DiClemente, C. C. (2018). Addiction and change: How addictions develop and addicted people recover (2nd ed.). New York, NY: Guilford Press.
Drapkin, M. L., Eddie, D., Buffington, A. J., & McCrady, B. S. (2015). Alcohol-specific coping styles of adult children of individuals with alcohol use disorders and associations with psychosocial functioning. Alcohol and Alcoholism, 50(4), 463–469. doi:10.1093/alcalc/agv023 25802055
Eddie, D., Epstein, E. E., & Cohn, A. M. (2015). Pathways to vulnerability for alcohol problem severity in a treatment-seeking sample. Addictive Disorders and Their Treatment, 14(2), 82–94. doi:10.1097/adt.0000000000000045 26170766
Elam, K. K., Chassin, L., & Pandika, D. (2018). Polygenic risk, family cohesion, and adolescent aggression in Mexican American and European American families: Developmental pathways to alcohol use. Development and Psychopathology, 30(5), 1715–1728. doi:10.1017/s0954579418000901 30168407
Escobar, O. S., & Vaughan, E. L. (2014). Public religiosity, religious importance, and substance use among Latino emerging adults. Substance Use and Misuse, 49(10), 1317–1325. doi:10.3109/10826084.2014.901384 24708430
Fang, L., & Schinke, S. P. (2013). Two-year outcomes of a randomized, family-based substance use prevention trial for Asian American adolescent girls. Psychology of Addictive Behaviors, 27(3), 788–798. doi:10.1037/a0030925 23276322
Fang, L., & Schinke, S. P. (2014). Mediation effects of a culturally generic substance use prevention program for Asian American adolescents. Asian American Journal of Psychology, 5(2), 116–125. doi:10.1037/a0035928 25505939
Fang, L., Schinke, S. P., & Cole, K. C. (2010). Preventing substance use among early Asian-American adolescent girls: Initial evaluation of a web-based, mother-daughter program. Journal of Adolescent Health, 47(5), 529–532. doi:10.1016/j.jadohealth.2010.03.011
Finan, L. J., Schulz, J., Gordon, M. S., & Ohannessian, C. M. (2015). Parental problem drinking and adolescent externalizing behaviors: The mediating role of family functioning. Journal of Adolescence, 43, 100–110. doi:10.1016/j.adolescence.2015.05.001 26073673
Fish, J. N., Maier, C. A., & Priest, J. B. (2015). Substance abuse treatment response in a Latino sample: The influence of family conflict. Journal of Substance Abuse Treatment, 49, 27–34. doi:10.1016/j.jsat.2014.07.011 25216811
Fletcher, K. (2013). Couple therapy treatments for substance use disorders: A systematic review. Journal of Social Work Practice in the Addictions, 13(4), 327–352. doi:10.1080/1533256X.2013.840213
Frank, L. E., & Nagel, S. K. (2017). Addiction and moralization: The role of the underlying model of addiction. Neuroethics, 10(1), 129–139. doi:10.1007/s12152-017-9307-x 28725284
Galanter, M. (2014). Network therapy for substance use disorders. In G. O. Gabbard (Ed.). Gabbard's treatments of psychiatric disorders (5th ed., pp. 919–922). Arlington, VA: American Psychiatric Publishing, Inc.
Galanter, M. (2015). Network therapy. In M. Galanter, H. D. Kleber, & K. T. Brady (Eds.) The American Psychiatric Publishing textbook of substance abuse treatment (5th ed., pp. 441–461). Arlington, VA: American Psychiatric Publishing, Inc.
Galanter, M., Dermatis, H., Glickman, L., Maslansky, R., Sellers, M. B., Neumann, E., & Rahman-Dujarric, C. (2004). Network therapy: Decreased secondary opioid use during buprenorphine maintenance. Journal of Substance Abuse Treatment, 26(4), 313–318.15182896
Galanter, M., Dermatis, H., Keller, D., & Trujillo, M. (2002). Network therapy for cocaine abuse: Use of family and peer supports. American Journal on Addictions, 11(2), 161–166.12028746
Garcia-Huidobro, D., Doty, J. L., Davis, L., Borowsky, I. W., & Allen, M. L. (2018). For whom do parenting interventions to prevent adolescent substance use work? Prevention Science, 19(4), 570–578. doi:10.1007/s11121-017-0853-6 29150747
Gehart, D. R. (2018). Mastering competencies in family therapy: A practical approach to theories and clinical case documentation (3rd ed.). Boston, MA: Cengage Learning.
Gerra, G., Somaini, L., Manfredini, M., Raggi, M. A., Saracino, M. A., Amore, M., … Donnini, C. (2014). Dysregulated responses to emotions among abstinent heroin users: Correlation with childhood neglect and addiction severity. Progress in Neuro-Psychopharmacology and Biological Psychiatry, 48, 220–228. doi:10.1016/j.pnpbp.2013.10.011 24161666
Gilliard-Matthews, S., Stevens, R., Nilsen, M., & Dunaev, J. (2015). “You see it everywhere. It's just natural.”: Contextualizing the role of peers, family, and neighborhood in initial substance use. Deviant Behavior, 36(6), 492–509. doi:10.1080/01639625.2014.944068
Gingerich, W. J., & Peterson, L. T. (2013). Effectiveness of solution-focused brief therapy: A systematic qualitative review of controlled outcome studies. Research on Social Work Practice, 23(3), 266–283. doi:10.1177/1049731512470859
Gladding, S. T. (2019). Family therapy: History, theory, and practice (7th ed.). Boston, MA: Pearson.
Glazer, S. S., Galanter, M., Megwinoff, O., Dermatis, H., & Keller, D. S. (2003). The role of therapeutic alliance in network therapy: A family and peer support-based treatment for cocaine abuse. Substance Abuse, 24(2), 93–100.12766376
Goldenberg, I., Stanton, M., & Goldenberg, H. (2017). Family therapy: An overview (9th ed.). Boston, MA: Cengage Learning.
Goorden, M., Schawo, S. J., Bouwmans-Frijters, C. A., van der Schee, E., Hendriks, V. M., & Hakkaart-van Roijen, L. (2016). The cost-effectiveness of family/family-based therapy for treatment of externalizing disorders, substance use disorders and delinquency: A systematic review. BMC Psychiatry, 16, 237. doi:10.1186/s12888-016-0949-8 27412612
Greenbaum, P. E., Wang, W., Henderson, C. E., Kan, L., Hall, K., Dakof, G. A., & Liddle, H. A. (2015). Gender and ethnicity as moderators: Integrative data analysis of multidimensional family therapy randomized clinical trials. Journal of Family Psychology, 29(6), 919–930. doi:10.1037/fam0000127 26213796
Gustavsen, G. W., Nayga, R. M., Jr., & Wu, X. (2016). Effects of parental divorce on teenage children's risk behaviors: Incidence and persistence. Journal of Family and Economic Issues, 37(3), 474–487. doi:10.1007/s10834-015-9460-5
Gutierrez, A., & Sher, L. (2015). Alcohol and drug use among adolescents: An educational overview. International Journal of Adolescent Medicine and Health, 27(2), 207–212. doi:10.1515/ijamh-2015-5013 25411992
Gutierrez, D. (2018). The role of intersectionality in marriage and family therapy multicultural supervision. American Journal of Family Therapy, 46(1), 14–26. doi:10.1080/01926187.2018.1437573
Harford, T. C., Chen, C. M., Kerridge, B. T., & Grant, B. F. (2018). Self- and other-directed forms of violence and their relationship with lifetime DSM-5 psychiatric disorders: Results from the National Epidemiologic Survey on Alcohol Related Conditions-III (NESARC-III). Psychiatry Research, 262, 384–392. doi:10.1016/j.psychres.2017.09.012 28939392
Harford, T. C., Yi, H. Y., Chen, C. M., & Grant, B. F. (2018). Substance use disorders and self- and other-directed violence among adults: Results from the National Survey on Drug Use And Health. Journal of Affective Disorders, 225, 365–373. doi:10.1016/j.jad.2017.08.021 28846958
Harp, K. L. H., & Oser, C. B. (2018). A longitudinal analysis of the impact of child custody loss on drug use and crime among a sample of African American mothers. Child Abuse and Neglect, 77, 1–12. doi:10.1016/j.chiabu.2017.12.017 29287167
Hartnett, D., Carr, A., Hamilton, E., & O'Reilly, G. (2017). The effectiveness of functional family therapy for adolescent behavioral and substance misuse problems: A meta-analysis. Family Process, 56(3), 607–619. doi:10.1111/famp.12256 27731494
Haverfield, M. C., & Theiss, J. A. (2016). Parent's alcoholism severity and family topic avoidance about alcohol as predictors of perceived stigma among adult children of alcoholics: Implications for emotional and psychological resilience. Health Communication, 31(5), 606–616. doi:10.1080/10410236.2014.981665 26452454
Henderson, C. E., Hogue, A., & Dauber, S. (2019). Family therapy techniques and one-year clinical outcomes among adolescents in usual care for behavior problems. Journal of Consulting and Clinical Psychology, 87(3), 308–312. doi:10.1037/ccp0000376 30589350
Henderson, C. E., Rowe, C. L., Dakof, G. A., Hawes, S. W., & Liddle, H. A. (2009). Parenting practices as mediators of treatment effects in an early-intervention trial of multidimensional family therapy. American Journal of Drug and Alcohol Abuse, 35(4), 220–226. doi:10.1080/00952990903005890 20180674
Henggeler, S. W., & Schaeffer, C. M. (2016). Multisystemic therapy: Clinical overview, outcomes, and implementation research. Family Process, 55, 514–528. doi:10.1111/famp.12232 27370172
Henson, M., Sabo, S., Trujillo, A., & Teufel-Shone, N. (2017). Identifying protective factors to promote health in American Indian and Alaska Native adolescents: A literature review. Journal of Primary Prevention, 38(1-2), 5–26. doi:10.1007/s10935-016-0455-2 27826690
Hernandez, L., Rodriguez, A. M., & Spirito, A. (2015). Brief family-based intervention for substance abusing adolescents. Child and Adolescent Psychiatric Clinics of North America, 24(3), 585–599. doi:10.1016/j.chc.2015.02.010 26092741
Hernandez Robles, E., Maynard, B. R., Salas-Wright, C. P., & Todic, J. (2018). Culturally adapted substance use interventions for Latino adolescents: A systematic review and meta-analysis. Research on Social Work Practice, 28(7), 789–801. doi:10.1177/1049731516676601
Hinrichs, J., Defife, J., & Westen, D. (2011). Personality subtypes in adolescent and adult children of alcoholics: A two-part study. Journal of Nervous and Mental Disease, 199(7), 487–498. doi:10.1097/NMD.0b013e3182214268 21716063
Hoggatt, K. J., Lehavot, K., Krenek, M., Schweizer, C. A., & Simpson, T. (2017). Prevalence of substance misuse among US veterans in the general population. American Journal on Addictions, 26(4), 357–365. doi:10.1111/ajad.12534 28370701
Hogue, A., Bobek, M., Dauber, S., Henderson, C. E., McLeod, B. D., & Southam-Gerow, M. A. (2017). Distilling the core elements of family therapy for adolescent substance use: Conceptual and empirical solutions. Journal of Child and Adolescent Substance Abuse, 26(6), 437–453. doi:10.1080/1067828X.2017.1322020 30705581
Hogue, A., Dauber, S., Henderson, C. E., Bobek, M., Johnson, C., Lichvar, E., & Morgenstern, J. (2015). Randomized trial of family therapy versus nonfamily treatment for adolescent behavior problems in usual care. Journal of Clinical Child and Adolescent Psychology, 44(6), 954–969. doi:10.1080/15374416.2014.963857 25496283
Horigian, V. E., Anderson, A. R., & Szapocznik, J. (2016). Family-based treatments for adolescent substance use. Child and Adolescent Psychiatric Clinics of North America, 25(4), 603–628. doi:10.1016/j.chc.2016.06.001 27613341
Horigian, V. E., Feaster, D. J., Brincks, A., Robbins, M. S., Perez, M. A., & Szapocznik, J. (2015). The effects of Brief Strategic Family Therapy (BSFT) on parent substance use and the association between parent and adolescent substance use. Addictive Behaviors, 42, 44–50. doi:10.1016/j.addbeh.2014.10.024 25462653
Horigian, V. E., Feaster, D. J., Robbins, M. S., Brincks, A., Perez, M. A., & Szapocznik, J. (2014). Long-term effects of brief strategic family therapy for adolescent substance users. Drug and Alcohol Dependence, 140, e91. doi:10.1016/j.drugalcdep.2014.02.265
Horigian, V. E., Feaster, D. J., Robbins, M. S., Brincks, A. M., Ucha, J., Rohrbaugh, M. J., … Szapocznik, J. (2015). A cross-sectional assessment of the long term effects of brief strategic family therapy for adolescent substance use. American Journal on Addictions, 24(7), 637–645. doi:10.1111/ajad.12278 26359441
Huey S. J., Jr., & Polo, A. J. (2017). Evidence-based psychotherapies with ethnic minority children and adolescents. In J. R. Weisz & A. E. Kazdin (Eds.), Evidence-based psychotherapies for children and adolescents (3rd ed., pp. 361–378). New York, NY: Guilford Press.
Huibregtse, B. M., Corley, R. P., Wadsworth, S. J., Vandever, J. M., DeFries, J. C., & Stallings, M. C. (2016). A longitudinal adoption study of substance use behavior in adolescence. Twin Research and Human Genetics, 19(4), 330–340. doi:10.1017/thg.2016.35 27161024
Hummel, A., Shelton, K. H., Heron, J., Moore, L., & van den Bree, M. B. (2013). A systematic review of the relationships between family functioning, pubertal timing and adolescent substance use. Addiction, 108(3), 487–496. doi:10.1111/add.12055 23163243
Ivanich, J. D., Mousseau, A. C., Walls, M., Whitbeck, L., & Whitesell, N. R. (2020). Pathways of adaptation: Two case studies with one evidence-based substance use prevention program tailored for indigenous youth. Prevention Science, 21(Suppl. 1), 43–53. doi:10.1007/s11121-018-0914-5 29876790
Jensen, M. R., Wong, J. J., Gonzales, N. A., Dumka, L. E., Millsap, R., & Coxe, S. (2014). Long-term effects of a universal family intervention: Mediation through parent-adolescent conflict. Journal of Clinical Child and Adolescent Psychology, 43(3), 415–427. doi:10.1080/15374416.2014.891228 24730357
Jessup, M. A., Ross, T. B., Jones, A. L., Satre, D. D., Weisner, C. M., Chi, F. W., & Mertens, J. R. (2014). Significant life events and their impact on alcohol and drug use: A qualitative study. Journal of Psychoactive Drugs, 46(5), 450–459. doi:10.1080/02791072.2014.962715 25364998
Jewell, T., Carr, A., Stratton, P., Lask, J., & Eisler, I. (2013). Development of a children's version of the SCORE Index of Family Function and Change. Family Process, 52(4), 673–684. doi:10.1111/famp.12044 24329409
Kaiser Permanente. (2019). Alcohol use in older adults. Retrieved April 7, 2020, from https://wa.kaiserpermanente.org/healthAndWellness/index.jhtml?item=%2Fcommon%2FhealthAndWellness%2FhealthyLiving%2Flifestyle%2Falcohol-seniors.html
Kalb, F. M., Vincent, V., Herzog, T., & Austin, J. (2017). Genetic counseling for alcohol addiction: Assessing perceptions and potential utility in individuals with lived experience and their family members. Journal of Genetic Counseling, 26(5), 963–970. doi:10.1007/s10897-017-0075-x 28176155
Kang, J. (2019). Do extended family members protect children from disadvantaged neighborhoods? Focusing on behavioral problems of children. Child and Youth Care Forum, 48(3), 427–447. doi:10.1007/s10566-019-09489-6
Kelly, S., Maynigo, P., Wesley, K., & Durham, J. (2013). African American communities and family systems: Relevance and challenges. Couple and Family Psychology: Research and Practice, 2(4), 264–277. doi:10.1037/cfp0000014
Kepple, N. J. (2017). The complex nature of parental substance use: Examining past year and prior use behaviors as correlates of child maltreatment frequency. Substance Use and Misuse, 52(6), 811–821. doi:10.1080/10826084.2016.1253747 28145806
Kepple, N. J. (2018). Does parental substance use always engender risk for children? Comparing incidence rate ratios of abusive and neglectful behaviors across substance use behavior patterns. Child Abuse and Neglect, 76, 44–55. doi:10.1016/j.chiabu.2017.09.015 29032186
Kidorf, M., Latkin, C., & Brooner, R. K. (2016). Presence of drug-free family and friends in the personal social networks of people receiving treatment for opioid use disorder. Journal of Substance Abuse Treatment, 70, 87–92. doi:10.1016/j.jsat.2016.08.013 27692194
Kim, J. S., Brook, J., & Akin, B. A. (2018). Solution-focused brief therapy with substance-using individuals: A randomized controlled trial study. Research on Social Work Practice, 28(4), 452–462. doi:10.1177/1049731516650517
Kim-Spoon, J., Lauharatanahirun, N., Peviani, K., Brieant, A., Deater-Deckard, K., Bickel, W. K., & King-Casas, B. (2019). Longitudinal pathways linking family risk, neural risk processing, delay discounting, and adolescent substance use. Journal of Child Psychology and Psychiatry, 60(6), 655–664. doi:10.1111/jcpp.13015 30809804
Klostermann, K., Chen, R., Kelley, M. L., Schroeder, V. M., Braitman, A. L., & Mignone, T. (2011). Coping behavior and depressive symptoms in adult children of alcoholics. Substance Use and Misuse, 46(9), 1162–1168. doi:10.3109/10826080903452546 21449712
Klostermann, K., Kelley, M. L., Mig none, T., Pusateri, L., & Wills, K. (2011). Behavioral couples therapy for substance abusers: Where do we go from here? Substance Use and Misuse, 46(12), 1502–1509. doi:10.3109/10826084.2011.576447 21707469
Klostermann, K., & O'Farrell, T. J. (2013). Treating substance abuse: Partner and family approaches. Social Work in Public Health, 28(3-4), 234–247. doi:10.1080/19371918.2013.759014 23731417
Kogan, S. M., Lei, M. K., Brody, G. H., Futris, T. G., Sperr, M., & Anderson, T. (2016). Implementing family-centered prevention in rural African American communities: A randomized effectiveness trial of the Strong African American Families Program. Prevention Science, 17(2), 248–258. doi:10.1007/s11121-015-0614-3 26459373
Korcha, R. A., Polcin, D. L., & Bond, J. C. (2016). Interaction of motivation and social support on abstinence among recovery home residents. Journal of Drug Issues, 46(3), 164–177. doi:10.1177/0022042616629514 27330222
Kuhn, C. (2015). Emergence of sex differences in the development of substance use and abuse during adolescence. Pharmacology and Therapeutics, 153, 55–78. doi:10.1016/j.pharmthera.2015.06.003 26049025
Kuntsche, S., & Kuntsche, E. (2016). Parent-based interventions for preventing or reducing adolescent substance use—A systematic literature review. Clinical Psychology Review, 45, 89–101. doi:10.1016/j.cpr.2016.02.004 27111301
Lam, W. K., Fals-Stewart, W., & Kelley, M. L. (2008). Effects of parent skills training with behavioral couples therapy for alcoholism on children: A randomized clinical pilot trial. Addictive Behaviors, 33(8), 1076–1080. doi:10.1016/j.addbeh.2008.04.002 18485612
Lam, W. K., Fals-Stewart, W., & Kelley, M. L. (2009). Parent training with behavioral couples therapy for fathers’ alcohol abuse: Effects on substance use, parental relationship, parenting, and CPS involvement. Child Maltreatment, 14(3), 243–254. doi:10.1177/1077559509334091 19502478
Lam, W. K. K., O'Farrell, T. J., & Birchler, G. R. (2012). Family therapy techniques for substance abuse treatment. In S. T. Walters & F. Rotgers (Eds.), Treating substance abuse: Theory and technique (3rd ed., pp. 256–280). New York, NY: Guilford Press.
Lambie, G. W., Mullen, P. R., Swank, J. M., & Blount, A. (2018). The counseling competencies scale: Validation and refinement. Measurement and Evaluation in Counseling and Development, 51(1), 1–15. doi:10.1080/07481756.2017.1358964
Lander, L., Howsare, J., & Byrne, M. (2013). The impact of substance use disorders on families and children: From theory to practice. Social Work in Public Health, 28(3-4), 194–205. doi:10.1080/19371918.2013.759005 23731414
Laqueur, H. P., Laburt, H. A., & Morong, E. (1964). Multiple family therapy. Current Psychiatric Therapies, 4, 150–154.14281131
Lassiter, P. S., Czerny, A. B., & Williams, K. S. (2015). Working with addictions in family therapy. In D. Capuzzi & M. D. Stauffer (Eds.), Foundations of couples, marriage, and family counseling (pp. 389–417). Hoboken, NJ: Wiley.
Lebensohn-Chialvo, F., Rohrbaugh, M. J., & Hasler, B. P. (2019). Fidelity failures in brief strategic family therapy for adolescent drug abuse: A clinical analysis. Family Process, 58(2), 305–317. doi:10.1111/famp.12366 29709061
Lee, J. O., Cho, J., Yoon, Y., Bello, M. S., Khoddam, R., & Leventhal, A. M. (2018). Developmental pathways from parental socioeconomic status to adolescent substance use: Alternative and complementary reinforcement. Journal of Youth and Adolescence, 47(2), 334–348. doi:10.1007/s10964-017-0790-5 29188410
Lei, N., & Pellitteri, J. (2017). Help-seeking and coping behaviors among Asian Americans: The roles of Asian values, emotional intelligence, and optimism. Asian American Journal of Psychology, 8(3), 224–234. doi:10.1037/aap0000086
Lent, J. P., & Otto, A. (2018). Grandparents, grandchildren, and caregiving: The impacts of America's substance use crisis. Generations, 42(3), 15–22.
Lester, P., Aralis, H., Sinclair, M., Kiff, C., Lee, K. H., Mustillo, S., & Wadsworth, S. M.. (2016). The impact of deployment on parental, family and child adjustment in military families. Child Psychiatry and Human Development, 47(6), 938–949. doi:10.1007/s10578-016-0624-9 26797704
Leventhal, A. M., Lee, W., Bergen, A. W., Swan, G. E., Tyndale, R. F., Lerman, C., & Conti, D. V. (2014). Nicotine dependence as a moderator of genetic influences on smoking cessation treatment outcome. Drug and Alcohol Dependence, 138, 109–117. doi:10.1016/j.drugalcdep.2014.02.016 24667010
Liddell, J., & Burnette, C. E. (2017). Culturally-informed interventions for substance abuse among indigenous youth in the United States: A review. Journal of Evidence-Informed Social Work, 14(5), 329–359. doi:10.1080/23761407.2017.1335631 28628397
Liddle, H. A. (2010). Multidimensional family therapy: A science-based treatment system. Australian and New Zealand Journal of Family Therapy, 31(2), 133–148. doi:10.1375/anft.31.2.133
Liddle, H. A., Dakof, G. A., Henderson, C., & Rowe, C. (2011). Implementation outcomes of Multidimensional Family Therapy-Detention to Community: A reintegration program for drug-using juvenile detainees. International Journal of Offender Therapy and Comparative Criminology, 55(4), 587–604. doi:10.1177/0306624x10366960 20427547
Liddle, H. A., Dakof, G. A., Rowe, C. L., Henderson, C., Greenbaum, P., Wang, W., & Alberga, L. (2018). Multidimensional Family Therapy as a community-based alternative to residential treatment for adolescents with substance use and co-occurring mental health disorders. Journal of Substance Abuse Treatment, 90, 47–56. doi:10.1016/j.jsat.2018.04.011 29866383
Liddle, H. A., Dakof, G. A., Turner, R. M., Henderson, C. E., & Greenbaum, P. E. (2008). Treating adolescent drug abuse: A randomized trial comparing multidimensional family therapy and cognitive behavior therapy. Addiction, 103(10), 1660–1670. doi:10.1111/j.1360-0443.2008.02274.x 18705691
Liddle, H. A., Rowe, C. L., Dakof, G. A., Henderson, C. E., & Greenbaum, P. E. (2009). Multidimensional family therapy for young adolescent substance abuse: Twelve-month outcomes of a randomized controlled trial. Journal of Consulting and Clinical Psychology, 77(1), 12–25. doi:10.1037/a0014160 19170450
Liddle, H. A., Rowe, C. L., Dakof, G. A., Ungaro, R. A., & Henderson, C. E. (2004). Early intervention for adolescent substance abuse: Pretreatment to posttreatment outcomes of a randomized clinical trial comparing Multidimensional Family Therapy and peer group treatment. Journal of Psychoactive Drugs, 36(1), 49–63. doi:10.1080/02791072.2004.10399723 15152709
Liepman, M. R., Flachier, R., & Tareen, R. S. (2008). Family behavior loop mapping: A technique to analyze the grip addictive disorders have on families and to help them recover. Alcoholism Treatment Quarterly, 26(1-2), 59–80. doi:10.1300/J020v26n01_04
Lipari, R., Palen, L. A., Ashley, O. S., Penne, M., Kan, M., & Pemberton, M. (2017). Examination of veteran fathers’ parenting and their adolescent children's substance use in the United States. Substance Use and Misuse, 52(6), 698–708. doi:10.1080/10826084.2016.1253748 28145805
Lipari, R. N., & Van Horn, S. L. (2017, August 24). Children living with parents who have a substance use disorder: The CBHSQ Report. Rockville, MD: Center for Behavioral Health Statistics and Quality, Substance Abuse and Mental Health Services Administration.
Lloyd-Hazlett, J., Honderich, E. M., & Heyward, K. J. (2016). Fa-MI-ly: Experiential techniques to integrate motivational interviewing and family counseling. Family Journal, 24(1), 31–37. doi:10.1177/1066480715615666
Loveland, D. (2014, June). Creating a front door to engage and retain individuals with a SUD. In Engagement strategies: Supporting wellness and recovery conference. Presentation at the Meeting of Community Care and Western Psychiatric Institute & Clinic. State College, PA.
Lucero, N. M., & Bussey, M. (2015). Practice-informed approaches to addressing substance abuse and trauma exposure in urban native families involved with child welfare. Child Welfare, 94(4), 97–117.26827478
Ma, M., Malcolm, L. R., Díaz-Albertini, K., Sánchez, J. C., Simpson, B., Cortes, L., & Kibler, J. L. (2017). Cultural assets and substance use among Hispanic adolescents. Health Education and Behavior, 44(2), 326–331. doi:10.1177/1090198116659440 27450551
MacNicol, B. (2017). The biology of addiction. Canadian Journal of Anesthesia, 64(2), 141–148. doi:10.1007/s12630-016-0771-2 27837404
Magette, A. L., Durtschi, J. A., & Love, H. A. (2018). Lesbian, gay, and bisexual substance use in emerging adulthood moderated by parent-child relationships in adolescence. American Journal of Family Therapy, 46(3), 272–286. doi:10.1080/01926187.2018.1493958
Mahalik, J. R., Lombardi, C. M., Sims, J., Coley, R. L., & Lynch, A. D. (2015). Gender, male-typicality, and social norms predicting adolescent alcohol intoxication and marijuana use. Social Science and Medicine, 143, 71–80. doi:10.1016/j.socscimed.2015.08.013 26344125
Marmorstein, Ν. R„ Iacono, W. G., & McGue, M. (2012). Associations between substance use disorders and major depression in parents and late adolescent-emerging adult offspring: An adoption study. Addiction, 107(11), 1965–1973. doi:10.1111/j.1360-0443.2012.03934.x 22571621
Marsiglia, F. F., Nagoshi, J. L., Parsai, M., & Castro, F. G. (2014). The effects of parental acculturation and parenting practices on the substance use of Mexican-heritage adolescents from southwestern Mexican neighborhoods. Journal of Ethnicity in Substance Abuse, 13(3), 288–311. doi:10.1080/15332640.2014.905215 25176121
Martinez, M. J., Ayers, S. L„ Kulis, S., & Brown, E. (2015). The relationship between peer, parent, and grandparent norms and intentions to use substances for urban American Indian youths. Journal of Child and Adolescent Substance Abuse, 24(4), 220–227. doi:10.1080/1067828X.2013.812529 26203212
Mathew, K. J., Regmi, B„ & Lama, L. D. (2018). Role of family in addictive disorders. International Journal of Psychosocial Rehabilitation, 22(1), 65–75.
McCollister, K. E., French, M. T., Sheidow, A. J., Henggeler, S. W„ & Halliday-Boykins, C. A. (2009). Estimating the differential costs of criminal activity for juvenile drug court participants: Challenges and recommendations. Journal of Behavioral Health Services and Research, 36(1), 111–126. doi:10.1007/s11414-007-9094-y 18172769
McCollum, E. E., & Trepper, T. S. (2013). Family solutions for substance abuse: Clinical and counseling approaches. New York, NY: Routledge Publishers.
McCrady, B. S„ Tonigan, J. S„ Ladd, B. O., Hallgren, Κ. Α., Pearson, M. R., Owens, M. D., & Epstein, E. E. (2019). Alcohol behavioral couple therapy: In-session behavior, active ingredients and mechanisms of behavior change. Journal of Substance Abuse Treatment, 99, 139–148. doi:10.1016/j.jsat.2019.01.018 30797386
McCrady, B. S„ Wilson, A. D„ Muñoz, R. E„ Fink, B. C„ Fokas, K„ & Borders, A. (2016). Alcohol-focused behavioral couple therapy. Family Process, 55(3), 443–459. doi:10.1111/famp.12231 27369809
McCutcheon, V. V., Agrawal, Α., Kuo, S. I., Su, J., Dick, D. M., Meyers, J. L., … Bucholz, Κ. K. (2018). Associations of parental alcohol use disorders and parental separation with offspring initiation of alcohol, cigarette and cannabis use and sexual debut in high-risk families. Addiction, 113(2), 336–345. doi:10.1111/add.14003 28804966
McFarlane, W. R., Dixon, L., Lukens, E., & Lucksted, A. (2003). Family psychoeducation and schizophrenia: A review of the literature. Journal of Marital and Family Therapy, 29(2), 223–245. doi:10.1111/j.1752-0606.2003.tb01202.x 12728780
McGoldrick, M. (1995). You can go home again: Reconnecting with your family. New York, NY: Norton.
McHugh, R. K., Votaw, V. R„ Sugarman, D. E., & Greenfield, S. F. (2018). Sex and gender differences in substance use disorders. Clinical Psychology Review, 66, 12–23. doi:10.1016/j.cpr.2017.10.012 29174306
McLaughlin, Κ. Α., Green, J. G., Gruber, M. J., Sampson, N. Α., Zaslavsky, A. M„ & Kessler, R. C. (2010). Childhood adversities and adult psychiatric disorders in the National Comorbidity Survey Replication II: Associations with persistence of DSM-IV disorders. Archives of General Psychiatry, 67(2), 124–132. doi:10.1001/archgenpsychiatry.2009.187 20124112
Menon, J., & Kandasamy, A. (2018). Relapse prevention. Indian Journal of Psychiatry, 60(Suppl. 4), S473–S478. doi:10.4103/psychiatry.lndianJPsychiatry_36_18 29540916
Mignon, S. I., & Holmes, W. M. (2013). Substance abuse and mental health issues within Native American grandparenting families. Journal of Ethnicity in Substance Abuse, 12(3), 210–227. doi:10.1080/15332640.2013.798751 23967883
Mignone, T., Klostermann, K., Mahadeo, M., Papagni, E., & Jankie, J. (2017). Confidentiality and family therapy: Cultural considerations. ARC Journal of Psychiatry, 2(1), 9–16.
Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). New York, NY: Guilford Press.
Milne, B. J., Caspi, Α., Harrington, H., Poulton, R., Rutter, M., & Moffitt, T. E. (2009). Predictive value of family history on severity of illness: The case for depression, anxiety, alcohol dependence, and drug dependence. Archives of General Psychiatry, 66(7), 738–747. doi:10.1001/archgenpsychiatry.2009.55 19581565
Mojtabai, R., Stuart, Ε. Α., Hwang, I., Eaton, W. W., Sampson, N., & Kessler, R. C. (2017). Long-term effects of mental disorders on marital outcomes in the National Comorbidity Survey ten-year follow-up. Social Psychiatry and Psychiatric Epidemiology, 52(10), 1217–1226. doi:10.1007/s00127-017-1373-1 28378065
Moon, Z. (2016). Pastoral care and counseling with military families. Journal of Pastoral Care Counseling, 70(2), 128–135. doi:10.1177/1542305016633663 27281760
Moos, R. H. (2011). Processes that promote recovery from addictive disorders. In J. F. Kelly & W. L. White (Eds.), Addiction recovery management: Theory, research, and practice (pp. 45–66). New York, NY: Humana Press.
Moos, R. H., & Moos, B. S. (2007). Protective resources and long-term recovery from alcohol use disorders. Drug and Alcohol Dependence, 86(1), 46–54. doi:10.1016/j.drugalcdep.2006.04.015 16769181
Moran, P. (2017). Selecting self-report outcome measures for use in family and systemic therapy. Journal of Family Therapy, 39(1), 41–56. doi:10.1111/1467-6427.12082
Morgan, T. B., & Crane, D. R. (2010). Cost-effectiveness of family-based substance abuse treatment. Journal of Marital and Family Therapy, 36(4), 486–498. doi:10.1111/j.1752-0606.2010.00195.x 21039660
Morgan, T. B., Crane, D. R., Moore, A. M., & Eggett, D. L. (2013). The cost of treating substance use disorders: Individual versus family therapy. Journal of Family Therapy, 35(1), 2–23. doi:10.1111/j.1467-6427.2012.00589.x
Myhra, L. L., Wieling, E., & Grant, H. (2015). Substance use in American Indian family relationships: Linking past, present, and future. American Journal of Family Therapy, 43(5), 413–424. doi:10.1080/01926187.2015.1069133
Nadel, E. L., & Thornberry, T. P. (2017). Intergenerational consequences of adolescent substance use: Patterns of homotypic and heterotypic continuity. Psychology of Addictive Behaviors, 31(2), 200–211. doi:10.1037/adb0000248 28182447
National Academies of Sciences, Engineering, and Medicine. (2016). Families caring for an aging America. Washington, DC: National Academies Press.
National Alliance on Mental Illness. (2019). NAMI family support group. Retrieved from https://www.nami.org/Support-Education/Support-Groups/NAMI-Family-Support-Group
National Association of Social Workers. (2015). Standards and indicators for cultural competence in social work practice. Retrieved April 7, 2020, from www.socialworkers.org/LinkClick.aspx?fileticket=7dVckZAYUmk%3d&portalid=0
National Domestic Violence Hotline. (2014, August 1). Why we don't recommend couples counseling for abusive relationships. Retrieved April 6, 2020, from www.thehotline.org/2014/08/01/why-we-dont-recommend-couples-counseling-for-abusive-relationships/
National Institute on Alcohol Abuse and Alcoholism. (n.d.). Drinking levels defined. Retrieved from www.niaaa.nih.gov/alcohol-health/overview-alcohol-consumption/moderate-binge-drinking
National Institute on Drug Abuse. (2018). Is drug addiction treatment worth its cost? Retrieved April 6, 2020, from www.drugabuse.gov/publications/principles-drug-addiction-treatment-research-based-guide-third-edition/frequently-asked-questions/drug-addiction-treatment-worth-its-cost
Nichols, M. P., & Davis, S. (2017). Family therapy: Concepts and methods (11th ed.). Boston, MA: Pearson.
Nicosia, N., Wong, E., Shier, V., Massachi, S., & Datar, A. (2017). Parental deployment, adolescent academic and social-behavioral maladjustment, and parental psychological well-being in military families. Public Health Reports, 132(1), 93–105. doi:10.1177/0033354916679995 28005475
Novins, D. K., Ferron, C., Abramson, L., & Barlow, A. (2018). Addressing substance-use problems in tribal home visiting. Infant Mental Health Journal, 39(3), 287–294. doi:10.1002/imhj.21706 29722426
O'Farrell, T. J., & Clements, K. (2012). Review of outcome research on marital and family therapy in treatment for alcoholism. Journal of Marital and Family Therapy, 38(1), 122–144. doi:10.1111/j.1752-0606.2011.00242. 22283384
O'Farrell, T. J., Murphy, M., Alter, J., & Fals-Stewart, W. (2010). Behavioral family counseling for substance abuse: A treatment development pilot study. Addictive Behaviors, 35(1), 1–6. doi:10.1016/j.addbeh.2009.07.003 19717243
O'Farrell, T. J., & Schein, A. Z. (2011). Behavioral couples therapy for alcoholism and drug abuse. Journal of Family Psychotherapy, 22(3), 193–215. doi:10.1080/08975353.2011.602615
O'Farrell, T. J., Schreiner, A., Schumm, J., & Murphy, M. (2016). Do outcomes after behavioral couples therapy differ based on the gender of the alcohol use disorder patient? Addictive Behaviors, 54, 46–51.26709856
O'Farrell, T. J., Schumm, J. A., Murphy, M. M., & Muchowski, P. M. (2017). A randomized clinical trial of behavioral couples therapy versus individually-based treatment for drug-abusing women. Journal of Consulting and Clinical Psychology, 85(4), 309–322.28333533
Ohannessian, C. M., Flannery, K. M., Simpson, E., & Russell, B. S. (2016). Family functioning and adolescent alcohol use: A moderated mediation analysis. Journal of Adolescence, 49, 19–27. doi:10.1016/j.adolescence.2016.02.009 26994346
Olmstead, T. A., Abraham, A. J., Martino, S., & Roman, P. M. (2012). Counselor training in several evidence-based psychosocial addiction treatments in private US substance abuse treatment centers. Drug and Alcohol Dependence, 120(1-3), 149–154. doi:10.1016/j.drugalcdep.2011.07.017 21831536
Orford, J., Hodgson, R., Copello, A., Wilton, S., Slegg, G., & UKATT Research Team. (2009). To what factors do clients attribute change? Content analysis of follow-up interviews with clients of the UK Alcohol Treatment Trial. Journal of Substance Abuse Treatment, 36(1), 49–58.18547778
Osilla, K. C., Trail, T. E., Pedersen, E. R., Gore, K. L., Tolpadi, A., & Rodriguez, L. M. (2018). Efficacy of a web-based intervention for concerned spouses of service members and veterans with alcohol misuse. Journal of Marital and Family Therapy, 44(2), 292–306. doi:10.1111/jmft.12279 28972265
Padilla, Y. C., Crisp, C., & Rew, D. L. (2010). Parental acceptance and illegal drug use among gay, lesbian, and bisexual adolescents: Results from a national survey. Social Work, 55(3), 265–275. doi:10.1093/sw/55.3.265 20632661
Papernow, P. L. (2018). Clinical guidelines for working with stepfamilies: What family, couple, individual, and child therapists need to know. Family Process, 57(1), 25–51. doi:10.1111/famp.12321 29057461
Park, S. Y., Anastas, J., Shibusawa, T., & Nguyen, D. (2014). The impact of acculturation and acculturative stress on alcohol use across Asian immigrant subgroups. Substance Use and Misuse, 49(8), 922–931. doi:10.3109/10826084.2013.855232 24779491
Partnership for Drug-Free Kids. (2015). How to build effective community partnerships to prevent teen substance abuse: Implementing PACT360 in your community. Washington, DC: Office of Community Oriented Policing Services.
Pina, A. A., Polo, A. J., & Huey, S. J. (2019). Evidence-based psychosocial interventions for ethnic minority youth: The 10-year update. Journal of Clinical Child and Adolescent Psychology, 48(2), 179–202. doi:10.1080/15374416.2019.1567350 30746965
Platt, L. F., & Skowron, E. A. (2013). The family genogram interview: Reliability and validity of a new interview protocol. Family Journal, 21(1), 35–45. doi:10.1177/1066480712456817
Prado, G., Cordova, D., Huang, S., Estrada, Y., Rosen, A., Bacio, G. A., … McCollister, K. (2012). The efficacy of Familias Unidas on drug and alcohol outcomes for Hispanic delinquent youth: Main effects and interaction effects by parental stress and social support. Drug and Alcohol Dependence, 125(Suppl. 1), S18–S25. doi:10.1016/j.drugalcdep.2012.06.011 22776441
Prochaska, J. O., & DiClemente, C. C. (1984). The transtheoretical approach: Crossing traditional boundaries of therapy. Homewood, IL: Dow Jones-Irwin.
Prom-Wormley, E. C., Ebejer, J., Dick, D. M., & Bowers, M. S. (2017). The genetic epidemiology of substance use disorder: A review. Drug and Alcohol Dependence, 180, 241–259. doi:10.1016/j.drugalcdep.2017.06.040 28938182
Rambo, A., & Hibel, J. (2013). What is family therapy? Underlying premises. In A. Rambo, C. West, A. Schooley, & T. V. Boyd (Eds.), Family therapy review: Contrasting contemporary models (pp. 3–8). New York, NY: Routledge, Taylor & Francis Group.
Rapp, C. A., & Goscha, R. J. (2012). The strengths model: A recovery-oriented approach to mental health services (3rd ed.). New York, NY: Oxford University Press.
Rapp, R. C., Van Den Noortgate, W., Broekaert, E., & Vanderplasschen, W. (2014). The efficacy of case management with persons who have substance abuse problems: A three-level meta-analysis of outcomes. Journal of Consulting and Clinical Psychology, 82(4), 605–618. doi:10.1037/a0036750 24821097
Reczek, C., Thomeer, M. B., Kissling, A., & Liu, H. (2017). Relationships with parents and adult children's substance use. Addictive Behaviors, 65, 198–206. doi:10.1016/j.addbeh.2016.10.014 27835859
Reilly, M. T., Noronha, A., Goldman, D., & Koob, G. F. (2017). Genetic studies of alcohol dependence in the context of the addiction cycle. Neuropharmacology, 122, 3–21. doi:10.1016/j.neuropharm.2017.01.017 28118990
Reiter, M. D. (2015). Substance abuse and the family. New York, NY: Routledge.
Reyes, H. L., Foshee, V. A., Tharp, A. T., Ennett, S. T., & Bauer, D. J. (2015). Substance use and physical dating violence: The role of contextual moderators. American Journal of Preventive Medicine, 49(3), 467–475. doi:10.1016/j.amepre.2015.05.018 26296445
Rigazio-DiGilio, S. A. (2016). MFT supervision: An overview. In K. Jordan (Ed.), Couple, marriage, and family therapy supervision (pp. 25–49). New York, NY: Springer Publishing.
Robbins, M. S., Feaster, D. J., Horigian, V. E., Rohrbaugh, M., Shoham, V., Bachrach, K., … Szapocznik, J. (2011). Brief strategic family therapy versus treatment as usual: Results of a multisite randomized trial for substance using adolescents. Journal of Consulting and Clinical Psychology, 79(6), 713–727. doi:10.1037/a0025477 21967492
Rogers, R. G., Lawrence, E. M., & Montez, J. K. (2016). Alcohol's collateral damage: Childhood exposure to problem drinkers and subsequent adult mortality risk. Social Forces, 95(2), 809–836. doi:10.1093/sf/sow074
Roozen, H. G., de Waart, R., & van der Kroft, P. (2010). Community reinforcement and family training: An effective option to engage treatment-resistant substance-abusing individuals in treatment. Addiction, 105(10), 1729–1738. doi:10.1111/j.1360-0443.2010.03016.x 20626372
Rothenberg, J. L., Sullivan, M. A., Church, S. H., Seracini, A., Collins, E., Kleber, H. D., & Nunes, E. V. (2002). Behavioral naltrexone therapy: An integrated treatment for opiate dependence. Journal of Substance Abuse Treatment, 23(4), 351–360.12495797
Rowan, M., Poole, N., Shea, B., Gone, J. P., Mykota, D., Farag, M., … Dell, C. (2014). Cultural interventions to treat addictions in indigenous populations: Findings from a scoping study. Substance Abuse Treatment, Prevention, and Policy, 9, 34. doi:10.1186/1747-597x-9-34 25179797
Rowe, C., Rigter, H., Henderson, C., Gantner, A., Mos, K., Nielsen, P., & Phan, O. (2013). Implementation fidelity of Multidimensional Family Therapy in an international trial. Journal of Substance Abuse Treatment, 44(4), 391–399. doi:10.1016/j.jsat.2012.08.225 23085040
Rowe, C. L. (2012). Family therapy for drug abuse: Review and updates 2003-2010. Journal of Marital and Family Therapy, 38(1), 59–81. doi:10.1111/j.1752-0606.2011.00280.x 22283381
Russell, B. S., Simpson, E., Flannery, K. M., & Ohannessian, C. M. (2019). The impact of adolescent substance use on family functioning: The mediating role of internalizing symptoms. Youth and Society, 51(4), 504–528. doi:10.1177/0044118X16688708
Santisteban, D. A., Mena, M. P., & Abalo, C. (2013). Bridging diversity and family systems: Culturally informed and flexible family-based treatment for Hispanic adolescents. Couple and Family Psychology: Research and Practice, 2(4), 246–263. doi:10.1037/cfp0000013
Satir, V. (1988). The new peoplemaking. Mountain View, CA: Science and Behavior Books.
Satir, V., Banmen, J., Gerber, J., & Gomori, M. (1991). The Satir model: Family therapy and beyond. Palo Alto, CA: Science and Behavior Books.
Savage, J. E., & Mezuk, B. (2014). Psychosocial and contextual determinants of alcohol and drug use disorders in the National Latino and Asian American Study. Drug and Alcohol Dependence, 139, 71–78. doi:10.1016/j.drugalcdep.2014.03.011 24742864
Schaeffer, C. M., Swenson, C. C., Tuerk, E. H., & Henggeler, S. W. (2013). Comprehensive treatment for co-occurring child maltreatment and parental substance abuse: Outcomes from a 24-month pilot study of the MST-Building Stronger Families Program. Child Abuse and Neglect, 37(8), 596–607. doi:10.1016/j.chiabu.2013.04.004 23768938
Schinke, S. P., Fang, L., Cole, K. C., & Cohen-Cutler, S. (2011). Preventing substance use among Black and Hispanic adolescent girls: Results from a computer-delivered, mother-daughter intervention approach. Substance Use and Misuse, 46(1), 35–5. doi:10.3109/10826084.2011.521074
Schuckit, M. A. (2014). A brief history of research on the genetics of alcohol and other drug use disorders. Journal of Studies on Alcohol and Drugs. 75(Suppl. 17), 59–67.24565312
Schumm, J. Α., Monson, C. M., O'Farrell, T. J., Gustin, Ν. G., & Chard, Κ. M. (2015). Couple treatment for alcohol use disorder and posttraumatic stress disorder: Pilot results from U.S. military veterans and their partners. Journal of Traumatic Stress, 28(3), 247–252. doi:10.1002/jts.22007 25965768
Schumm, J. Α., & O'Farrell, T. J. (2013a). Behavioral couples therapy for alcoholism. In P. M. Miller et al. (Eds.), Comprehensive addictive behaviors and disorders: Vol. 3. Interventions for addiction (pp. 57–65). San Diego, CA: Elsevier Academic Press.
Schumm, J. Α., & O'Farrell, T. J. (2013b). Families and addiction. In P. M. Miller et al. (Eds.), Comprehensive addictive behaviors and disorders: Vol. 1. Principles of addiction (pp. 303–312). San Diego, CA: Elsevier Academic Press.
Schumm, J. Α., O'Farrell, T. J., & Andreas, J. B. (2012). Behavioral couples therapy when both partners have a current alcohol use disorder. Alcoholism Treatment Quarterly, 30(4), 407–421. doi:10.1080/07347324.2012.718963 23264718
Schumm, J. Α., O'Farrell, T. J., Kahler, C. W„ Murphy, M. M., & Muchowski, P. (2014). A randomized clinical trial of behavioral couples therapy versus individually based treatment for women with alcohol dependence. Journal of Consulting and Clinical Psychology, 82(6), 993–1004. doi:10.1037/a0037497 25045910
Shaw, D. J., Warren, T. B„ & Johnson, M. E. (2019). Family structure and past-30 day opioid misuse among justice-involved children. Substance Use and Misuse, 54(7), 1226–1235. doi:10.1080/10826084.2019.1573839 30849263
Sheidow, A. J., & Henggeler, S. W. (2008). Multisystemic therapy for alcohol and other drug abuse in delinquent adolescents. Alcoholism Treatment Quarterly, 26(1-2), 125–145. doi:10.1300/J020v26n01_07
Sheidow, A. J., McCart, M. R„ & Davis, M. (2016). Multisystemic therapy for emerging adults with serious mental illness and justice involvement. Cognitive Behavioral Practice, 23(3), 356–367. doi:10.1016/j.cbpra.2015.09.003 28458504
Shellenberger, S. (2007). Use of the genogram with families for assessment and treatment. In F. Shapiro, F. W. Kaslow, & L. Maxfield (Eds.), Handbook of EMDR and family therapy processes (pp. 76–94). Hoboken, NJ: Wiley.
Shih, R. Α., Tucker, J. S„ Miles, J. N„ Ewing, Β. Α., Pedersen, E. R., & D'Amico, E. J. (2015). Differences in substance use and substance use risk factors by Asian subgroups. Asian American Journal of Psychology, 6(1), 38–6. doi:10.1037/a0036251 26388971
Slesnick, N., Erdem, G., Bartle-Haring, S., & Brigham, G. S. (2013). Intervention with substance-abusing runaway adolescents and their families: Results of a randomized clinical trial. Journal of Consulting and Clinical Psychology, 81(4), 600–614. doi:10.1037/a0033463 23895088
Smith, J. M., & Estefan, A. (2014). Families parenting adolescents with substance abuse—Recovering the mother's voice: A narrative literature review. Journal of Family Nursing, 20(4), 415–441. doi:10.1177/1074840714554397 25342471
Smith, T. E„ Malespin, T. S., Pereira, M. G., & Richards, K. V. (2016). Factors relating to the use of family therapy with adolescent marijuana abusers. Child and Adolescent Social Work Journal, 33(3), 237–243. doi:10.1007/s10560-015-0417-1
Smith, V. C., Wilson, C. R., & Committee on Substance Use and Prevention. (2016). Families affected by parental substance use. Pediatrics, 138(2), e20161575. doi:10.1542/peds.2016-1575 27432847
Smith-Genthôs, Κ. R., Logue, Ε. M., Low, Β. E., & Hendrick, S. S. (2017). The forgotten ones: Siblings of substance abusers. Journal of Loss and Trauma, 22(2), 120–134. doi:10.1080/15325024.2016.1202005
Soper, R. G. (2014, October 6). Intimate partner violence and co-occurring substance abuse/addiction. ASAM Magazine, 1-9.
Sparks, S. N„ Tisch, R„ & Gardner, M. (2013). Family-centered interventions for substance abuse in Hispanic communities. Journal of Ethnicity in Substance Abuse, 72(1), 68–81. doi:10.1080/15332640.2013.759785
Stanton, M., & Welsh, R. (2012). Systemic thinking in couple and family psychology research and practice. Couple and Family Psychology: Research and Practice, 1(1), 14–30. doi:10.1037/a0027461
Steinglass, P. (2009). Systemic-motivational therapy for substance abuse disorders: An integrative model. Journal of Family Therapy, 31(2), 155–174. doi:10.1111/j.1467-6427.2009.00460.x
Steinglass, P., Sanders, C., & Wells, F. (2019). Multiple family group therapy. In B. H. Fiese, M. Celano, K. Deater-Deckard, E. N. Jouriles, & M. A. Whisman (Eds.), APA handbook of contemporary family psychology: Family therapy and training (Vol. 3, pp. 155–169). Washington, DC: American Psychological Association.
Steinka-Fry, K. T., Tanner-Smith, E. E., Dakof, G. A., & Henderson, C. (2017). Culturally sensitive substance use treatment for racial/ethnic minority youth: A meta-analytic review. Journal of Substance Abuse Treatment, 75, 22–37. doi:10.1016/j.jsat.2017.01.006 28237051
Stormshak, E. A., Connell, A. M., Véronneau, M. H., Myers, M. W., Dishion, T. J., Kavanagh, K., & Caruthers, A. S. (2011). An ecological approach to promoting early adolescent mental health and social adaptation: Family-centered intervention in public middle schools. Child Development, 82(1), 209–225. doi:10.1111/j.1467-8624.2010.01551.x 21291438
Strunin, L., Díaz-Martinez, A., Díaz-Martinez, L. R., Kuranz, S., Hernández-Ávila, C. A., Pantridge, C. E., & Fernández-Varela, H. (2015). Natural mentors and youth drinking: A qualitative study of Mexican youths. Health Education Research, 30(4), 660–670. doi:10.1093/her/cyv030 26187913
Substance Abuse and Mental Health Services Administration. (2010). Recovery-oriented systems of care (ROSC) resource guide - Working draft.
Substance Abuse and Mental Health Services Administration. (2013). Substance abuse treatment: Addressing the specific needs of women. Treatment Improvement Protocol (TIP) Series 51. HHS Publication No. (SMA)13-4426. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2015). Using technology-based therapeutic tools in behavioral health services. Treatment Improvement Protocol (TIP) Series 60. HHS Publication No. (SMA) 15-4924. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2017, August 1). Complex connections: Intimate partner violence and women's substance abuse and recovery. PowerPoint slides presented as part of Relationships Matter, a webinar series on women's behavioral health. Rockville, MD: Substance Abuse and Mental Health Services Administration and Administration for Children and Families. Retrieved September 10, 2020, from https://www.youtube.com/watch?v=IE13p5GgW0E
Substance Abuse and Mental Health Services Administration. (2018). Behavioral health services for American Indians and Alaska Natives. Treatment Improvement Protocol (TIP) Series 61. HHS Publication No. (SMA) 18-5070. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2019a). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. HHS Publication No. PEP19-02-01-003. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration. (2019b). Substance abuse confidentiality regulations. Retrieved April 6, 2020, from www.samhsa.gov/about-us/who-we-are/laws-regulations/confidentiality-regulations-faqs
Substance Abuse and Mental Health Services Administration. (2020). National Survey of Substance Abuse Treatment Services (N-SSATS): 2019. Data on substance abuse treatment facilities. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved September 10, 2020, from https://www.samhsa.gov/data/sites/default/files/reports/rpt29389/NSSATS-2019.pdf
Sudhir, P. M. (2018). Cognitive behavioural interventions in addictive disorders. Indian Journal of Psychiatry, 60(Suppl. 4), S479–S484. doi:10.4103/psychiatry.IndianJPsychiatry_15_18 29540917
Sullivan, K., Capp, G., Gilreath, T. D., Benbenishty, R., Roziner, I., & Astor, R. A. (2015). Substance abuse and other adverse outcomes for military-connected youth in California: Results from a large-scale normative population survey. JAMA Pediatrics, 169(10), 922–928. doi:10.1001/jamapediatrics.2015.1413 26280338
Szapocznik, J., Hervis, O., & Schwartz, S. (2003). Brief strategic family therapy for adolescent drug abuse. Therapy Manuals for Drug Addiction. Bethesda, MD: National Institute on Drug Abuse.
Szapocznik, J., Muir, J. A., Duff, J. H., Schwartz, S. J., & Brown, C. H. (2015). Brief strategic family therapy: Implementing evidence-based models in community settings. Psychotherapy Research, 25(1), 121–133.24274187
Tanner-Smith, E. E., Wilson, S. J., & Lipsey, M. W. (2013). The comparative effectiveness of outpatient treatment for adolescent substance abuse: A meta-analysis. Journal of Substance Abuse Treatment, 44(2), 145–158. doi:10.1016/j.jsat.2012.05.006 22763198
Teeters, J. B., Lancaster, C. L., Brown, D. G., & Back, S. E. (2017). Substance use disorders in military veterans: Prevalence and treatment challenges. Substance Abuse and Rehabilitation, 8, 69–77. doi:10.2147/sar.S116720 28919834
Thapa, S., Selya, A. S., & Jonk, Y. (2017). Time-varying effects of parental alcoholism on depression. Preventing Chronic Disease, 14, E136. doi:10.5888/pcd14.170100 29240551
Trail, T. E., Martin, L. T., Burgette, L. F., May, L. W., Mahmud, A., Nanda, N., & Chandra, A. (2017). An evaluation of U.S. military non-medical counseling programs. Santa Monica, CA: RAND.
Trone, D. W., Powell, T. M., Bauer, L. M., Seelig, A. D., Peterson, A. V., Littman, A. J., … Boyko, E. J. (2018). Smoking and drinking behaviors of military spouses: Findings from the Millennium Cohort Family Study. Addictive Behaviors, 77, 121–130. doi:10.1016/j.addbeh.2017.09.015 28992577
Tucker, J. S., Edelen, M. O., & Huang, W. (2017). Effectiveness of parent-child mediation in improving family functioning and reducing adolescent problem behavior: Results from a pilot randomized controlled trial. Journal of Youth and Adolescence, 46(3), 505–515. doi:10.1007/s10964-015-0412-z 26762375
Tuerk, E. H., McCart, M. R., & Henggeler, S. W. (2012). Collaboration in family therapy. Journal of Clinical Psychology, 68(2), 168–178. doi:10.1002/jclp.21833 23616297
U.S. Census Bureau. (2017a). Grandchildren under 18 years living with a grandparent householder by age of grandchild, 2013-2017. American Community Survey 5-year estimates. Retrieved August 13, 2019.
U.S. Census Bureau. (2017b). Grandparents, 2013-2017. American Community Survey 5-year estimates. Retrieved August 13, 2019.
U.S. Census Bureau. (2019a). Grandchildren characteristics. 2018 American Community Survey 1-year estimates. Retrieved April 6, 2020, from https://data.census.gov/cedsci/table?q=S10&d=ACS%201-Year%20Estimates%20Subject%20Tables&tid=ACSST1Y2018.S1001&vintage=2018
U.S. Census Bureau. (2019b). Grandparents. 2018 American Community Survey 1-year estimates. Retrieved April 6, 2020, from https://data.census.gov/cedsci/table?q=S10&d=ACS%201-Year%20Estimates%20Subject%20Tables&tid=ACSST1Y2018.S1002&vintage=2018
U.S. Census Bureau. (2019c). Relationship to householder for children under 18 years in households. 2018 American Community Survey 1-year estimates. Retrieved April 6, 2020, from https://data.census.gov/cedsci/table?hidePreview=true&tid=ACSDT1Y2018.B09018&vintage=2018
U.S. Department of Health and Human Services, Centers for Disease Control and Prevention. (2011). Cognitive impairment: A call for action now. Retrieved April 7, 2020, from www.cdc.gov/aging/pdf/cognitiveimpairment/cogimppoilicyfinal.pdf
U.S. Department of Health and Human Services, Office of Minority Health. (2018). Brief strategic family therapy. Retrieved April 6, 2020, from https://minorityhealth.hhs.gov/npa/materials/briefstrategyfamilytherapy.pdf
U.S. Department of Health and Human Services, Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. Washington, DC: Author.
Vaeth, P. A., Wang-Schweig, M., & Caetano, R. (2017). Drinking, alcohol use disorder, and treatment access and utilization among U.S. racial/ethnic groups. Alcoholism: Clinical and Experimental Research, 41(1), 6–19. doi:10.1111/acer.13285 28019654
van Eeden-Moorefield, B., & Pasley, B. K. (2013). Remarriage and stepfamily life. In G. W. Peterson & K. R. Bush (Eds.), Handbook of marriage and the family (3rd ed., pp. 517–546). New York, NY: Springer Science + Business Media.
van Wormer, K. S., & Davis, D. R. (2018). Addiction treatment: A strengths perspective. Boston, MA: Cengage Learning.
Ventura, A. S., & Bagley, S. M. (2017). To improve substance use disorder prevention, treatment and recovery: Engage the family. Journal of Addiction Medicine, 11(5), 339–341. doi:10.1097/adm.0000000000000331 28787300
Vermeulen-Smit, E., Verdurmen, J. E., & Engels, R. C. (2015). The effectiveness of family interventions in preventing adolescent illicit drug use: A systematic review and meta-analysis of randomized controlled trials. Clinical Child and Family Psychology Review, 18(3), 218–239. doi:10.1007/s10567-015-0185-7 25998971
Vernig, P. M. (2011). Family roles in homes with alcohol-dependent parents: An evidence-based review. Substance Use and Misuse, 46(4), 535–542. doi:10.3109/10826084.2010.501676 20735193
Villatoro, A. P., Morales, E. S., & Mays, V. M. (2014). Family culture in mental health help-seeking and utilization in a nationally representative sample of Latinos in the United States: The NLAAS. American Journal of Orthopsychiatry, 84(4), 353–363. doi:10.1037/h0099844 24999521
Ward, K. P., Dennis, C. B., & Limb, G. E. (2018). The impact of stepfamily relationship quality on emerging adult non-medical use of prescription drugs. American Journal of Drug and Alcohol Abuse, 44(4), 463–471. doi:10.1080/00952990.2017.1405010 29261329
Watkins, C. E., Hook, J. N., Jr., Owen, J., DeBlaere, C., Davis, D. E., & Van Tongeren, D. R. (2019). Multicultural orientation in psychotherapy supervision: Cultural humility, cultural comfort, and cultural opportunities. American Journal of Psychotherapy, 72(2), 38–46. doi:10.1176/appi.psychotherapy.20180040 30945559
Wegscheider-Cruse, S. (1989). Another chance: Hope and health for the alcoholic family (2nd ed.). Palo Alto, CA: Science and Behavior Books.
Wells, E. A., Kristman-Valente, A. N., Peavy, K. M., & Jackson, T. R. (2013). Social workers and delivery of evidence-based psychosocial treatments for substance use disorders. Social Work in Public Health, 28(3-4), 279–301. doi:10.1080/19371918.2013.759033 23731420
Welsh, J. W., Knight, J. R., Hou, S. S., Malowney, M., Schram, P., Sherritt, L., & Boyd, J. W. (2017). Association between substance use diagnoses and psychiatric disorders in an adolescent and young adult clinic-based population. Journal of Adolescent Health, 60(6), 648–652. doi:10.1016/j.jadohealth.2016.12.018
Werner, D., Young, N. K., Dennis, K., & Amatetti, S. (2007). Family-centered treatment for women with substance use disorders: History, key elements and challenges. Rockville, MD: Substance Abuse and Mental Health Services Administration.
White, M., & Epston, D. (1990). Narrative means to therapeutic ends (1st ed.). New York, NY: Norton.
White, W., & Cloud, W. (2008). Recovery capital: A primer for addictions professionals. Counselor, 9(5), 22–27.
White, W. L. (2014). Slaying the dragon: The history of addiction treatment and recovery in America (2nd ed.). Bloomington, IL: Chestnut Health Systems.
White, W. L., & Sanders, M. (2006). Recovery management and people of color: Redesigning addiction treatment for historically disempowered communities. In W. L. White, E. Kurtz, & M. Sanders (Eds.), Recovery management (pp. 58–86). Chicago, IL: Great Lakes Addiction Technology Transfer Center.
Whiteman, S. D., Jensen, A. C., Mustillo, S. A., & Maggs, J. L. (2016). Understanding sibling influence on adolescents’ alcohol use: Social and cognitive pathways. Addictive Behaviors, 53, 1–6.26414204
Wilkinson, A. L., Fleming, P. J., Halpern, C. T., Herring, A. H., & Harris, K. M. (2018). Adherence to gender-typical behavior and high frequency substance use from adolescence into young adulthood. Psychology of Men and Masculinity, 19(1), 145–155. doi:10.1037/men0000088 29479292
Williamson, E., Smith, M., Orford, J., Copello, A., & Day, E. (2007). Social Behavior and Network Therapy for drug problems: Evidence of benefits and challenges. Addictive Disorders and Their Treatment, 6, 167–179.
Wlodarczyk, O., Schwarze, M., Rumpf, H. J., Metzner, F., & Pawils, S. (2017). Protective mental health factors in children of parents with alcohol and drug use disorders: A systematic review. PloS One, 12(6), e0179140. doi:10.1371/journal.pone.0179140 28609440
Wong, E. C., Derose, K. P., Litt, P., & Miles, J. N. V. (2018). Sources of care for alcohol and other drug problems: The role of the African American church. Journal of Religion and Health, 57(4), 1200–1210. doi:10.1007/s10943-017-0412-2 28502023
Worley, M. J., Trim, R. S., Tate, S. R., Roesch, S. C., Myers, M. G., & Brown, S. A. (2014). Self-efficacy and social networks after treatment for alcohol or drug dependence and major depression: Disentangling person and timelevel effects. Psychology of Addictive Behaviors, 28(4), 1220–1229. doi:10.1037/a0037901 25347018
Yap, M. B. H., Cheong, T. W. K., Zaravinos-Tsakos, F., Lubman, D. I., & Jorm, A. F. (2017). Modifiable parenting factors associated with adolescent alcohol misuse: A systematic review and meta-analysis of longitudinal studies. Addiction, 112(7), 1142–1162. doi:10.1111/add.13785 28178373
Yoon, G., Westermeyer, J., Kuskowski, M. A., & Nesheim, L. (2013). Impact of the number of parents with alcohol use disorder on alcohol use disorder in offspring: A population-based study. Journal of Clinical Psychiatry, 74(8), 795–801. doi:10.4088/JCP.13m08350 24021496
Zhao, S., Sampson, S., Xia, J., & Jayaram, M. B. (2015). Psychoeducation (brief) for people with serious mental illness. Cochrane Database of Systematic Reviews, (4), CD010823. doi:10.1002/14651858.CD010823.pub2 25854522
Zweben, J. E., Moses, Y., Cohen, J. B., Price, G., Chapman, W., & Lamb, J. (2015). Enhancing family protective factors in residential treatment for substance use disorders. Child Welfare, 94(5), 145–166.26827469