# Consensus Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

## Chair

Steven L. Batki, M.D.
Professor
Department of Psychiatry
SUNY Upstate Medical University
Syracuse, New York

## Co-Chair

Peter A. Selwyn, M.D., M.P.H.
Professor and Chairman
Department of Family Medicine and Community Health
Montefiore Medical Center
Albert Einstein College of Medicine
Bronx, New York

## Panelists

Deborah Wright Bauer, M.P.H., M.L.S.
Health Project Consultant
Georgia Ryan White Title IV Project
Epidemiology and Prevention Branch
Department of Human Resources
Atlanta, Georgia

Margaret K. Brooks, J.D., M.A.
New Perspectives
Montclair, New Jersey

Robert Paul Cabaj, M.D.
Medical Director
San Mateo County Mental Health Services
Mental Health Services Administration
San Mateo, California

Susan M. Gallego, M.S.S.W., L.M.S.W.-A.C.P.
Trainer, Consultant, and Facilitator
Austin, Texas

Larry M. Gant, Ph.D., C.S.W., M.S.W.
Associate Professor
School of Social Work
University of Michigan
Ann Arbor, Michigan

Brian C. Giddens, M.S.W., A.C.S.W.
Associate Director
Social Work Department
University of Washington Medical Center
Seattle, Washington

Gregory L. Greenwood, Ph.D., M.P.H.
TAPS Fellow
Center for AIDS Prevention Studies
University of California at San Francisco
San Francisco, California

Elizabeth F. Howell, M.D.
Substance Abuse Program Chief
Georgia Department of Human Resources
Division of Mental Health, Mental Retardation and Substance Abuse
Atlanta, Georgia

Martin Yoneo Iguchi, Ph.D.
Co-Director
Senior Behavioral Scientist
Drug Policy Research Center
RAND
Santa Monica, California

Susan LeLacheur, M.P.H., P.A.-C.
Assistant Professor of Health Care Sciences and Health Sciences
The George Washington University
Physician Assistant Program
Washington, D.C.

Andrea Ronhovde, L.C.S.W.
Director
Alexandria Mental Health HIV/AIDS Project
Alexandria Mental Health Center
Alexandria, Virginia

Ronald D. Stall, Ph.D., M.P.H.
Center for AIDS Prevention Studies
University of California at San Francisco
San Francisco, California

Michael D. Stein, M.D.
Associate Professor
Department of Medicine
Brown University
Providence, Rhode Island