# Appendix J Field Reviewers

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

Deborah Wright Bauer, M.P.H., M.L.S.
Health Project Consultant
Georgia Ryan White Title IV Project
Epidemiology and Prevention Branch
Department of Human Resources
Atlanta, Georgia

Margaret K. Brooks, J.D., M.A.
New Perspectives
Montclair, New Jersey
Robert Paul Cabaj, M.D.
Medical Director
San Mateo County Mental Health Services
Mental Health Services Administration
San Mateo, California

Edwin M. Craft, Ph.D.
Program Analyst
Office of Evaluation, Scientific Analysis and Synthesis, Synthesis Branch
Center for Substance Abuse Treatment
Rockville, Maryland

Michael A. Dawes, M.D.
Assistant Professor of Psychiatry
Child and Adolescent Psychiatry
Western Psychiatric Institute and Clinic
Pittsburgh, Pennsylvania

James Donagher, M.A.
Director
Senior Services
Special Populations of Office of Behavioral Health Department of Mental Health and Addiction Services
Hartford, Connecticut

Michael Fingerhood, M.D.
Associate Professor of Medicine
Center for Chemical Dependence School of Medicine
Johns Hopkins University
Baltimore, Maryland

Stewart L. Gallas, S.W.A., M.A.
Co-Director, Client Services
AIDS Services of Austin
Austin, Texas

Susan M. Gallego, M.S.S.W., L.M.S.W.-A.C.P.
Trainer, Consultant, and Facilitator
Austin, Texas

Larry M. Gant, Ph.D., C.S.W., M.S.W.
Associate Professor School of Social Work
University of Michigan
Ann Arbor, Michigan

Brian C. Giddens, M.S.W., A.C.S.W.
Associate Director Social Work Department
University of Washington Medical Center
Seattle, Washington

Michael Gorman, Ph.D., M.S.W., M.P.H.
Research Scientist/Principal
Investigator Alcohol and Drug Abuse
Institute School of Social Work
University of Washington
Seattle, Washington

Brian L. Greenberg, Ph.D.
Director of Development Walden House, Incorporated
San Francisco, California

Gregory L. Greenwood, Ph.D., M.P.H.
TAPS Fellow
Center for AIDS Prevention Studies
University of California at San Francisco
San Francisco, California

Susan Haikalis, A.C.S.W., M.S.W., L.C.S.W.
Director
HIV Services and Treatment Support
San Francisco AIDS Foundation
San Francisco, California

William F. Haning, III, M.D.
Department of Psychiatry School of Medicine
University of Hawaii
Honolulu, Hawaii

Peter Hayden
Director
TURNING POINT
National Chairperson National Black Alcoholism and Addictions Council
Minneapolis, Minnesota

Warren W. Hewitt, Jr., M.S.
Planner
Office of Policy Coordination and Planning Center for Substance Abuse Treatment
Rockville, Maryland

Donna Johnson, L.M.S.W.
Hospice Social Worker
Denson Community Health Services Hospice
League City, Texas

Murali R. Jonnalagadda, M.D., M.P.H., F.A.P.A.
Jacksonville
North Carolina

Karen Kelly-Woodall, M.S., M.A.C., N.C.A.C.II
Criminal Justice Coordinator
Addiction Technology Transfer Center
Morehouse School of Medicine
Atlanta, Georgia

Sherry Knapp, Ph.D.
Associate Director
Division of Substance Abuse Rhode Island
Department of Health Providence
Rhode Island

Marshall K. Kubota, M.D.
Director
Family Practice Residency Program
Sutter Medical Center of Santa Rosa
Santa Rosa, California

Susan LeLacheur, M.P.H., P.A.-C.
Assistant Professor of Health Care Sciences and Health Sciences
The George Washington University
Physician Assistant Program
Washington, D.C.

Yvette Lindsey
HIV Community Coalition
Washington, D.C.

Russell P. MacPherson, Ph.D., C.A.P., C.A.P.P.
President
RPM Addiction Prevention Training
Deland, Florida

John J. McGovern, C.S.W.
Director
Clinical Services
HELP/Project Samaritan, Inc.
Bronx, New York

Lisa A. Melchior, Ph.D.
Vice President
The Measurement Group
Culver City, California

Alelia Munroe
Consultant
National Black Alcoholism and Addictions Council
Orlando, Florida

Gail M. Nahwahquaw, B.S.
Case Manager Consultant
Consultant (Menominee)
The HIV Center for Excellence
Phoenix Indian Medical Center
Phoenix, Arizona

Thomas Nicholson, Ph.D., M.P.H., M.A.Ed.
Professor
Department of Public Health
Western Kentucky University
Bowling Green, Kentucky

Kenneth L. Packer
Health Education Consultant
The Golden Skate
Washingtonville, New York

Eileen Stark Pagan, M.S., R.N.C.
Director of Nursing Services
HELP/ Project Samaritan, Inc.
Bronx, New York

Billy Pick, J.D., M.S.W.
Program Manager
AIDS Office San Francisco
Department of Public Health
San Francisco, California

Mel Pohl, M.D.
Charter Hospital
Las Vegas, Nevada

John F. Robertson, Ph.D.
Executive Director
Robertson Psychological and Consulting Services
National Black Alcoholism and Addictions Council
Utica, New York

Andrea Ronhovde, L.C.S.W.
Director
Alexandria Mental Health HIV/AIDS Project
Alexandria Mental Health Center
Alexandria, Virginia

Jeffrey H. Samet, M.D., M.A., M.P.H.
Associate Professor of Medicine
Boston University School of Medicine
Boston, Massachusetts

Christine Smith, M.S.W.
Senior Analyst
ABT Associates
Cambridge, Massachusetts

Mary Sowder, L.P.C., C.D.A.C.
Vice President
Texas HIV Connection Workers Assistance Program
Austin, Texas

Ronald D. Stall, Ph.D., M.P.H.
Center for AIDS Prevention Studies
University of California at San Francisco
San Francisco, California

Richard T. Suchinsky, M.D.
Associate Chief for Addictive Disorders and Psychiatric Rehabilitation Mental Health and Behavioral Sciences Services
Department of Veterans Affairs
Washington, D.C.

David C. Thompson
Public Health Advisor
Division of Practice and Systems
Development Center for Substance Abuse Treatment
Rockville, Maryland

Mark E. Wallace, M.D.
Psychiatrist
New York City Human Resources Administration Office of Health and Mental Services
New York, New York

Gloria Weissman
Director
Program Development Staff
Division of Community Based Programs
HIV/AIDS Bureau Health Resources and Services Administration
Rockville, Maryland

Christopher J. Welsh, M.D.
Clinical Assistant Professor
Alcohol and Drug Abuse/Psychiatry
Medical Director
HIV/LAAM Program
University of Maryland
Baltimore, Maryland

Barbara C. Zeller, M.D.
Medical Director
HELP/Project Samaritan, Inc.
Bronx, New York

Janet Zwick
Director
Division of Substance Abuse and Health Promotion
Iowa Department of Public Health
Des Moines, Iowa