# Appendix I Resource Panel

Note: The information given indicates each participant's affiliation during the time the panel was convened and may no longer reflect the individual's current affiliation.

Brad Austin
Public Health Advisor
Division of State and Community Assistance
PPG Program Branch
Center for Substance Abuse Treatment
Rockville, Maryland

Jose Martin Garcia-Ordoria
Technical Assistant Manager
National Latino/a Lesbian and Gay Organization
Washington, D.C.

Patricia Hawkins, Ph.D.
Associate Executive Director
Whitman-Walker Clinic
Washington, D.C.

Adolfo Mata
Director
Migrant Health Program
Community of Migrant Health
Bureau of Primary Health Care
Health Resources Services Administration
Bethesda, Maryland

M. Valerie Mills, M.S.W.
Associate Administrator for AIDS
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Andrea Ronhovde, L.C.S.W.
Director
Alexandria Mental Health HIV/AIDS Project
Alexandria Mental Health Center
Alexandria, Virginia

Gloria Weissman
Director
Program Development Staff
Division of Community Based Programs
HIV/AIDS Bureau Health Resources and Services Administration
Rockville, Maryland