# Appendix G Mini Mental State Examination (MMSE)

Not available for download because of lack of permissions.