# Appendix F State and Territorial Health Agencies/Offices of AIDS

Listed immediately following each State's name is the State's HIV/AIDS Hotline telephone number, which provides free and anonymous information and referral to services.

ALABAMA

Hotline: (800) 228-0469

Alabama Department of Public Health

Division of HIV/AIDS Prevention and Control

RSA Tower

201 Monroe Street

Suite 1400

Montgomery, AL 36104

Phone: (334) 206-5364; Fax: (334) 206-2092

ALASKA

Hotline: (800) 478-2437

Alaska Department of Health and Social Services

Division of Public Health

350 Main Street, Room 503

Juneau, AK 99801

Phone: (907) 465-3090; Fax: (907) 586-1877

(See “Section on Epidemiology” for HIV/AIDS information.)

ARIZONA

Hotline: (800) 352-3792

Arizona Department of Health Services Bureau of Epidemiology & Disease Control Services

3815 North Black Canyon

Phoenix, AZ 85015

Phone: (602) 230-5808; Fax: (602) 230-5959

Arizona Office of HIV/STD Services

Phone: (602) 230-5819

ARKANSAS

Hotline: (800) 482-5400

Arkansas Department of Health

AIDS/STD Section

Arkansas Department of Health

4815 West Markham Street, Mailstop 33

Little Rock, AR 72205-3867

Phone: (501) 661-2111; Fax: (501) 671-1450

CALIFORNIA

Hotline: (800) 367-AIDS

TDD: (888) 225-AIDS

California Department of Health Services

Office of AIDS

611 North 7th Street

P.O. Box 942732

Sacramento, CA 94234-7320

Phone: (916) 445-0553

COLORADO

Hotline: (800) 252-2437

Colorado Department of Public Health and Environment

Disease Control & Environmental Epidemiology Division

DCEED-A3

4300 Cherry Creek Drive South

Denver, CO 80246-1530

Phone: (303) 692-2700; Fax: (303) 782-0904

CONNECTICUT

Hotline: [not available]

State of Connecticut Department of Public Health

Bureau of Community Health

410 Capitol Avenue

P.O. Box 340308, MS #11BCH

Hartford, CT 06134-0308

Phone: (860) 509-7655; Fax: (860) 509-7717

DELAWARE

Hotline: (800) 422-0429

Delaware Health and Social Services

Division of Public Health, Epidemiology

Federal & Water Streets

P.O. Box 637

Dover, DE 19903

Phone: (302) 739-5617; Fax: (302) 739-6659

DISTRICT OF COLUMBIA

Hotline: (800) 322-7432

District of Columbia Department of Health

Administration for HIV/AIDS

717 14th Street NW, 6th Floor

Washington, DC 20036

Phone: (202) 727-2500; Fax: (202) 724-3795

FEDERATED STATES OF MICRONESIA

Hotline: [not available]

Government of the Federated States of Micronesia

P.O. Box PS70

Palikir Station

Pohnpei, FSM 96941

Phone: 011 (691) 320-2619; Fax: (690) 320-5263

FLORIDA

Hotline: (800) 352-AIDS

TDD: (888) 503-7118

Spanish: (800) 545-SIDA

Haitian Creole: (800) 243-7101

Department of Health

Bureau of HIV/AIDS

2020 Capital Circle SE, BIN A09

Tallahassee, FL 32399-1715

Phone: (850) 488-9766; Fax: (850) 414-0038

GEORGIA

Hotline: (800) 551-2728

Georgia Division of Public Health

Epidemiology and Health Information

HIV/STD Surveillance Unit

Two Peachtree Street, NW, Suit 14460

Atlanta, GA 30303-3186

Phone: (404) 657-2624

GUAM

Hotline: [not available]

Guam Department of Public Health and Social Services

P.O. Box 2816

Agana, GU 96910

Phone: 011 (671) 735-7102; Fax: (671) 734-5910

HAWAII

Hotline: (800) 321-1555

Hawaii Department of Health

Communicable Disease Division

STD/AIDS Information and Prevention

3627 Kileuee Avenue

Suite 305

Honolulu, HI 96816-2399

Phone: (808) 733-9010

IDAHO

Hotline: (800) 677-2437

Idaho Department of Health and Welfare

P.O. Box 83720

450 West State Street, 10th Floor

Boise, ID 83720-0036

Phone: (208) 334-5500

ILLINOIS

Hotline: (800) 243-2437

TDD: (800) 782-0423

Illinois Department of Public Health

535 West Jefferson Street

Springfield, IL 62761

Phone: (217) 782-4977; Fax: (217) 782-3987

INDIANA

Hotline: (800) 848-2437

TDD: (800) 972-1846

Indiana State Department of Health

2 North Meridian Street

Indianapolis, IN 46204

Phone: (317) 233-1325

IOWA

Hotline: (800) 445-2437

Iowa Department of Public Health

STD/HIV Prevention Program

Lucas State Office Building

321 East 12th Street

Des Moines, IA 50319

Phone: (515) 242-5838; Fax: (515) 281-4570

KANSAS

Hotline: [not available]

Kansas Department of Health and Environment

Division of Health

Bureau of Epidemiology and Disease Prevention, AIDS Section

109 SW 9th Street, Suite 605

Topeka, KS 66612-1271

Phone: (785) 296-6173; Fax: (785) 296-4197

KENTUCKY

Hotline: [not available]

Kentucky Department for Public Health

275 East Main Street

Frankfort, KY 40621

Phone: (502) 564-3970; Fax: (502) 564-6533

LOUISIANA

Hotline: (800) 992-4379

TDD: (504) 944-2492

Louisiana Department of Health and Hospitals

P.O. Box 3214

Baton Rouge, LA 70821

Phone: (504) 342-8093; Fax: (504) 342-8098

MAINE

Hotline: (800) 851-2437

Maine Bureau of Health

State House Station 11

157 Capitol Street

Augusta, ME 04333-0011

Phone: (207) 287-8016; Fax: (207) 287-4631

MARYLAND

Hotline: (800) 638-6252

Metro D.C. and VA: (800) 322-7432

TDD (Baltimore area only): (410) 333-2437

Spanish: (301) 949-0945

State of Maryland Department of Health and Mental Hygiene

AIDS Administration

500 North Calvert St.

Fifth Floor

Baltimore, MD 21202

Phone: (410) 767-6505; Fax: (410) 767-6489

MASSACHUSETTS

Hotline: (800) 235-2331

TDD: (617) 437-1672

Massachusetts Department of Public Health

250 Washington Street, 2nd Floor

Boston, MA 02108-4619

Phone: (617) 624-5200; Fax: (617) 624-5206

MICHIGAN

Hotline: (800) 872-2437

TDD: (800) 332-0849

Michigan Department of Community Health

3423 North Martin Luther King, Jr. Boulevard.

P.O. Box 30195

Lansing, MI 48909

Phone: (517) 335-8024; Fax: (517) 335-9476

MINNESOTA

Hotline: (800) 248-2437

Minnesota Department of Health

121 East Seventh Place, Suite 450

P.O. Box 9441

St. Paul, MN 55164-0975

Phone: (612) 215-5803; Fax: (612) 215-5801

MISSISSIPPI

Hotline: (800) 826-2961

Mississippi State Department of Health

570 East Woodrow Wilson

P.O. Box 1700

Jackson, MS 39215-1700

Phone: (601) 576-7634; Fax: (601) 960-7931

MISSOURI

Hotline: (800) 533-2437

Missouri Department of Health

920 Wildwood

P.O. Box 570

Jefferson City, MO 65102

Phone: (573) 751-6002; Fax: (573) 751-6041

MONTANA

Hotline: (800) 233-6668

Montana Department of Public Health and Human Services

P.O. Box 202951

Helena, MT 59620-2951

Phone: (406) 444-5622; Fax: (406) 444-1970

NEBRASKA

Hotline: (800) 782-2437

Nebraska Health and Human Services System

P.O. Box 95007

Lincoln, NE 68509-5007

Phone: (402) 471-3711; Fax: (402) 471-0820

NEVADA

Hotline: (800) 842-2437

Nevada State Health Division

505 East King Street, Room 201

Carson City, NV 89701-4797

Phone: (775) 687-3786; Fax: (702) 687-3859

NEW HAMPSHIRE

Hotline: (800) 752-2437

New Hampshire Department of Health and Human Services

Six Hazen Drive

Concord, NH 03301-6527

Phone: (603) 271-4372; Fax: (603) 271-4727

NEW JERSEY

Hotline: (800) 624-2377

TDD: (201) 926-8008

New Jersey Department of Health and Senior Services

CN360, Room 805

John Fitch Plaza

Trenton, NJ 08625-0360

Phone: (609) 292-7837; Fax: (609) 292-0053

NEW MEXICO

Hotline: (800) 545-2437

New Mexico Department of Health

P.O. Box 26110

Santa Fe, NM 87502-6110

Phone: (505) 827-2613; Fax: (505) 827-2530

NEW YORK

Hotline: (800) 872-2777, (800) 541-2437; Spanish: (800) 233-SIDA

TDD: (800) 369-2437

New York State Department of Health AIDS Institute

Empire State Plaza, 14th Floor Corning Tower Building Albany, NY 12237

Phone: (518) 474-2011; Fax: (518) 474-5450

NORTH CAROLINA

Hotline: (800) 342-2437

North Carolina Department of Health and Human Services

1601 Mail Service Center Raleigh, NC 27699-1601

Phone: (919) 733-4984; Fax: (919) 715-3060

NORTH DAKOTA

Hotline: (800) 472-2180

North Dakota Department of Health

600 East Boulevard Avenue

Bismarck, ND 58505-0200

Phone: (701) 328-2372; Fax: (701) 328-4727

OHIO

Hotline: (800) 332-2437; TDD: (800) 332-3889

Ohio Department of Health

246 North High Street

P.O. Box 118

Columbus, OH 43266-0118

Phone: (614) 466-2253; Fax: (614) 644-0085

OKLAHOMA

Hotline: (800) 535-2437

Oklahoma State Department of Health

1000 NE 10th Street

Oklahoma City, OK 73117-1299

Phone: (405) 271-4200; Fax: (405) 271-3431

OREGON

Hotline: (800) 777-2437 (For area codes 503, 206 and 208)

Voice and TDD: (503) 223-2437

Oregon Department of Human Services

800 NE Oregon Street, #21, Suite 925

Portland, OR 97232

Phone: (503) 731-4000; Fax: (503) 731-4078

PENNSYLVANIA

Hotline: (800) 662-6080

Pennsylvania Department of Health HIV/AIDS Programs

Health and Welfare Building, Room 802

Harrisburg, PA 17120

Phone: (717) 787-6436; Fax: (717) 787-0191

PUERTO RICO

Hotline: (800) 981-5721

Puerto Rico Department of Public Health

Commonwealth of Puerto Rico

Building A

Call Box 70184

San Juan, PR 00936

Phone: (809) 274-7600; Fax: (809) 250-6745

RHODE ISLAND

Hotline: (800) 726-3010

Rhode Island Department of Health

Three Capitol Hill, Room 106

Providence, RI 02908-5097

Phone: (401) 222-2577; Fax: (401) 272-3771

SOUTH CAROLINA

Hotline: (800) 322-2437

South Carolina Department of Health and Environmental Control

2600 Bull Street

Columbia, SC 29201

Phone: (803) 898-3432; Fax: (803) 734-4620

SOUTH DAKOTA

Hotline: (800) 592-1861

South Dakota Department of Health

Sigurd Anderson Building

445 East Capitol Avenue

Pierre, SD 57501-3185

Phone: 605-773-3361; Fax: 605-773-5683

TENNESSEE

Hotline: (800) 525-2437

Tennessee Department of Health

Cordell Hull Building, 3rd Floor

425 Fifth Avenue North

Nashville, TN 37247-0101

Phone: (615) 741-3111; Fax: (615) 741-2491

TEXAS

Hotline: (800) 299-2437

TDD: (800) 252-8012

Texas Department of Health

1100 West 49th Street

Austin, TX 78756-7446

Phone: (512) 458-7376; Fax: (512) 458-7477

UTAH

Hotline: (800) 366-2437

Utah Department of Health

Bureau of HIV/AIDS/TB Control/Refugee Health

288 North 1460 West

P.O. Box 142105

Salt Lake City, UT 84114-2105

Phone: (801) 538-0696; Fax: (801) 538-6306

VERMONT

Hotline: (800) 464-4343

Vermont Department of Health

108 Cherry Street

Burlington, VT 05402-0070

Phone: (802) 863-7280; Fax: (802) 863-7425

U.S. VIRGIN ISLANDS

Hotline: (809) 773-2437

Virgin Islands Department of Social and Health Services

48 Sugar Estate

St. Thomas, VI 00802

Phone: (809) 774-0117; Fax: (809) 777-4001

VIRGINIA

Hotline: (800) 533-4148

Spanish: (800) 322-7432

Virginia Department of Health

1500 East Main Street, Suite 214

P.O. Box 2448

Richmond, VA 23219

Phone: (804) 786-3561; Fax: (804) 786-4616

WASHINGTON

Hotline: (800) 272-2437

Washington State Department of Health

1112 SE Quince Street

P.O. Box 47890

Olympia, WA 98504-7890

Phone: (360) 753-5871; Fax: (360) 586-7424

WEST VIRGINIA

Hotline: (800) 642-8244

West Virginia Department of Health and Human Resources Bureau for

Public Health Surveillance and Disease Control Room 125

350 Capitol Street

Charleston, WV 25302-3715

Phone: (304) 558-5358; Fax: (394) 558-1035

WISCONSIN

Hotline: (414) 273-2437 or (800) 334-2437

Wisconsin Department of Health and Family Services

One West Wilson Street

P.O. Box 309

Madison, WI 53701-0309

Phone: (608) 266-1511; Fax: (608) 267-2832

WYOMING

Hotline: (800) 327-3577

Wyoming Department of Health

117 Hathaway Building

Cheyenne, WY 82002

Phone: (307) 777-7656; Fax: (307) 777-7439