# Appendix A Bibliography

AIDS Weekly Plus. Knowledge, attitudes, and behavior: Conspiracy theories about HIV put individuals at risk. November 13, 1995.
Allen, D.M.; Lehman, J.S.; Green, T.A.; Lindegren, M.L.; Onorato, I.M.; and Forrester, W. HIV infection among homeless adults and runaway youth, United States, 1989–1992. AIDS 8(11):1593–1598, 1994.7848596
Alliegro, M.B.; Dorrucci, M.; Phillips, A.N.; Pezzotti, P.; Boros, S.; Zaccarelli, M.; Pristera, R.; and Rezza, G. Incidence and consequences of pregnancy in women with known duration of HIV infection. Archives of Internal Medicine 157(22):2585–2590, 1997.9531227
Amass, L.; Bickel, W.K.; Higgins, S.T.; and Hughes, J.R. A preliminary investigation of outcome following gradual or rapid buprenorphine detoxification. Journal of Addictive Diseases 13(3):33–45, 1994.7734458
American Academy of Neurology, AIDS Task Force. Criteria for diagnosis of HIV-1 associated dementia complex: Nomenclature and research case definitions for neurologic manifestations of HIV-1 infection. Neurology 41:778–784, 1991.2046917
American Psychiatric Association (APA). Diagnostic and Statistical Manual of Mental Disorders, 4th ed. Washington, DC: APA, 1994.
American Psychiatric Association (APA). Practice Guidelines for Treatment of Patients With Substance Use Disorders; Alcohol, Cocaine, Opioids. Washington, DC: APA, 1995.
American Society of Addiction Medicine (ASAM). Guidelines for HIV Infection and AIDS in Addiction Treatment. Chevy Chase, MD: ASAM, 1998.
American Thoracic Society. Treatment of tuberculosis in alcoholic patients. American Review of Respiratory Disease 116:559–560, 1977.409319
Americans With Disabilities Act. 42 U.S.C. §12101 et seq. (1992).
Anand, A.; Carmosino, L.; and Glatt, A.E. Evaluation of recalcitrant pain in HIV-infected hospitalized patients. Journal of Acquired Immune Deficiency Syndromes 7(1):52–56, 1994.8263753
Angelone, S.M.; Bellini, L.; Di Bella, D.; and Catalano, M. Effects of fluvoxamine and citalopram in maintaining abstinence in a sample of Italian detoxified alcoholics. Alcohol and Alcoholism 33(2):151–156, 1998.9566477
Ashery, R.S. Issues in AIDS training for substance abuse workers. Journal of Substance Abuse Treatment 9(1):15–19, 1992.1593660
Asim, J. “Black paranoia far-fetched? Maybe, but understandable.” The Phoenix Gazette Op-Ed:A13, February 23, 1993.
Avins, A.L.; Woods, W.J.; Lindan, C.P.; Hudes, E.S.; Clark, W.; and Hulley, S.B. HIV infection and risk behaviors among heterosexuals in alcohol treatment programs. JAMA 271(7):515–518, 1994.8301765
Baker, A.; Kochan, N.; Dixon, J.; Wodak, A.; and Heather, N. HIV risk-taking behaviour among injecting drug users currently, previously, and never enrolled in methadone treatment. Addiction 90(4):545–554, 1995.7773117
Ball, J.C.; Lange, W.R.; Myers, C.P.; and Friedman, S.R. Reducing the risk of AIDS through methadone maintenance treatment. Journal of Health and Social Behavior 29(3):214–226, 1988.3241064
Ball, J.C., and Ross, A. The Effectiveness of Methadone Maintenance Treatment. New York: Springer-Verlag, 1991.
Bandura, A. Self-efficacy: Toward a unifying theory of behavioral change. Psychological Review 84(2):191–215, 1977.847061
Banks, A., and Gartrell, N.K. Lesbians in the medical setting. In: Cabaj, R.P., and Stein, T.S., eds. Homosexuality and Mental Health: A Comprehensive Review. Washington, DC: American Psychiatric Press, 1996. pp. 659–671.
Barre-Sinoussi, F.; Chermann, J.C.; Rey, F.; Nugeyre, M.T.; Chamaret, S.; Gruest, J.; Dauguet, C.; Axler-Blin, C.; Vezinet-Brun, F.; Rouzioux, C.; Rozenbaum, W.; and Montagnier, L. Isolation of T-lymphotropic retrovirus from a patient at risk for acquired immunodeficiency syndrome (AIDS). Science 220(4599):868–871, 1983.6189183
Bartlett, J.G. Medical Management of HIV Infection. Baltimore, MD: Johns Hopkins AIDS Service, 1999.
Batki, S.L. Treatment of intravenous drug abusers with AIDS: The role of methadone maintenance. Journal of Psychoactive Drugs 20(2):213–216, 1988.3418453
Batki, S.L.; Blake, M.; Gruber, V.; Milovitch, E.; Ouye, G.; Nathan, K.; and Warren, R. Standards of Care: Client Assessment and Treatment Protocol. Unpublished tool used by the Opiate Treatment Outpatient Program, San Francisco General Hospital, University of California at San Francisco, 1999.
Batki, S.L.; Ferrando, S.J.; Manfredi, L.; London, J.; Pattillo, J.; and Delucchi, K. Psychiatric disorders, drug use, and medical status in injection drug users with HIV disease. American Journal on Addictions 5(3):249–258, 1996.
Batki, S.L., and London, J. Drug abuse treatment for HIV-infected patients. In: Sorensen, J.L.; Wermuth, L.A.; Gibson, D.R.; Choi, K.-H., Guydish, J.R.; and Batki, S.L., eds. Preventing AIDS in Drug Abusers and Their Sexual Partners. New York: Guilford Press, 1991. pp. 77–98.
Beatty, R.L. “Alcoholism and the adult gay male population of Pennsylvania.” Master's thesis. Harrisburg, PA: Pennsylvania State University, 1983.
Beck, A.T., and Steer, R.A. Beck Depression Inventory. San Antonio, TX: Psychological Corporation, 1993.
Bell, A.P., and Weinberg, M.S. Homosexualities: A Study of Diversities Among Men and Women. New York: Simon & Schuster, 1978.
Bell, A.P.; Weinberg, M.S.; and Hammersmith, S.K. Sexual Preference; Its Development in Men and Women. Bloomington, IN: Indiana University Press, 1981.
Berglund, M., and Ojehagen, A. The influence of alcohol drinking and alcohol use disorders on psychiatric disorders and suicidal behavior. Alcoholism, Clinical and Experimental Research 22(7 Suppl):333S–345S, 1998.9799958
Berlin, E.A., and Fowkes, Jr., N.C. A teaching framework for cross-cultural health care. Western Journal of Medicine 139(6):934–938, 1983.6666112
Bickel, W.K., and Amass, L. The relationship of mean daily blood alcohol levels to admission MAST, clinic absenteeism, and depression in alcoholic methadone patients. Drug and Alcohol Dependence 32:113–118, 1993.8389689
Bickel, W.K.; Amass, L.; Higgins, S.T.; Badger, G.J.; and Esch, R.A. Effects of adding behavioral treatment to opioid detoxification with buprenorphine. Journal of Consulting and Clinical Psychology 65(5):803–810, 1997.9337499
Bindman, A.B.; Osmond, D.; Hecht, F.M.; Lehman, J.S.; Vranizan, K.; Keane, D.; Reingold, A.; and the Multistate Evaluation of Surveillance of HIV (MESH) Study Group. Multistate evaluation of anonymous HIV testing and access to medical care. JAMA 280(16):1416–1420, 1998.9801001
Bloomfield, K. A comparison of alcohol consumption between lesbians and heterosexual women in an urban population. Drug and Alcohol Dependence 33(3):257–269, 1993.8261890
Boccellari, A.A.; Chambers, D.B.; Dilley, J.W.; Shore, M.D.; Tauber, M.A.; Moss, A.R.; and Osmond, D.H. Relationship of beta 2 microglobulin and CD4 counts to neuropsychological performance in HIV-1-infected intravenous drug abusers. Journal of Acquired Immune Deficiency Syndromes 7(10):1040–1049, 1994.7916050
Boccellari, A.A.; Dilley, J.W.; Chambers, D.B.; Yingling, C.D.; Tauber, M.A.; Moss, A.R.; and Osmond, D.H. Immune function and neuropsychological performance in HIV-1-infected homosexual men. Journal of Acquired Immune Deficiency Syndromes 6(6):592–601, 1993a.8098751
Boccellari, A.A.; Dilley, J.W.; Yingling, C.D.; Chambers, D.B.; Tauber, M.A.; Moss, A.R.; and Osmond, D.H. Relationship of CD4 counts to neurophysiological function in HIV-1-infected homosexual men. Archives of Neurology 50(5):517–521, 1993b.8098207
Bokos, P.J.; Mejta, C.L.; Mickenberg, J.H.; and Monks, R.L. Case management: An alternative approach to working with intravenous drug abusers. In: Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92–1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 92–111.
Booth, R.E.; Kwiatkowski, C.; Iguchi, M.Y.; Pinto, F.; and John, D. Facilitating treatment entry among out-of-treatment injection drug users. Public Health Reports 113 (Suppl. 1):116–128, 1998.9722817
Booth, R.E., and Wiebel, W.W. Effectiveness of reducing needle-related risks for HIV through indigenous outreach to injection drug users. American Journal on Addictions 1(4):277–287, 1992.
Bortolotti, F.; Stivanello, A.; Armi, Dall' A.; Rinaldi, R.; and La Grasto, F. AIDS information campaign has significantly reduced risk factors for HIV infection in Italian drug abusers. Journal of Acquired Immune Deficiency Syndromes 1(4):412–413, 1988.3216322
Bozzette, S.A.; Finkelstein, D.M.; Spector, S.A.; Frame, P.; Powderly, W.G.; He, W.; Phillips, L.; Craven, D.; van der Horst, C.; and Feinberg, J. A randomized trial of three antipneumocystis agents in patients with advanced human immunodeficiency virus infection. New England Journal of Medicine 332(11):693–699, 1995.7854375
Bradford, J., and Ryan, C. “National Lesbian Health Care Survey: Mental Health Implications.” Washington, DC: National Lesbian and Gay Health Foundation, 1987.
Bradley-Springer, L.A. The complex realities of primary prevention for HIV infection in a “just do it” world. Nursing Clinics of North America 34(1):49–70, 1999.9922279
Branson, B.M. Home sample collection tests for HIV infection. JAMA 280(19):1699–1701, 1998.9832003
Breitbart, W. Suicide risk and pain in cancer and AIDS patients. In: Chapman, C.R., and Foley, K.M., eds. Current and Emerging Issues in Cancer Pain: Research and Practice. New York: Raven Press, 1993. pp. 49–65.
Breitbart, W.; Passik, S.; Bronaugh, T.; Zale, C.; Bluestine, S.; Gomez, M.; Galer, B.; and Portney, R. Pain in the ambulatory AIDS patient: Prevalence and psychosocial correlates. Proceedings of the 38th Annual Meeting, Academy of Psychosomatic Medicine, Atlanta, GA, October 17–20, 1991.
Brindis, C.; Pfeffer, R.; and Wolfe, A. A case management program for chemically dependent clients with multiple needs. Journal of Case Management 4(1):22–28, 1995.7795539
Brindis, C., and Theidon, K.S. The role of case management in substance abuse treatment services for women and their children. Journal of Psychoactive Drugs 29(1):79–88, 1997.9110268
Broers, B.; Morabia, A.; and Hirschel, B. A cohort study of drug abusers' compliance with zidovudine treatment. Archives of Internal Medicine 154(10):1121–1127, 1994.8185425
Brooner, R.; Kidorf, M.; King, V.; Beilenson, P.; Svikis, D.; and Vlahov, D. Reduced drug use in needle exchange participants. International Conference on AIDS 12:671 (Abstract No. 33408), 1998.
Buckingham, S.L., and Van Gorp, W.G. HIV-associated dementia: A clinician's guide to early detection, diagnosis, and intervention. Families in Society: The Journal of Contemporary Human Services 75(6):333–345, 1994.
Bux, D.A.; Iguchi, M.Y.; Lidz, V.; Baxter, R.C.; and Platt, J.J. Participation in an outreach-based coupon distribution program for free methadone detoxification. Hospital and Community Psychiatry 44(11):1066–1072, 1993.8288175
Cabaj, R.P. Homosexuality and neurosis: Considerations for psychotherapy. Journal of Homosexuality 15(1–2):13–23, 1988.3403978
Cabaj, R.P. AIDS and chemical dependency: Special issues and treatment barriers for gay and bisexual men. Journal of Psychoactive Drugs 21(4):387–393, 1989.2621509
Cabaj, R.P. Substance abuse in gay men, lesbians, and bisexual individuals. In: Cabaj, R.P., and Stein, T.S., eds. Textbook of Homosexuality and Mental Health. Washington, DC: American Psychiatric Press, 1996. pp. 783–799.
Cabaj, R.P. Gays, lesbians, and bisexuals. In: Lowinson, J.H.; Ruiz, P.; Millman, R.B.; and Langrod, J.G., eds. Substance Abuse: A Comprehensive Textbook, 3rd ed. Baltimore, MD: Williams & Wilkins, 1997. pp. 725–733.
Cabaj, R.P., and Stein, T.S., eds. Textbook of Homosexuality and Mental Health. Washington, DC: American Psychiatric Press, 1996.
California Department of Corrections. What percentage of the California correctional population has a history of substance abuse? California Correctional Statistics, CCS 1–98, July 1998.
Calsyn, D.A.; Saxon, A.J.; Freeman, Jr., G.; and Whittaker, S. Ineffectiveness of AIDS education and HIV antibody testing in reducing high-risk behaviors among injection drug users. American Journal of Public Health 82:573–575, 1992.1546776
Calzavara, L.M.; Coates, R.A.; Raboud, J.M.; Farewell, V.T.; Read, S.E.; Shephered, F.A.; Fanning, M.M.; and MacFadden, D. Ongoing high-risk sexual behaviors in relation to recreational drug use in sexual encounters. Analysis of 5 years of data from the Toronto Sexual Contact Study. Annals of Epidemiology 3(3):272–280, 1993.8275200
Cameron, D.W.; Heath-Chiozzi, M.; Danner, S.; Cohen, C.; Kravcik, S.; Maurath, C.; Sun, E.; Henry, D.; Rode, R.; Potthoff, A.; and Leonard, J. Randomised, placebo-controlled trial of ritonavir in advanced HIV-1 disease. Lancet 351(9102):543–549, 1998.9492772
Cameron, D.W.; Pavon, J.; Rodriguez de Castro, F.; Diaz, F.; Julia, G.; Cayla, J.; and Cabrera, P. “Prolongation of life and prevention of AIDS complications in advanced HIV immunodeficiency with ritonavir.” Eleventh International Conference on AIDS, Vancouver, Canada, July 7–12, 1996.
Cameron, D.W.; Simonsen, J.N.; D'Costa, L.J.; Ronald, A.R.; Maitha, G.M.; Gakinya, M.N.; Cheang, M.; Ndinya-Achola, J.O.; Piot, P.; and Brunham, R.C. Female to male transmission of human immunodeficiency virus type 1: Risk factors for seroconversion in men. Lancet 2(8660):403–407, 1989.2569597
Carpenter, C.C.; Fischl, M.A.; Hammer, S.M.; Hirsch, M.S.; Jacobsen, D.M.; Katzenstein, D.A.; Montaner, J.S.; Richman, D.D.; Saag, M.S.; Schooley, R.T.; Thompson, M.A.; Vella, S.; Yeni, P.G.; and Volberding, P.A. Antiretroviral therapy for HIV infection in 1996. Recommendations of an international panel. JAMA 276(2):146–154, 1996.8656507
Carpenter, C.C.; Fischl, M.A.; Hammer, S.G.; Hirsch, M.S.; Jacobsen, D.M.; Katzenstein, D.A.; Montaner, J.S.; Richman, D.D.; Saag, M.S.; Schooley, R.T.; Thompson, M.A.; Vella, S.; Yeni, P.G.; and Volberding, P.A. Antiretroviral therapy for HIV-infection in 1997. Updated recommendations of the International AIDS Society-USA Panel. JAMA 277(24):1962–1969, 1997.9200638
Carpenter, C.C.; Fischl, M.A.; Hammer, S.M.; Hirsch, M.S.; Jacobsen, D.M.; Katzenstein, D.A.; Montaner, J.S.; Richman, D.D.; Saag, M.S.; Schooley, R.T.; Thompson, M.A.; Vella, S.; Yeni, P.G.; and Volberding, P.A. Antiretroviral therapy for HIV infection in 1998: Updated recommendations of the International AIDS Society-USA Panel. JAMA 280(1):78–86, 1998.9660368
Carroll, J. The negative attitudes of some general nurses towards drug misusers. Nursing Standard 9(34):36–38, 1995.
Casadonte, P.P.; Des Jarlais, D.C.; Friedman, S.R.; and Rotrosen, J.P. Psychological and behavioral impact among intravenous drug abusers of learning HIV test results. International Journal of the Addictions 25:409–426, 1990.2246090
Castro, K.G.; Ward, J.W.; Slutsker, L.; Buehler, J.W.; Jaffe, H.W.; and Berkelman, R.L. 1993 Revised Classification System for HIV Infection and Expanded Surveillance Case Definition for AIDS Among Adolescents and Adults. Morbidity and Mortality Weekly Report 41, December 18, 1992.
Center for AIDS Prevention Studies. What Are Women's HIV Prevention Needs? Fact Sheet #4Er, 1998.
Center for Substance Abuse Treatment. Assessment and Treatment of Patients With Coexisting Mental Illness and Alcohol and Other Drug Abuse. Treatment Improvement Protocol (TIP) Series, Number 9. HHS Pub. No. (SMA) 94–2078. Washington, DC: U.S. Government Printing Office, 1994a.
Center for Substance Abuse Treatment. Treatment for Alcohol and Other Drug Abuse: Opportunities for Collaboration. Technical Assistance Publication (TAP) Series, Number 11. HHS Pub. No. (SMA) 94–2075. Washington, DC: U.S. Government Printing Office, 1994b.
Center for Substance Abuse Treatment. Developing State Outcomes Monitoring Systems for Alcohol and Other Drug Abuse Treatment. Treatment Improvement Protocol (TIP) Series, Number 14. HHS Pub. No. (SMA) 95–3031. Washington, DC: U.S. Government Printing Office, 1995a.
Center for Substance Abuse Treatment. Treatment for HIV-Infected Alcohol and Other Drug Abusers. Treatment Improvement Protocol (TIP) Series, Number 15. HHS Pub. No. (SMA) 95–3038. Washington, DC: U.S. Government Printing Office, 1995b.
Center for Substance Abuse Treatment. Planning for Alcohol and Other Drug Abuse Treatment for Adults in the Criminal Justice System. Treatment Improvement Protocol (TIP) Series, Number 17. HHS Pub. No. (SMA) 95–3039. Washington, DC: U.S. Government Printing Office, 1995c.
Center for Substance Abuse Treatment. The Tuberculosis Epidemic: Legal and Ethical Issues for Alcohol and Other Drug Abuse Treatment Providers. Treatment Improvement Protocol (TIP) Series, Number 18. HHS Pub. No. (SMA) 95–3047. Washington, DC: U.S. Government Printing Office, 1995d.
Center for Substance Abuse Treatment. Detoxification From Alcohol and Other Drugs. Treatment Improvement Protocol (TIP) Series, Number 19. HHS Pub. No. (SMA) 95–3046. Washington, DC: U.S. Government Printing Office, 1995e.
Center for Substance Abuse Treatment. Matching Treatment to Patient Needs in Opioid Substitution Therapy. Treatment Improvement Protocol (TIP) Series, Number 20. HHS Pub. No. (SMA) 95–3049. Washington, DC: U.S. Government Printing Office, 1995f.
Center for Substance Abuse Treatment. LAAM in the Treatment of Opiate Addiction. Treatment Improvement Protocol (TIP) Series, Number 22. HHS Pub. No. (SMA) 95–3052. Washington, DC: U.S. Government Printing Office, 1995g.
Center for Substance Abuse Treatment. Treatment Drug Courts: Integrating Substance Abuse Treatment With Legal Case Processing. Treatment Improvement Protocol (TIP) Series, Number 23. HHS Pub. No. (SMA) 96–3113. Washington, DC: U.S. Government Printing Office, 1996.
Center for Substance Abuse Treatment. A Guide to Substance Abuse Services for Primary Care Clinicians. Treatment Improvement Protocol (TIP) Series, Number 24. HHS Pub. No. (SMA) 97–3139. Washington, DC: U.S. Government Printing Office, 1997.
Center for Substance Abuse Treatment. Substance Abuse Among Older Adults. Treatment Improvement Protocol (TIP) Series, Number 26. HHS Pub. No. (SMA) 98–3179. Washington, DC: U.S. Government Printing Office, 1998a.
Center for Substance Abuse Treatment. Comprehensive Case Management for Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series, Number 27. HHS Pub. No. (SMA) 98–3222. Washington, DC: U.S. Government Printing Office, 1998b.
Center for Substance Abuse Treatment. Substance Use Disorder Treatment for People With Physical and Cognitive Disabilities. Treatment Improvement Protocol (TIP) Series, Number 29. HHS Pub. No. (SMA) 98–3249. Washington, DC: U.S. Government Printing Office, 1998c.
Center for Substance Abuse Treatment. Continuity of Offender Treatment for Substance Use Disorders From Institution to Community. Treatment Improvement Protocol (TIP) Series, Number 30. HHS Pub. No. (SMA) 98–3245. Washington, DC: U.S. Government Printing Office, 1998d.
Center for Substance Abuse Treatment. Screening and Assessing Adolescents for Substance Use Disorders. Treatment Improvement Protocol (TIP) Series, Number 31. HHS Pub. No. (SMA) 99–3282. Washington, DC: U.S. Government Printing Office, 1999a.
Center for Substance Abuse Treatment. Treatment of Adolescents With Substance Use Disorders. Treatment Improvement Protocol (TIP) Series, Number 32. HHS Pub. No. (SMA) 99–3283. Washington, DC: U.S. Government Printing Office, 1999b.
Center for Substance Abuse Treatment. Brief Interventions and Brief Therapies for Substance Abuse. Treatment Improvement Protocol (TIP) Series, Number 34. HHS Pub. No. (SMA) 99–3353. Washington, DC: U.S. Government Printing Office, 1999c.
Center for Substance Abuse Treatment. Enhancing Motivation for Change in Substance Abuse Treatment. Treatment Improvement Protocol (TIP) Series, Number 35. HHS Pub. No. (SMA) 99–3354. Washington, DC: U.S. Government Printing Office, 1999d.
Center for Substance Abuse Treatment. Cultural Issues in Substance Abuse Treatment. HHS Pub. No. (SMA) 99–3278. Washington, DC: U.S. Government Printing Office, 1999e.
Center for Substance Abuse Treatment. Substance Abuse Treatment for Persons With Child Abuse and Neglect Issues. Treatment Improvement Protocol (TIP) Series, Number 36. HHS Pub. No. (SMA) 00–3357. Washington, DC: U.S. Government Printing Office, 2000.
Center for Substance Abuse Treatment. Integrating Substance Abuse Treatment and Vocational Services. Treatment Improvement Protocol (TIP) Series, Number 38. Washington, DC: U.S. Government Printing Office, in press (a).
Center for Substance Abuse Treatment. Gay, Lesbian, Bisexual, and Transgender Populations. Technical Assistance Publication (TAP) Series. Washington, DC: U.S. Government Printing Office, in press (b).
Centers for Disease Control and Prevention. Pneumocystis pneumonia—Los Angeles. Morbidity and Mortality Weekly Report 30(21):250–252, 1981.6265753
Centers for Disease Control and Prevention. Unexplained immunodeficiency and opportunistic infections in infants—New York, New Jersey, California. Morbidity and Mortality Weekly Report 31(49):665–667, 1982.
Centers for Disease Control and Prevention. Antibody to human immunodeficiency virus in female prostitutes. Morbidity and Mortality Weekly Report 36(11):157–161, 1987a.3102921
Centers for Disease Control and Prevention. Recommendations for prevention of HIV transmission in health-care settings. Morbidity and Mortality Weekly Report 36(Suppl. 2S):1S–18S, 1987b.
Centers for Disease Control and Prevention. Update: Reducing HIV transmission in intravenous-drug users not in drug treatment in the United States. Morbidity and Mortality Weekly Report 39(31):529, 536–538, 1990.2115973
Centers for Disease Control and Prevention. 1993 Revised Classification System for HIV Infection and Expanded Surveillance Case Definition for AIDS Among Adolescents and Adults. Morbidity and Mortality Weekly Report 41(51):961–962, 1992.
Centers for Disease Control and Prevention. Technical guidance on HIV counseling. Morbidity and Mortality Weekly Report 42(RR-2):11–17, 1993.
Centers for Disease Control and Prevention. Recommendations of the U.S. Public Health Service Task Force on the use of zidovudine to reduce perinatal transmission of human immunodeficiency virus. Morbidity and Mortality Weekly Report 43(RR-11):1–20, 1994.
Centers for Disease Control and Prevention. U.S. Public Health Service recommendations for human immunodeficiency virus counseling and voluntary testing for pregnant women. Morbidity and Mortality Weekly Report 44(RR-7):1–15, 1995.7799912
Centers for Disease Control and Prevention. HIV/AIDS education and prevention programs for adults in prisons and jails and juveniles in confinement facilities—United States, 1994. Morbidity and Mortality Weekly Report 45(13):268–271, 1996a.8596527
Centers for Disease Control and Prevention. HIV/AIDS Surveillance Report 8(2), 1996b.
Centers for Disease Control and Prevention. Provisional public health service recommendations for chemoprophylaxis after occupational exposure to HIV. Morbidity and Mortality Weekly Report 45(22):468–472, 1996c.8622618
Centers for Disease Control and Prevention. 1997 USPHS/IDSA guidelines for the prevention of opportunistic infections in persons infected with human immunodeficiency virus: A summary. Morbidity and Mortality Weekly Report 46(RR-12):1–45, 1997a.9011775
Centers for Disease Control and Prevention. HIV/AIDS and women who have sex with women (WSW) in the United States. CDC Facts, July 1997b.
Centers for Disease Control and Prevention. HIV/AIDS Surveillance Report 9(2), 1997c.
Centers for Disease Control and Prevention. 1998 guidelines for treatment of sexually transmitted diseases. Morbidity and Mortality Weekly Report 47(RR-1):1–118, 1998a.9450721
Centers for Disease Control and Prevention. Assessing Health Risk Behaviors Among Young People: Youth Risk Behavior Surveillance System, 1998b.
Centers for Disease Control and Prevention. Basic Statistics—Ten States/Territories and Cities Reporting Highest Number of AIDS
Centers for Disease Control and Prevention. HIV/AIDS Surveillance Report: U.S. HIV and AIDS Cases Reported Through June 1998 10(1), 1998d.
Centers for Disease Control and Prevention. HIV/AIDS Surveillance Report: U.S. HIV and AIDS Cases Reported Through December 1998 10(2), 1998e.
Centers for Disease Control and Prevention. Prevention and treatment of sexually transmitted diseases as an HIV prevention strategy. CDC Update, June 1998f.
Centers for Disease Control and Prevention. Public health service guidelines for the management of health-care worker exposures to HIV and recommendations for postexposure prophylaxis. Morbidity and Mortality Weekly Report 47(RR-7):1–28, 1998g 9450721
Centers for Disease Control and Prevention. Public Health Service Task Force recommendations for the use of antiretroviral drugs in pregnant women infected with HIV-1 for maternal health and for reducing perinatal HIV-1 transmission in the United States. Morbidity and Mortality Weekly Report 47(RR-2):1–30, 1998h.9450721
Centers for Disease Control and Prevention. Rapid HIV Tests: Questions/Answers. March 1998i.
Centers for Disease Control and Prevention. Report of the NIH panel to define principles of therapy of HIV infection. Morbidity and Mortality Weekly Report 47(RR-5):1–41, 1998j.9450721
Centers for Disease Control and Prevention. The HIV/AIDS Epidemic in the United States, 1997–1998, 1999a.
Centers for Disease Control and Prevention. HIV/AIDS Surveillance Report: U.S. HIV and AIDS Cases Reported Through June 1999 11(1), 1999b.
Centers for Disease Control and Prevention. HIV/AIDS Surveillance Supplemental Report Atlanta, GA: Centers for Disease Control and Prevention, 1999c.
Centers for Disease Control and Prevention. Preventing occupational HIV transmission to health care workers. 1999d.
Centers for Disease Control and Prevention. Young people at risk—epidemic shifts further toward young women and minorities. 1999e.
Centers for Disease Control and Prevention, Center for Substance Abuse Treatment, National Institute on Drug Abuse. HIV/AIDS Prevention Bulletin. Rockville, MD: April 19, 1993.
Centers for Disease Control and Prevention. National Center for Health Statistics. Births and deaths: Preliminary data for 1998. National Vital Statistics Reports 47(25), 1999f.
Chaisson, R.E.; Stanton, D.L.; Gallant, J.E.; Rucker, S.; Bartlett, J.G.; and Moore, R.D. Impact of the 1993 revision of the AIDS case definition on the prevalence of AIDS in a clinical setting. AIDS 7:857–862, 1993.8103343
Chandra, P.S.; Ravi, V.; Desai, A.; and Subbakrishna, D.K. Anxiety and depression among HIV-infected heterosexuals—a report from India. Journal of Psychosomatic Research 45(5):401–409, 1998.9835233
Chatham, L.R.; Rowan-Szal, G.A.; Joe, G.W.; Brown, B.S.; and Simpson, D.D. Heavy drinking in a population of methadone-maintained clients. Journal of Studies on Alcohol 56:417–422, 1995.7674677
Chen, Z.; Branson, B.; Ballenger, A.; and Peterman, T.A. Risk assessment to improve targeting of HIV counseling and testing services for STD clinic patients. Sexually Transmitted Diseases 25(10):539–543, 1998.9858350
Chin, D.P.; Osmond, D.; Page-Shafer, K.; Glassroth, J.; Rosen, M.J.; Reichman, L.B.; Kvale, P.A.; Wallace, J.M.; Poole, W.K.; and Hopewell, P.C. Reliability of anergy skin-testing in persons with HIV infection. American Journal of Respiratory and Critical Care Medicine 153(6 pt. 1):1982–1984, 1996.8665065
Clark, S.J.; Saag, M.S.; Decker, W.D.; Campbell-Hill, S.; Roberson, J.L.; Veldkamp, P.J.; Kappes, J.C.; Hahn, B.H.; and Shaw, G.M. High titers of cytopathic virus in plasma of patients with symptomatic primary HIV-1 infection. New England Journal of Medicine 324:954–960, 1991.1900576
Clayman, C.B., ed. The American Medical Association Encyclopedia of Medicine. New York: Random House, 1989.
Clements, K.; Gleghorn, A.; Garcia, D.; Katz, M.; and Marx, R. A risk profile of street youth in northern California: Implications for gender-specific human immunodeficiency virus prevention. Journal of Adolescent Health 20(5):343–353, 1997.
Clements, K.; Marx, B.; Guzman, R.; Ikeda, S.; and Katz, M. Prevalence of HIV infection in transgendered individuals in San Francisco. The International Conference on AIDS 12:449 (Abstract No. 23536), 1998.
Cochran, S.D., and Mays, V.M. Relation between psychiatric syndromes and behaviorally defined sexual orientation in a sample of the U.S. population. American Journal of Epidemiology 151(5):516–523, 2000.10707921
Cockrell, J.R., and Folstein, M.F. Mini Mental State Examination (MMSE). Psychopharmacology Bulletin 24:689–692, 1988.3249771
Coffin, J.A. “HIV and viral dynamics.” Plenary address presented at the Eleventh International Conference on AIDS, Vancouver, Canada, July 12, 1996.
Cohen, M.S.; Hoffman, I.F.; Royce, R.A.; Kazembe, P.; Dyer, J.R.; Daly, C.C.; Zimba, D.; Vernazza, P.L.; Maida, M.; Fiscus, S.A.; and Eron, Jr., J.J. Reduction of concentration of HIV-1 in semen after treatment of urethritis: Implications for prevention of sexual transmission of HIV-1. Lancet 349:1868–1873, 1997.9217758
Colon, H.M.; Robles, R.R.; Marrero, C.A.; Matos, T.D.; Lopez, C.M.; and Orraca, O. Reduction in sexual risk behaviors among HIV seropositve drug abusers in Puerto Rico. International Conference on AIDS 11(2):146 (Abstract No. We.C. 3512) 1996.
Condelli, W.S.; Fairbank, J.A.; Dennis, M.L.; and Rachal, J.V. Cocaine use by clients in methadone programs: Significance, scope, and behavioral interventions. Journal of Substance Abuse Treatment 8:203–212, 1991.1787544
Conley, L.J.; Bush, T.J.; Buchbinder, S.P.; Penley, K.A.; Judson, F.N.; and Holmberg, S.D. The association between cigarette smoking and selected HIV-related medical conditions. AIDS 10:1121–1126, 1996.8874629
Cooper, J.R. Methadone treatment and acquired immunodeficiency syndrome. JAMA 262:1664–1668, 1989.2491420
Cornelius, J.R.; Salloum, I.M.; Ehler, J.G.; Jarrett, P.J.; Cornelius, M.D.; Black, A.; Perel, J.M.; and Thase, M.E. Double-blind fluoxetine in depressed alcoholic smokers. Psychopharmacology Bulletin 33:165–170, 1997.9133770
Cornelius, J.R.; Salloum, I.M.; Thase, M.E.; Haskett, R.F.; Daley, D.C.; Jones-Barlock, A.; Upsher, C.; and Perel, J.M. Fluoxetine versus placebo in depressed alcoholic cocaine abusers. Psychopharmacology Bulletin 34:117–121, 1998.9564208
Cottler, L.B.; Compton, W.M.; Ben Abdallah, A.; Cunningham-Williams, R.; Abram, F.; Fitchenbaum, C.; and Dotson, W. Peer-delivered interventions reduce HIV risk behaviors among out-of-treatment drug abusers. Public Health Reports 113(Suppl. 1):31–41, 1998.9722808
Cox, G.B.; Meijer, L.; Carr, D.I.; and Freng, S.A. Systems alliance and support (SAS): A program of intensive case management for chronic public inebriates. Alcohol Treatment Quarterly 10(3/4):125–138, 1993.
Cox, J.M. Justice, compassion needed in treating AIDS patients. Health Program 67(4):34–37, 1986.
Crespi, T.D., and Sabatelli, R.M. Adolescent runaways and family strife: A conflict-induced differentiation framework. Adolescence 28(112):867–878, 1993.8266840
Croop, R.S.; Faulkner, E.B.; Labriola, D.F.; and the Naltrexone Usage Study Group. The safety profile of naltrexone in the treatment of alcoholism. Results from a multicenter usage study. Archives of General Psychiatry 54:1130–1135, 1997.9400350
Cross, T.; Bazron, B.; Dennis, K.; and Isaacs, M. Towards a Culturally Competent System of Care: A Monograph on Effective Services for Minority Children Who Are Severely Emotionally Disturbed. Washington, DC: Child and Adolescent Service System Program, Technical Assistance Center, Georgetown University Child Development Center, 1989.
Culnane, M.; Fowler, M.G.; Lee, S.S.; McSherry, G.; Brady, M.; O'Donnell, K.; Mofenson, L.; Gortmaker, S.L.; Shapiro, D.E.; Scott, G.; Jimenez, E.; Moore, E.C.; Diaz, C.; Flynn, P.M.; Cunningham, B.; and Oleske, J. Lack of long-term effects of in utero exposure to zidovudine among uninfected children born to HIV-infected women. JAMA 281:151–157, 1999.9917118
Deeks, S.G.; Loftus, R.; Cohen, P.; Chin, S.; and Grant, R. Incidence and predictors of virologic failure of indinavir and/or ritonavir in an urban health clinic. Program and Abstracts of the 37th Interscience Conference on Antimicrobial Agents and Chemotherapy (ICAAC). Abstract No. LB-02. Toronto, Canada, September 28-October 1, 1997.
Deeks, S.G.; Smith, M.; Holodniy, M.; and Kahn, J.O. HIV-1 protease inhibitors. A review for clinicians. JAMA 277:145–153, 1997.8990341
DeHovitz, J.A.; Kelly, P.; Feldman, J.; Sierra, M.F.; Clarke, L.; Bromberg, J.; Wan, J.Y.; Vermund, S.H.; and Landesman, S. Sexually transmitted diseases, sexual behavior, and cocaine use in inner-city women. American Journal of Epidemiology 140(12):1125–1134, 1994.7998594
de Monteflores, C. Notes on the management of difference. In: Stein, T.S., and Cohen, C.C., eds. Contemporary Perspectives on Psychotherapy With Lesbians and Gay Men. New York: Plenum Press, 1986.
Dennis, M.L.; Ingram, P.W.; Burks, M.E.; and Rachal, J.V. Effectiveness of streamlined admissions to methadone treatment: A simplified time-series analysis. Journal of Psychoactive Drugs 26:207–216, 1994.7931865
Dennison, R. Should I have a baby? It may be the most important decision you'll ever make. W.O.R.L.D. Newsletter, April 1998.
Des Jarlais, D.C.; Hagan, H.; Friedman, S.R.; Friedmann, P.; Goldberg, D.; Frischer, M.; Green, S.; Tunving, K.; Ljungberg, B.; and Wodak, A. Maintaining low HIV seroprevalence in populations of injecting drug users. JAMA 274:1226–1231, 1995.7563513
Des Jarlais, D.C.; Marmor, M.; Paone, D.; Titus, S.; Shi, Q.; Perlis, T.; Jose, B.; and Friedman, S.R. HIV incidence among injecting drug users in New York City syringe-exchange programs. Lancet 348:987–991, 1996.8855855
Des Jarlais, D.C.; Wenston, J.; Friedman, S.R.; Sotheran, J.L.; Maslansky, R.; and Marmor, M. Crack cocaine use in a cohort of methadone maintenance patients. Journal of Substance Abuse Treatment 9:319–325, 1992.1479629
Diamond, D.L., and Wilsnack, S.C. Alcohol abuse among lesbians: A descriptive study. Journal of Homosexuality 4(2):123–142, 1978.739144
Diaz, R.M.; Stall, R.D.; Hoff, C.; Daigle, D.; and Coates, T.J. HIV risk among Latino gay men in the southwestern United States. AIDS Education and Prevention 8(5):415–429, 1996.8911569
Diaz, T.; Buehler, J.W.; Castro, K.G.; and Ward, J.W. AIDS trends among Latinos in the United States. American Journal of Public Health 83:504–509, 1993.8384802
Diaz, T., and Klevens, M. Differences by ancestry in sociodemographics and risk behaviors among Hispanics with AIDS. The Supplement to HIV and AIDS Surveillance Project Group. Ethnicity and Disease 7(3):200–206, 1997.9467702
Dieterich, D.T. Advances in the pathophysiology and treatment of HIV-associated wasting. Improving the Management of HIV Disease 4(5), 1997.
Dixon, P.S.; Flanigan, T.P.; DeBuono, B.A.; Laurie, J.J.; De Ciantis, M.L.; Hoy, J.; Stein, M.; Scott, H.D.; and Carpenter, C.C. Infection with the human immunodeficiency virus in prisoners: Meeting the health care challenge. American Journal of Medicine 95(6):629–635, 1993.8259780
Dole, V.P.; Nyswander, M.E.; and Kreek, M.J. Narcotic blockade. Archives of Internal Medicine 118:304–309, 1966.4162686
Doyle, A.; Jefferys, R.; and Kelly, J. National ADAP Monitoring Project: Interim Technical Report. March 1998.
Drake, R.E., and Noordsy, D.L. Case management for people with coexisting severe mental disorder and substance abuse. Psychiatric Annals 24(8):427–431, 1994.
Edlin, B.R.; Irwin, K.L.; Faruque, S.; McCoy, C.B.; Word, C.; Serrano, Y.; Inciardi, J.A.; Bowser, B.P.; Schilling, R.F.; and Holmberg, S.D. Intersecting epidemics—crack cocaine use and HIV infection among inner-city adults. New England Journal of Medicine 331:1422–1427, 1994.7969281
Edsall, J.R.; Awe, R.J.; Bunyan, S.B.; Hackney, Jr., R.L.; Iseman, M.D.; and Reagan, W.P. Treatment of tuberculosis in alcoholic patients. American Review of Respiratory Disease 116(3):559–561, 1977.409319
El-Bassel, N.; Gilbert, L.; Krishnan, S.; Schilling, R.; Gaeta, T.; Purpura, S.; and Witte, S.S. Partner violence and sexual HIV-risk behaviors among women in an inner-city emergency department. Violence and Victims 13(4):377–393, 1998.10328445
El-Bassel, N., and Schilling, R.F. 15-month followup of women methadone patients taught skills to reduce heterosexual HIV transmission. Public Health Reports 107(5):500–504, 1992.1410230
Elifson, K.W.; Boles, J.; and Sweat, M. Risk factors associated with HIV infection among male prostitutes. American Journal of Public Health 83:79–83, 1993.8417612
Esteban, J.I.; Esteban, R.; Viladomiu, L.; Lopez-Talavera, J.C.; Gonzalez, A.; Hernandez, J.M.; Roget, M.; Vargas, V.; Genesca, J.; and Buti, M., et al. Hepatitis C virus antibodies among risk groups in Spain. Lancet 2(8658):294–297, 1989.2569102
European Mode of Delivery Collaboration. Elective caesarean-section versus vaginal delivery in prevention of vertical HIV-1 transmission: A randomised clinical trial. Lancet 353(9158):1035–1039, 1999.10199349
European Study Group on Heterosexual Transmission of HIV. Comparison of female to male and male to female transmission of HIV in 563 stable couples. British Medical Journal 304:809–813, 1992.1392708
Fairfield, K.M.; Eisenberg, D.M.; Davis, R.B.; Libman, H.; and Phillips, R.S. Patterns of use, expenditures, and perceived efficacy of complementary and alternative therapies in HIV-infected patients. Archives of Internal Medicine 158:2257–2264, 1998.9818806
Federal Rehabilitation Act. 29 U.S.C. §791 et seq., 1973.
Fernandez, F. Psychopharmacological interventions in HIV infections. New Directions in Mental Health Services 48:43–53, 1990.
Ferrando, S.J., and Batki, S.L. HIV infection: From dual to triple diagnosis. In: Kranzler, H.R., and Rounsaville, B.J., eds. Dual Diagnosis and Treatment. New York: Marcel Dekker, 1998. pp. 503–534.
Ferrando, S.J.; Wall, T.L.; Batki, S.L.; and Sorensen, J.L. Psychiatric morbidity, illicit drug use and adherence to zidovudine (AZT) among injection drug users with HIV disease. American Journal of Drug and Alcohol Abuse 22(4): 475–487, 1996.8911586
Festinger, D.S.; Lamb, R.J.; Kirby, K.C.; and Marlowe, D.B. The accelerated intake: A method for increasing initial attendance to outpatient cocaine treatment. Journal of Applied Behavior Analysis 29:387–389, 1996.8810062
Fifield, L.; De Crescenzo, T.A.; and Latham, J.D. Alcoholism and the Gay Community. Los Angeles: Los Angeles Gay Community Services Center, 1975.
Figley, C.R. Compassion Fatigue: Coping With Secondary Traumatic Stress Disorder in Those Who Treat the Traumatized. New York: Brunner/Mazel, 1995.
Finnegan, D.G., and McNally, E.B. Dual Identities: Counseling Chemically Dependent Gay Men and Lesbians. Center City, MN: Hazelden, 1987.
Folkers, G. IL-2 plus HAART sharply reduces HIV in hiding places. UniSci Science and Research News, November 16, 1998.
Folstein, M.F.; Folstein, S.E.; and McHugh, P.R. “Mini Mental State”: A practical method for grading the cognitive state of patients for the clinician. Journal of Psychiatric Research 12:196–198, 1975.
Forstein, M. The neuropsychiatric aspects of HIV infection. Primary Care 19(1):97–117, 1992.1594705
Freedberg, K.A.; Malabanan, A.; Samet, J.H.; and Libman, H. Initial assessment of patients infected with human immunodeficiency virus: The yield and cost of laboratory testing. Journal of AIDS 7:1134–1140, 1994.
Friedman, S.R.; Jose, B.; Deren, S.; Des Jarlais, D.C.; and Neaigus, A. Risk factors for human immunodeficiency virus seroconversion among out-of-treatment drug injectors in high and low seroprevalence cities. American Journal of Epidemiology 142:864–874, 1995.7572963
Fudala, P.J.; Jaffe, J.H.; Dax, E.M.; and Johnson, R.E. Use of buprenorphine in the treatment of opioid addiction, II: Physiologic and behavioral effects of daily and alternate day administration and abrupt withdrawal. Clinical Pharmacology and Therapeutics 47:525–534, 1990.2328561
Fuentes, A. Naming names: Will the squabble over HIV reporting tear us apart? POZ March 1999.
Fultz, J.M., and Senay, E.C. Guidelines for the management of hospitalized narcotic addicts. Annals of Internal Medicine 82(6): 815–818, 1975.1138596
Gallo, R.C.; Sarin, P.S.; Gelmann, E.P.; Robert-Guroff, M.; Richardson, E.; Kalyanaraman, V.S.; Mann, D.; Sidhu, G.D.; Stahl, R.E.; Zolla-Pazner, S.; Leibowitch, J.; and Popovic, M. Isolation of human T-cell leukemia virus in acquired immune deficiency syndrome (AIDS). Science 220(4599):865–867, 1983.6601823
Gamble, V.N. Under the shadow of Tuskegee: African Americans and health care. American Journal of Public Health 87(11):1773–1778, 1997.9366634
Gao, F.; Bailes, E.; Robertson, D.L.; Chen, Y.; Rodenburg, C.M.; Michael, S.F.; Cummins, L.B.; Arthur, L.O.; Peeters, M.; Shaw, G.M.; Sharp, P.M.; and Hahn, B.H. Origin of HIV-1 in the chimpanzee Pan troglodytes troglodytes. Nature 397(6718):436–441, 1999.9989410
Gary, L.E. Attitudes toward human service organizations: Perspectives from an urban black community. Journal of Applied Behavior Science 21(4):445–458, 1985.
Gerbert, B.; Maguire, B.T.; Bleecker, T.; Coates, T.J.; and McPhee, S.J. Primary care physicians and AIDS: Attitudinal and structural barriers to care. JAMA 266:2837–2842, 1991.1942450
Gerstein, D.R., and Harwood, H.J., eds. Treating Drug Problems. Washington, DC: National Academy Press, 1990-1992.
Gervasoni, C.; Ridolfo, A.L.; Trifiro, G.; Santambrogio, S.; Norbiato, G.; Musicco, M.; Clerici, M.; Galli, M.; and Moroni, M. Redistribution of body fat in HIV-infected women undergoing combined antiretroviral therapy. AIDS 13(4):465–471, 1999.10197374
Glassroth, J.; Jordan, M.; Wallace, J.M.; Kvale, P.A.; Follmann, D.A.; Rosen, M.J.; Reichman, L.B.; Mossar, M.; and Hopewell, P.C. Use of preventive interventions by persons infected with type-1 human immunodeficiency virus (HIV-1). The Pulmonary Complications of HIV Study Group. American Journal of Preventive Medicine 10(5):259–266, 1994.7848668
Gold, M.S.; Redmond, Jr., D.E.; and Kleber, H.D. Clonidine blocks acute opioid-withdrawal symptoms. Lancet 2(8090):599–602, 1978.80526
Gómez, C.A., and Marín, B.V. Gender, culture and power: Barriers to HIV prevention strategies for women. Journal of Sex Research 33(4):355–362, 1996.
Gonsiorek, J.C., ed. A Guide to Psychotherapy With Gay and Lesbian Clients. New York: Harrington Park Press, 1985.
Gorman, E.M. Speed use and HIV transmission. Focus: A Guide to AIDS Research and Counseling 11(7):4–6, 1996.
Gorman, E.M.; Morgan, P.; and Lambert, E.Y. Qualitative research considerations and other issues in the study of methamphetamine use among men who have sex with other men. In: Lambert, E.Y.; Ashery, R.S.; and Needle, R.H., eds. Qualitative Methods in Drug Abuse and HIV Research. NIDA Research Monograph Series, Number 157. NIDA Pub. No. 95–4025. Rockville, MD: National Institute on Drug Abuse, 1995. pp. 156–181.
Gourevitch, M., and Friedland, G. Methadone and antiretroviral medications, part I. AIDS Clinical Care 1(4):30–31, 1999a.
Gourevitch, M., and Friedland, G. Methadone and antiretroviral medications, part II. AIDS Clinical Care 11(5):37–45, 1999b.11367102
Graham, K.; Timney, C.B.; Bois, C.; and Wedgerfield, K. Continuity of care in addictions treatment: The role of advocacy and coordination in case management. American Journal of Drug and Alcohol Abuse 21(4):433–451, 1995.8561096
Graham, N.M.; Zeger, S.L.; Park, L.P.; Vermund, S.H.; Detels, R.; Rinaldo, C.R.; and Phair, J.P. The effects on survival of early treatment of human immunodeficiency virus infection. New England Journal of Medicine 326(16):1037–1042, 1992.1347907
Greenblatt, R.M.; Lukehart, S.A.; Plummer, F.A.; Quinn, T.C.; Critchlow, C.W.; Ashley, R.L.; D'Costa, L.J.; Ndinya-Achola, J.O.; Corey, L.; and Ronald, A.R., et al. Genital ulceration as a risk factor for human immunodeficiency virus infection. AIDS 2(1):47–50, 1988.3128996
Grella, C.E.; Anglin, M.D.; and Wugalter, S.E. Cocaine and crack use and HIV risk behaviors among high-risk methadone maintenance clients. Drug and Alcohol Dependence 37:15–21, 1995.7882869
Griffin, M.M.; Ryan, J.G.; Briscoe, V.S.; and Shadle, K.M. Effects of incarceration on HIV-infected individuals. Journal of the National Medical Association 88(10):639–644, 1996.8918068
Haas, D.W.; Morgan, M.E.; and Harris, V.L. Increased viral load and suicidal ideation in an HIV-infected patient. Annals of Internal Medicine 126(1):86–87, 1997.
Hagan, H.; Des Jarlais, D.C.; Purchase, D.; Reid, T.; and Friedman, S.R. The Tacoma syringe exchange. Journal of Addictive Diseases 10:81–88, 1991.
Hall, J.M. Lesbians and alcohol: Patterns and paradoxes in medical notions and lesbians' beliefs. Journal of Psychoactive Drugs 25(2):109–119, 1993.8377078
Hammer, S.M.; Katzenstein, D.A.; Hughes, M.D.; Gundacker, H.; Schooley, R.T.; Haubrich, R.H.; Henry, W.K.; Lederman, M.M.; Phair, J.P.; Niu, M.; Hirsch, M.S.; and Merigan, T.C. A trial comparing nucleoside monotherapy with combination therapy in HIV-infected adults with CD4 cell counts from 200 to 500 per cubic millimeter. AIDS Clinical Trials Group Study 175 Study Team. New England Journal of Medicine 335:1081–1090, 1996.8813038
Hardy, W.D.; Feinberg, J.; Finklestein, D.M.; Power, M.E.; He, W.; Kaczka, C.; Frame, P.T.; Holmes, M.; Waskin, H.; Fass, R.J.; and the AIDS Clinical Trials Group Protocol 021. A controlled trial of trimethoprim-sulfamethoxazole or aerosolized pentamidine for secondary prophylaxis of Pneumocystis carinii pneumonia in patients with acquired immunodeficiency syndrome.. New England Journal of Medicine 327:1842–1848, 1992.1448121
Hartgers, C.; van den Hoek, A.; Krijnen, P.; and Coutinho, R.A. HIV prevalence and risk behavior among injecting drug abusers who participate in “low threshold” methadone programs in Amsterdam. American Journal of Public Health 82:547–551, 1992.1312311
Hayter, M. Burnout and AIDS care-related factors in HIV community clinical nurse specialists in the North of England. Journal of Advanced Nursing 29(4):984–993, 1999.10215992
Heather, N. Brief intervention strategies. In: Hester, R.K., and Miller, W.R., eds. Handbook of Alcoholism Treatment Approaches: Effective Alternatives, 2nd ed. Allyn & Bacon, 1995. pp. 105–120.
Hecht, F.M.; Colfax, G.; Swanson, M.; and Chesney, M.A. “Adherence and effectiveness of protease inhibitors in clinical practice.” Paper presented at the fifth Conference on Retroviruses and Opportunistic Infections, Chicago, IL, 1998a.
Hecht, F.M.; Grant, R.M.; Petropoulos, C.J.; Dillon, B.; Chesney, M.A.; Tian, H.; Hellmann, N.S.; Bandrapalli, N.I.; Digilio, L.; Branson, B.; and Kahn, J.O. Sexual transmission of an HIV-1 variant resistant to multiple reverse-transcriptase and protease inhibitors. New England Journal of Medicine 339(5):307–311, 1998b.9682043
Heimer, R. Can syringe exchange serve as a conduit to drug treatment? Journal of Substance Abuse Treatment 15:183–191, 1998.9633030
Henry, J.A., and Hill, I.R. Fatal interaction between ritonavir and MDMA. Lancet 352(9142):1751–1752, 1998.
Herek, G.M. Heterosexism and homophobia. In: Cabaj, R.P., and Stein, T.S., eds. Textbook of Homosexuality and Mental Health: A Comprehensive Review. Washington, DC: American Psychiatric Press, 1996. pp. 101–113.
Herz, A. Endogenous opioid systems and alcohol addiction. Psychopharmacology (Berl) 129:99–111, 1997.9040115
Higgins, D.L.; Galavotti, C.; O'Reilly, K.R.; Schnell, D.J.; Moore, M.; Rugg, D.L.; and Johnson, R. Evidence for the effects of HIV antibody counseling and testing on risk behaviors. JAMA 266:2419–2429, 1991.1920748
Ho, D.D. Time to hit HIV, early and hard. New England Journal of Medicine 333:450–451, 1995.7616996
Hodgson, I. HIV and combination therapy: Meeting the challenge of a new era. British Journal of Nursing 8(1):39–43, 1999.10085812
Holmberg, S.D. The estimated prevalence and incidence of HIV in 96 large U.S. metropolitan areas. American Journal of Public Health 86:642–654, 1996.8629714
Horn, G. Party favors—Do yourself one: Get the dope on the protease effect. POZ June 1998.
Huba, G.J., and Melchior, L.A. Evaluation of the Effects of Ryan White Title I Funding on Services for HIV-Infected Drug Abusers: Summary Report & Executive Summary for Year 1: Baseline. A joint project of the Health Resources and Services Administration, the National Institute on Drug Abuse, and the Consortium on Drug Abuse and HIV Services Access. Pub No. HRSA-RD-SP-94-8. Washington, DC: U.S. Department of Health and Human Services, 1994.
Hubbard, R.L.; Marsden, M.E.; and Rachal, J.V. Drug Abuse Treatment: A National Study of Effectiveness. Chapel Hill, NC: University of North Carolina Press, 1989.
Hughes, C.P.; Berg, L.; Danziger, W.L.; Coben, L.A.; and Martin, R.L. A new clinical scale for the staging of dementia. British Journal of Psychiatry 140:566–572, 1982.
Hull, H.F.; Bettinger, C.J.; Gallaher, M.M.; Keller, N.M.; Wilson, J.; and Mertz, G.J. Comparison of HIV-antibody prevalence in patients consenting to and declining HIV-antibody testing in an STD clinic. JAMA 260(7):935–938, 1988.3398198
Human Rights Campaign. The Ryan White CARE Act … Caring for People With HIV/AIDS. http://www.hrc.org/resources/entry/federal-response-to-hiv-aids
Humphry, D. Final Exit: The Practicalities of Self-Deliverance and Assisted Suicide for the Dying. Secaucus, NJ: The Hemlock Society, 1991.
Ickovics, J.R., and Rodin, J. Women and AIDS in the United States: Epidemiology, natural history, and mediating mechanisms. Health Psychology 11:1–16, 1992.
Iguchi, M.Y. Drug abuse treatment as HIV prevention: Changes in social drug use patterns might also reduce risk. Journal of Addictive Diseases 17(4):9–18, 1998.
Iguchi, M.Y.; Belding, M.A.; Morral, A.R.; Lamb, R.J.; and Husband, S.D. Reinforcing operants other than abstinence: An effective alternative for reducing drug use. Journal of Consulting and Clinical Psychology 65:421–428, 1997.9170765
Iguchi, M.Y.; Bux, Jr., D.A.; Lidz, V.; French, J.F.; Baxter, R.C.; and Platt, J.J. Changes in HIV-risk behaviors among injecting drug abusers: Impact of 21 vs. 90 days of methadone detoxification. AIDS 10:1719–1728, 1996.8970693
Iguchi, M.Y.; Handelsman, L.; Bickel, W.K.; and Griffiths, R.R. Benzodiazepine and sedative use/abuse by methadone maintenance clients. Drug and Alcohol Dependence 32:257–266, 1993.8102331
Iguchi, M.Y.; Platt, J.J.; French, J.; Baxter, R.C.; Kushner, H.; Lidz, V.M.; Bux, D.A.; Rosen, M.; and Musikoff, H. Correlates of HIV seropositivity among injection drug users not in treatment. Journal of Drug Issues 22:849–866, 1992.
Iguchi, M.Y., and Stitzer, M.L. Predictors of opiate drug abuse during a 90-day methadone detoxification. American Journal of Drug and Alcohol Abuse 17:279–294, 1991.1928022
Institute of Medicine. Pathways of Addiction: Opportunities in Drug Abuse Research. Washington, DC: National Academy Press, 1996.
International Association for the Study of Pain. Subcommittee of Taxonomy. Classification of chronic pain. Descriptions of chronic pain syndromes and definitions of pain terms. Pain Suppl 3:S1–S226, 1986.3461421
International Perinatal HIV Group. The mode of delivery and the risk of vertical transmission of human immunodeficiency virus type 1—A meta-analysis of 15 prospective cohort studies. New England Journal of Medicine 340(13):977–987, 1999.10099139
Jackson, J.F.; Rotkiewicz, L.G.; Quinones, M.A.; and Passannante, M.R. A coupon program— drug treatment and AIDS education. International Journal of the Addictions 24(11):1035–1051, 1989.2628354
James, J.S. Protease inhibitors: Drug resistance and cross-resistance overview. AIDS Treatment News No. 235, November 17, 1995.
Janikowski, T.P., and Glover, N.M. Incest and substance abuse: Implications for treatment professionals. Journal of Substance Abuse Treatment 11(3):177–183, 1994.8072045
Janiri, L.; Gobbi, G.; Mannelli, P.; Pozzi, G.; Serretti, A.; and Tempesta, E. Effects of fluoxetine at antidepressant doses on short-term outcome of detoxified alcoholics. International Clinical Psychopharmacology 11:109–117, 1996.
Joe, G.W., and Simpson, D.D. Mortality rates among opioid addicts in a longitudinal study. American Journal of Public Health 77:347–348, 1987.3812844
Joe, G.W.; Simpson, D.D.; and Hubbard, R.L. Treatment predictors of tenure in methadone maintenance. Journal of Substance Abuse 3:73–84, 1991.1821275
Joint Commission on Accreditation of Healthcare Organizations (JCAHO). 1999-2000 Comprehensive Accreditation Manual for Behavioral Health Care. Oakbrook Terrace, IL: JCAHO, 1999.
Junge, B.; Vlahov, D.; Riley, E.; Huettner, S.; Brown, M.; and Beilenson, P. Pharmacy access to sterile syringes for injection drug users: Attitudes of participants in a syringe exchange program. Journal of the American Pharmaceutical Association 39(1):17–22, 1999.9990182
Kail, B.L.; Watson, D.D.; and Ray, S. Needle-using practices within the sex industry. American Journal of Drug and Alcohol Abuse 21:241–255, 1995.7639210
Kalichman, S.C., and Hospers, H.J. Efficacy of behavior-skills enhancement HIV risk-reduction interventions in community settings. AIDS 11 Suppl A:S191–S199, 1997.9451985
Kalichman, S.C., and Stevenson, L.Y. Psychological and social factors associated with histories of risk for human immunodeficiency virus infection among African-American inner-city women. Journal of Womens Health 6(2):209–217, 1997.
Kanof, P.D.; Aronson, M.J.; and Ness, R. Organic mood syndrome associated with detoxification from methadone maintenance. American Journal of Psychiatry 150(3):423–428, 1993.8434657
Karkabi, B. Blacks' health problems addressed. The Houston Chronicle Lifestyle:3, April 10, 1994.
Kedes, D.H.; Ganem, D.; Ameli, N.; Bacchetti, P.; and Greenblatt, M. The prevalence of serum antibody to human herpesvirus 8 (Kaposi sarcoma-associated herpesvirus) among HIV-seropositive and high-risk HIVseronegative women. JAMA 277:478–481, 1997.9020272
Kelly, R.; Kiwanuka, N.; Wawer, M.J.; Serwadda, D.; Sewankambo, N.K.; Wabwire-Mangen, F.; Li, C.; Konde-Lule, J.K.; Lutalo, T.; Makumbi, F.; and Gray, R.H. Age of male circumcision and risk of prevalent HIV infection in rural Uganda. AIDS 13(3):399–405, 1999.10199231
Kessler, R.C.; Nelson, C.B.; McGonagle, K.A.; Edlund, M.J.; Frank, R.G.; and Leaf, P.J. The epidemiology of co-occurring addictive and mental disorders: Implications for prevention and services utilization. American Journal of Orthopsychiatry 66(1):17–31, 1996.8720638
Khabazz, R.F.; Onorato, I.M.; Cannon, R.O.; Hartley, T.M.; Roberts, B.; Hosein, B.; and Kaplan, J.E. Seroprevalence of HTLV-1 and HTLV-2 among intravenous drug abusers and persons in clinics for sexually transmitted diseases. New England Journal of Medicine 326:75–80, 1992.
Khantzian, E.J. The self-medication hypothesis of addictive disorders: Focus on heroin and cocaine dependence. American Journal of Psychiatry 142:1259–1264, 1985.3904487
Kipke, M.D.; O'Connor, S.; Palmer, R.; and MacKenzie, R.G. Street youth in Los Angeles. Profile of a group at high risk for human immunodeficiency virus infection. Archives of Pediatrics and Adolescent Medicine 149(5):513–519, 1995.7735403
Kitchener, K.S. Ethical principles and decisions in student affairs. In: Cannon, H.J., and Brown, R.D., eds. Applied Ethics in Student Services. New Directions for Student Services, No. 30. San Francisco: Jossey-Bass, 1985. pp. 17–29.
Kleber, H.D.; Topazian, M.; Gaspari, J.; Riordan, C.E.; and Kosten, T. Clonidine and naltrexone in the outpatient treatment of heroin withdrawal. American Journal of Drug and Alcohol Abuse 13:1–17, 1987.3687878
Kosten, T.R.; Gawin, F.H.; Rounsaville, B.J.; and Kleber, H.D. Cocaine abuse among opioid addicts: Demographic and diagnostic factors in treatment. American Journal of Drug and Alcohol Abuse 12:1–16, 1986.3788892
Kreek, M.J. Using methadone effectively: Achieving goals by application of laboratory, clinical, and evaluation research and by development of innovative programs. In: Pickens, R.W.; Leukfeld, C.G.; and Schuster, C.R., eds. Improving Drug Abuse Treatment. NIDA Research Monograph Series, Number 106. HHS Pub. No. (ADM) 91–1754. Rockville, MD: National Institute on Drug Abuse, 1991. pp. 245–266.
Kreek, M.J.; Garfield, J.W.; Gutjahr, C.L.; and Giusti, L.M. Rifampin-induced methadone withdrawal. New England Journal of Medicine 294:1104–1106, 1976.1256526
Ku, L.; Sonenstein, F.L.; and Pleck, J.H. Patterns of HIV risk and preventive behavior among teenage men. Public Health Reports 107(2):131–138, 1992.1561292
Kübler-Ross, E. On Death and Dying. New York: MacMillan, 1969.
Kufeldt, K.; Durieux, M.; Nimmo, M.; and McDonald, M. Providing shelter for street youth: Are we reaching those in need? Child Abuse and Neglect 16(2):187–199, 1992.1559168
Laumann, E.O.; Masi, C.M.; and Zuckerman, E.W. Circumcision in the United States. Prevalence, prophylactic effects, and sexual practice. JAMA 277(13):1052–1057, 1997.9091693
Laurence, J. T-cell subsets in health, infectious disease, and idiopathic CD4+ T lymphocytopenia. Annals of Internal Medicine 119(1):55–62, 1993.8098929
Lebovits, A.H.; Lefkowitz, M.; McCarthy, D.; Simon, R.; Wilpon, H.; Jung, R.; and Fried, E. The prevalence and management of pain in patients with AIDS: A review of 134 cases. Clinical Journal of Pain 5:245–248, 1989.2520410
Leigh, B.C. The relationship of substance abuse during sex to high-risk sexual behavior. Journal of Sex Research 27(2):199–213, 1990.
Leigh, B.C., and Stall, R. Substance use and risky sexual behavior for exposure to HIV. Issues in methodology, interpretation, and prevention. American Psychologist 48:1035–1045, 1993.8256876
Leroy, V.; Newell, M.L.; Dabis, F.; Peckham, C.; Van de Perre, P.; Bulterys, M.; Kind, C.; Simonds, R.J.; Wiktor, S.; and Msellati, P. International multicentre pooled analysis of late postnatal mother-to-child transmission of HIV-1 infection. Ghent International Working Group on Mother-to-Child Transmission of HIV. Lancet 352(9128):597–600, 1998.9746019
Lesbian and Gay Substance Abuse Planning Group. San Francisco Lesbian, Gay, and Bisexual Substance Abuse Needs Assessment: A Report. San Francisco: EMT Associates, August 1991.
Levine, S. Who Dies? An Investigation of Conscious Living and Conscious Dying. Garden City, NY: Anchor Press/Doubleday, 1982.
Lewis, C.E.; Saghir, M.T.; and Robins, E. Drinking patterns in homosexual and heterosexual women. Journal of Clinical Psychiatry 43:277–279, 1982.7085588
Lidz, V.; Bux, D.; Platt, J.; and Iguchi, M. Transitional case management: A service model for AIDS outreach projects. In: Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92–1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 112–144.
Ling, W.; Rawson, R.A.; and Compton, M.A. Substitution pharmacotherapies for opioid addiction: From methadone to LAAM and buprenorphine. Journal of Psychoactive Drugs 26:119–128, 1994.7931856
Liuzzi, G.; Chirianni, A.; Clementi, M.; Bagnarelli, P.; Valenza, A.; Cataldo, P.T.; and Piazza, M. Analysis of HIV-1 load in blood, semen, and saliva: Evidence for different viral compartments in a cross-sectional and longitudinal study. AIDS 10(14):F51–F56, 1996.8970677
Lohrenz, L.J.; Connelly, J.C.; Cony, L.; and Spare, K.E. Alcohol problems in several midwestern homosexual communities. Journal of Studies on Alcohol 39(11):1959–1963, 1978.739779
Longshore, D.; Anglin, M.D.; Annon, K.; and Hsieh, S. Trends in self-reported HIV risk behavior: Injection drug users in Los Angeles. Journal of Acquired Immune Deficiency Syndromes 6(1):82–90, 1993.8417180
Longshore, D.; Annon, J.; and Anglin, M.D. HIV prevalence among injection drug users in three Northern California communities. Journal of Acquired Immune Deficiency Syndromes and Human Retrovirology 19(2):200, 1998.
Longshore, D.; Hsieh, S.C.; Anglin, M.D.; and Annon, T.A. Ethnic patterns in drug abuse treatment utilization. Journal of Mental Health Administration 19(3):268–277, 1992.10171332
Loue, S.; Lurie, P.; and Lloyd, L.S. Ethical issues raised by needle exchange programs. Journal of Law, Medicine and Ethics 23:382–388, 1995.
Lowinson, J.H.; Marion, I.J.; Joseph, H.; and Dole, J.P. Methadone maintenance. In: Lowinson, J.H.; Ruiz, P.; and Millman, R.B., eds. Substance Abuse: A Comprehensive Textbook, 2nd ed. Baltimore: Williams & Wilkins, 1992. pp. 550–561.
Lurie, P.G.; Drucker, E.; and Knowles, A. Still working after all these years: Increasing evidence of needle exchange program (NEP) effectiveness in studies published since 1993. International Conference on AIDS 12:670 (Abstract No. 33403), 1998.
Lurie, P.G.; Sorensen, J.; Lane, S.; Kahn, J.G.; Guydish, J.; Foley, J.; Chen, D.; Bowser, B.; Jones, T.S.; and Reingold, A.L. The public health impact of needle exchange programs (NEPs). (Abstract No. 564C). International Conference on AIDS 10(2):72, August 1994.
Lyketsos, C.G.; Hanson, A.L.; Fishman, M.; Rosenblatt, A.; McHugh, P.R.; and Treisman, G.J. Manic syndrome early and late in the course of HIV. American Journal of Psychiatry 150(2):326–327, 1993.8422087
Lyketsos, C.G.; Hutton, H.; Fishman, M.; Schwartz, J.; and Treisman, G.J. Psychiatric morbidity on entry to an HIV primary care clinic. AIDS 10(9):1033–1039, 1996.8853738
MacDougall, D.S. HIV/AIDS behind bars: Incarceration provides a valuable opportunity to implement HIV/AIDS treatment and prevention strategies in a high-risk population. Journal of the International Association of Physicians in AIDS Care 4(4):8–13, 1998.11365184
MacGowan, R.J.; Brackbill, R.M.; Rugg, D.L.; Swanson, N.M.; Weinstein, B.; Couchon, A.; Scibak, J.; Molde, S.; McLaughlin, P.; Barker, T.; and Voigt, R. Sex, drugs and HIV counseling and testing: A prospective study of behavior-change among methadone-maintenance clients in New England. AIDS 11(2):229–235, 1997.9030371
Marck, J. Aspects of male circumcision in sub-equatorial African culture history. Health Transition Review 7:357–360, 1997.
Margolick, J.B.; Munoz, A.; Vlahov, D.; Solomon, L.; Astemborski, J.; Cohn, S.; and Nelson, K.E. Changes in T-lymphocyte subsets in intravenous drug abusers with HIV-1 infection. JAMA 267(12):1631–1636, 1992.1347321
Marin, B.V. Analysis of AIDS Prevention Among African Americans and Hispanics in the United States. National Technical Information Service Order No. PB96-10851 INZ. Washington, DC: Office of Technology Assessment, 1995.
Marlatt, G.A.; Somers, J.M.; and Tapert, S.F. Harm reduction: Application to alcohol abuse problems. In: Onken, L.S.; Blaine, J.D.; and Boren, J.J., eds. Behavioral Treatments for Drug Abuse and Dependence. NIDA Research Monograph Series, Number 137. HHS Pub. No. (ADM) 93–3684. Rockville, MD: National Institute on Drug Abuse, 1993. pp. 147–166.
Martinez, T.E.; Gleghorn, A.; Marx, R.; Clements, K.; Boman, M.; and Katz, M.H. Psychosocial histories, social environment, and HIV risk behaviors of injection and noninjection drug using homeless youths. Journal of Psychoactive Drugs 30(1):1–9, 1998.9565203
Maruschak, L. HIV in Prisons and Jails, 1995. Bureau of Justice Statistics. Pub. No. NCJ-164260. Washington, DC: U.S. Department of Justice, Office of Justice Programs, 1997.
Maslow, A. Hierarchy of needs. In: Maslow, A., ed. Motivation and Personality. New York: Harper & Row, 1970. p. 369.
Mason, B.J.; Kocsis, J.H.; Ritvo, E.C.; and Cutler, R.B. A double-blind, placebo-controlled trial of desipramine for primary alcohol dependence stratified on the presence or absence of major depression. JAMA 13:761–767, 1996.
Masur, H.; Michelis, M.A.; Greene, J.B.; Onorato, I.; Stouwe, R.A.; Holzman, R.S.; Wormser, G.; Brettman, L.; Lange, M.; Murray, H.W.; and Cunningham-Rundles, S. An outbreak of community acquired Pneumocystis carinii pneumonia: Initial manifestation of cellular immune dysfunction. New England Journal of Medicine 305(24):1431–1438, 1981.6975437
Masur, H.; Michelis, M.A.; Wormser, G.P.; Lewin, S.; Gold, J.; Tapper, M.L.; Giron, J.; Lerner, C.W.; Armstrong, D.; Setia, U.; Sender, J.A.; Siebkin, R.S.; Nicholas, P.; Arlen, Z.; Maayan, S.; Ernst, J.A.; Siegal, F.P.; and Cunningham-Rundles, S. Opportunistic infection in previously healthy women. Initial manifestations of a community-acquired cellular immunodeficiency. Annals of Internal Medicine 97(4):533–539, 1982.6982014
McCaffery, M. Nursing Management of the Patient With Pain. Philadelphia: Lippincott, 1979.
McCann, R.M.; Hall, W.J.; and Groth-Juncker, A. Comfort care for terminally ill patients. The appropriate use of nutrition and hydration. JAMA 272(16):1263–1266, 1994.7523740
McCarthy, E.P.; Feldman, Z.T.; and Lewis, B.F. Development and implementation of an interorganizational case management model for substance users. In: Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92–1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 331–349.
McCoy, H.V.; Dodds, S.; Rivers, J.E.; and McCoy, C.B. Case management services for HIV-seropositive IDUs. In: Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92–1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 181–207.
McCusker, J.; Bigelow, C.; Stoddard, A.M.; and Zorn, M. Human immunodeficiency virus type 1 antibody status and change among drug abusers. Annals of Epidemiology 4:466–471, 1994a.7804502
McCusker, J.; Willis, G.; McDonald, M.; Lewis, B.F.; Sereti, S.M.; and Feldman, Z.T. Admission of injection drug users to drug abuse treatment following HIV counseling and testing. Public Health Reports 109:212–218, 1994b.8153272
McGrath, P.J.; Nunes, E.V.; Stewart, J.W.; Goldman, D.; Agosti, V.; Ocepek-Welikson, K.; and Quitkin, F.M. Imipramine treatment of alcoholics with primary depression: A placebo-controlled clinical trial. Archives of General Psychiatry 53:232–240, 1996.8611060
McKirnan, D., and Peterson, P.L. Alcohol and drug use among homosexual men and women: Epidemiology and population characteristics. Addictive Behaviors 14:545–553, 1989.2589133
McLellan, A.T.; Arndt, I.O.; Metzger, D.S.; Woody, G.E.; and O'Brien, C.P. The effects of psychological services in substance abuse treatment. JAMA 269(15):1953–1959, 1993.8385230
McNally, E.B., and Finnegan, D.G. Lesbian recovering alcoholics: A qualitative study of identity transformation. A report on research and applications to treatment. Journal of Chemical Dependency Treatment 5(1):93–103, 1992.
McRoy, C.P.; Shorkey, C.T.; and Garcia, L. Alcohol use and abuse among Mexican-Americans. In: Freeman, E.M., ed. Social Work Practice With Clients Who Have Alcohol Problems. Springfield, IL: Charles C. Thomas, 1985.
McWhirter, D.P.; Sanders, S.A.; and Reinisch, J.M., eds. Homosexuality/Heterosexuality: Concepts of Sexual Orientation. New York: Oxford University Press, 1990.
Mejta, C.L.; Bokos, P.J.; Mickenburg, J.H.; Maslar, M.E.; and Senay, E. Improving substance abuse treatment access and retention using a case management approach. Journal of Drug Issues 27(2):329–340, 1997.
Mello, N.K., and Mendelson, J.H. Primate studies of the behavioral pharmacology of buprenorphine. In: Blaine, J.D., ed. Buprenorphine: An Alternative Treatment for Opioid Dependence. NIDA Research Monograph Series, Number 121. HHS Pub. No. (ADM) 92–1912. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 61–100.
Mellors, J.W. Closing in on human immunodeficiency virus. Nature Medicine 2(3):274–275, 1996.
Mellors, J.W. “Review of Lago Maggiore resistance meeting.” Twelfth World AIDS Conference, Geneva, Switzerland, 1998.
Mellors, J.W., and Kuritzkes, D. “Antiretroviral therapy: Resistance.” Eighth Clinical Care Options for HIV Symposium, 1998.
Mellors, J.W.; Munoz, A.; Giorgi, J.V.; Margolick, J.B.; Tassoni, C.J.; Gupta, P.; Kingsley, L.A.; Todd, J.A.; Saah, A.J.; Detels, R.; Phair, J.P.; and Rinaldo, Jr., C.R. Plasma viral load and CD4+ lymphocytes as prognostic markers of HIV-1 infection. Annals of Internal Medicine 126:946–954, 1997.9182471
Metzger, D.S.; Woody, G.E.; McLellan, A.T.; O'Brien, C.P.; Druley, P.; Navaline, H.; DePhillipis, D.; Stolley, P.; and Abrutyn, E. Human immunodeficiency virus seroconversion among intravenous drug users in- and out-of-treatment: An 18-month prospective follow-up. Journal of Acquired Immune Deficiency Syndromes 6:1049–1056, 1993.8340896
Meyer, C. Surviving Death. Mystic, CT: Twenty-Third Publications, 1994.
Miller, N. In Search of Gay America: Women and Men in a Time of Change. New York: Atlantic Monthly Press, 1989.
Miller, W.R. Behavioral treatments for drug problems: Lessons from the alcohol treatment outcome literature. In: Onken, L.S.; Blaine, J.D.; and Boren, J.J., eds. Behavioral Treatment for Drug Abuse and Dependence. NIDA Research Monograph Series, Number 137. HHS Pub. No. (ADM) 93–3684. Rockville, MD: National Institute on Drug Abuse, 1993. pp. 167–180.
Mills, T.C.; Stall, R.; Catania, J.A.; and Coates, T.J. Interpreting HIV prevalence and incidence among Americans: Bridging data and public policy. American Journal of Public Health 87:864–866, 1997.9184526
Millstein, S.G., and Moscicki, A.B. Sexually-transmitted disease in female adolescents: Effects of psychosocial factors and high risk behaviors. Journal of Adolescent Health 17(2):83–90, 1995.
Mirin, S.M.; Weiss, R.D.; Michael, J.; and Griffin, M.L. Psychopathology in substance abusers: Diagnosis and treatment. American Journal of Drug and Alcohol Abuse 14(2):139–157, 1988.
Montgomery, K., and Lewis, C.E. Fear of HIV contagion as workplace stress: Behavioral consequences and buffers. Hospital and Health Services Administration 40(4):439–456, 1995.10153368
Moody, R., Jr. Life After Life: The Investigation of a Phenomenon, Survival of Bodily Death. New York: Bantam Books, 1975.
Moore, B.E., and Fine, B.D. Psychoanalytic Terms and Concepts. New Haven, CT: The American Psychoanalytic Association and Yale University Press, 1990.
Morales, E., and Graves, M.A. Substance Abuse: Patterns and Barriers to Treatment for Gay Men and Lesbians in San Francisco. San Francisco: San Francisco Department of Public Health, 1983.
Morales, T.; Gomez, C.A.; and Marin B.V. “Freedom and HIV prevention: Challenges facing Latino inmates leaving prison.” Paper presented at the 103rd American Psychological Association Convention, New York, 1995.
Moreno, S.; Baraia-Etxaburu, J.; Bouza, E.; Parras, F.; Perez-Tascon, M.; Miralles, P.; Vicente, T.; Alberdi, J.C.; Cosin, J.; and Lopez-Gay, D. Risk for developing tuberculosis among anergic patients infected with HIV. Annals of Internal Medicine 119:194–198, 1993.8100693
Mosbacher, D. Lesbian alcohol and substance abuse. Psychiatric Annals 18(1):47, 49–50, 1988.
Mosbacher, D. Alcohol and other drug use in female medical students: A comparison of lesbians and heterosexuals. Journal of Gay and Lesbian Psychotherapy 2(1):37–48, 1993.
Moses, S.; Bailey, R.C.; and Ronald, A.R. Male circumcision: Assessment of health benefits and risks. Sexually Transmitted Infections 74(5):368–373, 1998.10195035
Mumola, C.J. Substance Abuse and Treatment, State and Federal Prisoners, 1997. Bureau of Justice Statistics. Pub No. NCJ-172871. Washington, DC: U.S. Department of Justice, Office of Justice Programs, 1999.
Musher, D.M.; Hamill, R.J.; and Baughn, R.E. Effect of human immunodeficiency virus (HIV) infection on the course of syphilis and on the response to treatment. Annals of Internal Medicine 113:872–881, 1990.2240901
Myers, T.; Orr, K.W.; Locker, D.; and Jackson, E.A. Factors affecting gay and bisexual men's decisions and intentions to seek HIV testing. American Journal of Public Health 83(5):701–704, 1993.8484452
Nahass, R.G.; Weinstein, M.P.; Bartels, J.; and Gocke, D.J. Infective endocarditis in intravenous drug users: A comparison of human immunodeficiency virus type 1-negative and -positive patients. Journal of Infectious Diseases 162(4):967–970, 1990.2401795
Nakashima, A.K.; Horsley, R.; Frey, R.L.; Sweeney, P.A.; Weber, J.T.; and Fleming, P.L. Effects of HIV reporting by name on use of HIV testing in publicly funded counseling and testing programs. JAMA 280:1421–1426, 1998.9801002
National Association of Social Workers. “Ethical Issues, HIV/AIDS, and Social Work Practice.” Workshop sponsored by the HIV/AIDS Spectrum: Mental Health Training and Education of Social Workers Project, 1997.
National Commission on AIDS. The Challenge of HIV/AIDS in Communities of Color. Washington, DC: National Commission on AIDS, 1992.
National Institute of Allergy and Infectious Diseases. HIV and Adolescents. NIAID Fact Sheet. Washington, DC: National Institutes of Health, 1999.
National Institutes of Health. Effective medical treatment of opiate addiction. NIH Consensus Statement Online 15(6):1–38, 1997a.
National Institutes of Health. Interventions to prevent HIV risk behaviors. NIH Consensus Statement Online 15(2):1–41, 1997b.
Needle, R.; Coyle, S.L.; Normand, J.; Lambert, E.L.; and Cesari, H. HIV prevention with drug-using populations: Current status and future prospects: Introduction and overview. Public Health Reports 113(Suppl.1):4–18, 1998.
Niccolai, L.M.; Dorst, D.; Myers, L.; and Kissinger, P.J. Disclosure of HIV status to sexual partners: Predictors and temporal patterns. Sexually Transmitted Diseases 26(5):281–285, 1999.10333282
Normand, J.; Vlahov, D.; and Moses, L.E., eds. Preventing HIV Transmission: The Role of Sterile Needles and Bleach. Washington, DC: National Academy Press, 1995.
North, C.S., and Smith, E.M. A systematic study of mental health services utilization by homeless men and women. Social Psychiatry and Psychiatric Epidemiology 28:77–83, 1993.8511667
Nuland, S. How We Die: Reflections on Life's Final Chapter. New York: A.A. Knopf, 1994.
Nunes, E.V.; McGrath, P.J.; Quitkin, F.M.; Stewart, J.W.; Harrison, W.; Tricamo, E.; and Ocepek-Welikson, K. Imipramine treatment of alcoholism with comorbid depression. American Journal of Psychiatry 150:963–965, 1993.8494079
O'Brien, C.; Greenstein, R.; Ternes, J.; and Woody, G. Clinical pharmacology of narcotic antagonists. Annals of the New York Academy of Sciences 311:232–240, 1978.369432
O'Connor, P.G.; Molde, S.; Henry, S.; Shockcor, W.T.; and Schottenfeld, R.S. Human immunodeficiency virus infection in intravenous drug users: A model for primary care. American Journal of Medicine 93:382–386, 1992a.1415300
O'Connor, P.G., and Samet, J.H. The substance-using human immunodeficiency virus patient: Approaches to outpatient management. American Journal of Medicine 101(4):435–444, 1996.8873515
O'Connor, P.G.; Samet, J.H.; and Stein, M.D. Management of hospitalized intravenous drug users: Role of the internist. American Journal of Medicine 96:551–558, 1994a.8017454
O'Connor, P.G.; Selwyn, P.A.; and Schottenfeld, R.S. Medical care for injection-drug users with human immunodeficiency virus infection. New England Journal of Medicine 331(7):450–459, 1994b.8035842
O'Connor, P.G.; Waugh, M.E.; Schottenfeld, R.S.; Diakogiannis, I.A.; and Rounsaville, B.J. Ambulatory opiate detoxification and primary care: A role for the primary care physician. Journal of General Internal Medicine 7:532–534, 1992b.1403211
Office of National Drug Control Policy (ONDCP). High Intensity Drug Trafficking Areas. http://www.whitehouse.gov/ondcp/high-intensity-drug-trafficking-areas-program
O'Malley, S.S.; Jaffe, A.; Chang, G.; Schottenfeld, R.S.; Meyer, R.E.; and Rounsaville, B.J. Naltrexone and coping skills therapy for alcohol dependence. A controlled study. Archives of General Psychiatry 49: 881–887, 1992.1444726
Packer, K.L. HIV Infection: The Facts You Need To Know. New York: Franklin Watts, 1998.
Page, J.B.; Lai, S.H.; Chitwood, D.D.; Klimas, N.G.; Smith, P.C.; and Fletcher, M.A. HTLV-I/II seropositivity and death from AIDS among HIV-1 seropositive intravenous drug users. Lancet 335(8703):1439–1441, 1990.1972217
Pascal, C.B. Letter to John Harkness, M.D., Oklahoma State Department of Health, from the Legal Advisor to the U.S. Alcohol, Drug Abuse, and Mental Health Administration, September 2, 1988. In: Center for Substance Abuse Treatment. Confidentiality of Patient Records for Alcohol and Other Drug Treatment. Technical Assistance Publication (TAP) Series, Number 13. HHS Pub. No. (SMA) 95–3018. Washington, DC: U.S. Government Printing Office, 1995.
Paul, J.P. Clean and Sober and Safe. 18th Street Services Continuing Recovery Group Client Workbook. San Francisco: 1991a.
Paul, J.P.; Stall, R.D.; and Bloomfield, K. Gay and alcoholics: Epidemiological and clinical issues. Alcohol Health and Research World 15:151–160, 1991b.
Paul, J.P.; Stall, R.D.; Crosby, G.M.; Barrett, D.C.; and Midanik, L.T. Correlates of sexual risk-taking among gay male substance abusers. Addiction 89:971–983, 1994.7950855
Paul, J.P.; Stall, R.D.; and Davis, F. Sexual risk for HIV transmission among gay/bisexual men in substance-abuse treatment. Journal of AIDS Education and Prevention 5:11–24, 1993.8481269
Perlman, D. Quarter of AIDS patients not getting best therapy. The San Francisco Chronicle, June 4, 1998. p. A9.
Pena, J., and Koss-Chioino, J. Cultural sensitivity in drug treatment research with African American males. In: Trimble, J.E.; Bolek, C.S.; and Niemrcyk, S.J., eds. Ethnic and Multicultural Drug Abuse. Binghampton, NY: The Haworth Press, 1992. pp. 157–179.
Perez-Arce, P.; Carr, K.D.; and Sorensen, J.L. Cultural issues in an outpatient program for stimulant abusers. Journal of Psychoactive Drugs 25(1):35–44, 1993.8097765
Perlman, D.C.; Perkins, M.P.; Solomon, N.; Kochems, L.; Des Jarlais, D.C.; and Paone, D. Tuberculosis screening at a syringe exchange program. American Journal of Public Health 87(5):862–863, 1997.9184525
Perry, S.; Jacobsberg, L.; and Fishman, B. Suicidal ideation and HIV testing. JAMA 263(5):679–682, 1990.2296122
Peterson, J.L.; Coates, T.J.; Catania, J.A.; Middleton, L.; Hilliard, B.; and Hearst, N. High-risk sexual behavior and condom use among gay and bisexual African American men. American Journal of Public Health 82:1490–1494, 1992.1443298
Phillips, K.A., and Coates, T.J. HIV counseling and testing: Research and policy issues. AIDS Care 7:115–124, 1995.7619865
Pike, E.C. Human Immunodeficiency Virus (HIV-1) Guidelines for Chemical Dependency Treatment and Care Programs in Minnesota. St. Paul, MN: Chemical Dependency Program Division, Minnesota Department of Human Services, 1989.
Pillard, R.C. Sexual orientation and mental disorder. Psychiatric Annals 18(1):52–56, 1989.
Pirkola, S.P.; Isometsa, E.T.; Henriksson, M.; Heikkinen, M.E.; Marttunen, M.J.; and Lonnqvist, J.K. The treatment received by substance-dependent male and female suicide victims. Acta Psychiatrica Scandinavica 99(3):207–213, 1999.10100915
Polonsky, S.; Kerr, S.; Harris, B.; Gaiter, J.; Fichtner, R.R.; and Kennedy, M.G. HIV prevention in prisons and jails: Obstacles and opportunities. Public Health Reports 109:615–625, 1994.7938381
Portenoy, R.K., and Payne, R. Acute and chronic pain. In: Lowinson, J.H.; Ruiz, P.; and Millman, R.B., eds. Substance Abuse: A Comprehensive Textbook, 2nd ed. Baltimore: Williams & Wilkins, 1992. pp. 691–721.
Power, R.; Hartnoll, R.; and Daviaud, E. Drug injecting, AIDS, and risk behavior: Potential for change and intervention strategies. British Journal of Addiction 83:649–654, 1988.3165302
Preston, K.L., and Bigelow, G.E. Subjective and discriminative effects of drugs. Behavioral Pharmacology 2:293–313, 1991.
Price, R.W., and Brew, B.J. The AIDS dementia complex. Journal of Infectious Diseases 158(5):1079–1083, 1988.3053922
Price, R.W., and Perry, S.W., III, eds. HIV, AIDS, and the Brain. New York: Raven Press, 1994.
Rakower, D., and Galvin, T.A. Nourishing the HIV-infected adult. Holistic Nursing Practice 3(4):26–37, 1989.
Rall, T.W. Hypnotics and sedatives: Ethanol. In: Gilman, A.G.; Rall, T.W.; Nies, A.S.; and Taylor, P., eds. Goodman and Gilman's: The Pharmacological Basis of Therapeutics, 8th ed. New York: Pergamon Press, 1990. pp. 345–382.
Reamer, F. AIDS, social work, and the “duty to protect.” Social Work 36(1):56–60, 1991.1998129
Regier, D.A.; Farmer, M.E.; Rae, D.S.; Locke, B Z.; Keith, S.J.; Judd, L.L.; and Goodwin, F.K. Comorbidity of mental disorders with alcohol and other drug abuse. Results from the Epidemiologic Catchment Area (ECA) Study. JAMA 264(19):2511–2518, 1990.2232018
Reilly, P.M.; Banys, P.; Tusel, D.J.; Sees, K.L.; Krumenaker, C.L.; and Shopshire, M.S. Methadone transition treatment: A treatment model for 180-day methadone detoxification. International Journal of the Addictions 30:387–402, 1995.7607775
Renton, A.; Whitaker, L.; Ison, C.; Wadsworth, J.; and Harris, J.R. Estimating the sexual mixing patterns in the general population from those in people acquiring gonorrhoea infection: Theoretical foundation and empirical findings. Journal of Epidemiology and Community Health 49:205–213, 1995.7798052
Resnick, R.; Schuyten-Resnick, E.; and Washton, A.M. Narcotic antagonists in the treatment of opioid dependence: Review and commentary. Comprehensive Psychiatry 20:116–125, 1979.421447
Richardson, L. Man faces felony charge in HIV case. New York Times, August 20, 1998.
Richter, R.; Michaels, M.; Carlson, B.; and Coates, T.J. Motivators and Barriers to Use of Combination Therapies in Patients With HIV Disease. CAPS Monograph Series, Occasional Paper No. 5. San Francisco: University of California at San Francisco, Center for AIDS Prevention Studies, 1998.
Rosen, A.D., and Rosen, T. Study of condom integrity after brief exposure to over-the-counter vaginal preparations. Southern Medical Journal 92(3):305–307, 1999.10094272
Rotheram-Borus, M.J.; Rosario, M.; Reid, H.; and Koopman, C. Predicting patterns of sexual acts among homosexual and bisexual youths. American Journal of Psychiatry 152(4):588–595, 1995.7694909
Rowan-Szal, G.; Joe, G.W.; Chatham, L.R.; and Simpson, D.D. A simple reinforcement system for methadone clients in a community-based treatment program. Journal of Substance Abuse Treatment 11:217–223, 1994.8072049
Royce, R.A.; Sena, A.; Cates, W.; and Cohen, M.S. Sexual transmission of HIV. New England Journal of Medicine 336(15):1072–1078, 1997.9091805
Russell, N.D., and Sepkowitz, K.A. Primary HIV infection: Clinical, immunologic, and virologic predictors of progression. The AIDS Reader 8(4):164–172, 1998.
Saag, M.S. The natural history of HIV-1 infection. In: Broder, S.; Merigan, T.C.; and Bolognesi, D., eds. Textbook of AIDS Medicine. Baltimore: Williams & Wilkins, 1994. pp. 45–53.
Sadownick, S. Kneeling at the crystal cathedral: The alarming new epidemic of methamphetamine abuse in the gay community. Genre December/January 1994: 40–45, 86–90.
Saghir, M.T., and Robins, E. Male and Female Homosexuality. Baltimore: Williams & Wilkins, 1973.
Samet, J.H. Models of medical care for HIV-infected drug users. Substance Abuse 16(3):131–139, 1995.
Samet, J.H.; Freedberg, K.A.; Stein, M.D.; Lewis, R.; Savetsky, J.; Sullivan, L.; Levenson, S.M.; and Hingson, R. Trillion virion delay: Time from testing positive for HIV to presentation for primary care. Archives of Internal Medicine 158:734–740, 1998.9554679
Samet, J.H.; Libman, H.; Labelle, C.; Steger, K.; Lewis, R.; Craven, D.E.; and Freedberg, K.A. A model clinic for the initial evaluation and establishment of primary care for persons infected with human immunodeficiency virus. Archives of Internal Medicine 155:1629–1633, 1995.7618986
Samet, J.H.; Libman, H.; Steger, K.A.; Dhawan, R.K.; Chen, J.; Shevitz, A.H.; Dewees-Dunk, R.; Levenson, S.; Kufe, D.; and Craven, D.E. Compliance with zidovudine therapy in patients infected with human immunodeficiency virus, type 1: A cross-sectional study in a municipal hospital clinic. American Journal of Medicine 92(5):495–502, 1992.1580296
Samet, J.H.; Mulvey, K.P.; Zaremba, N.; and Plough, A. HIV testing in substance abusers. American Journal of Drug and Alcohol Abuse 25:269–280, 1999.10395160
Samet, J.H.; Muz, P.; Cabral, P.; Jhamb, K.; Suwanchinda, A.; and Freedberg, K.A. Dermatologic manifestations in HIV-infected patients: A primary care perspective. Mayo Clinic Proceedings 74(7):658–660, 1999.10405693
Samet, J.H.; O'Connor, P.G.; and Stein, M.D. Alcohol and other substance abuse. Medical Clinics of North America 81(4):831–1075, 1997.9222256
Samuel, M.C.; Osmond, D.H.; and Osmond, D.E. Annotation: Uncertainties in the estimation of HIV prevalence and incidence in the United States. American Journal of Public Health 86:627–628, 1996.8629709
San Francisco AIDS Foundation. HIV Postexposure Prevention (PEP). Summary Sheets on HIV Treatment Strategies. 1997a. http://www.sfaf.org/
San Francisco AIDS Foundation. HIV viral load and CD4 T-cell testing, drug resistance, and adherence to HAART. Summary Sheets on HIV Treatment Strategies. 1997b.
San Francisco AIDS Foundation. Protease inhibitor drugs and new HIV treatment strategies. Summary Sheets on HIV Treatment Strategies. 1997c.
Savin-Williams, R.C. Verbal and physical abuse as stressors in the lives of lesbian, gay male, and bisexual youths: Association with school problems, running away, substance abuse, prostitution, and suicide. Journal of Consulting and Clinical Psychology 62(2):261–269, 1994.8201062
Saxinger, W.C.; Levine, P.H.; Dean, A.G.; de The, G.; Lange-Wantzin, G.; Moghissi, J.; Laurent, F.; Hoh, M.; Sarngadharan, M.G.; and Gallo, R.C. Evidence for exposure to HTLV-III in Uganda before 1973. Science 227(4690):1036–1038, 1985.2983417
Schlenger, W.E.; Kroutil, L.A.; and Roland, E.J. Case management as a mechanism for linking drug abuse treatment and primary care: Preliminary evidence from the ADAMHA/HRSA linkage demonstration. In: Ashery, R.S., ed. Progress and Issues in Case Management. NIDA Research Monograph Series, Number 127. HHS Pub. No. (ADM) 92–1946. Rockville, MD: National Institute on Drug Abuse, 1992. pp. 316–330.
Schneider, M.M.; Hoepelman, A.I.; Eeftinck Schattenkerk, J.K.; Nielsen, T.L.; van der Graaf, Y.; Frissen, J.P.; van der Ende, I.M.; Kolsters, A.F.; and Borleffs, J.C. A controlled trial of aerosolized pentamidine or trimethoprim-sulfamethoxazole as primary prophylaxis against Pneumocystis carinii pneumonia in patients with human immunodeficiency virus infection. The Dutch AIDS Treatment Group. New England Journal of Medicine 327:1836–1841, 1992.1360145
Schofferman, J., and Brody, R. Pain in far advanced AIDS. In: Foley, K.M.; Bonica, J.J.; and Ventafridda, V., eds. Advances in Pain Research and Therapy. Vol. 16. Proceedings of the Second International Congress on Cancer Pain. New York: Raven Press, 1990. pp. 379–386.
Schoofs, M. AIDS: The agony of Africa. Part 4: The virus, past and future. The Village Voice, November 24, 1999.
Schuster, C.R., and Silverman, K. Advancing the application of behavioral treatment approaches for drug dependence. In: Onken, L.S.; Blaine, J.D.; and Boren, J.J., eds. Behavioral Treatment for Drug Abuse and Dependence. NIDA Research Monograph Series, Number 137. HHS Pub. No. (ADM) 93–3684. Rockville, MD: National Institute on Drug Abuse, 1993. pp. 5–17.
Schwartz, E.L.; Brechbuhl, A.B.; Kahl, P.; Miller, M.H.; Selwyn, P.A.; and Friedland, G.H. Altered pharmacokinetics of zidovudine in former IV drug-using patients receiving methadone. International Conference on AIDS 6(3):194, 1990.
Seil, D. Transsexuals: The boundaries of sexual identity and gender. In: Cabaj, R.P., and Stein, T.S., eds. Textbook of Homosexuality and Mental Health. Washington, DC: American Psychiatric Press, 1996. pp. 743–762.
Selwyn, P.A. The impact of HIV infection on medical services in drug abuse treatment programs. Journal of Substance Abuse Treatment 13:397–410, 1996.9142670
Selwyn, P.A.; Alcabse, P.; Hartel, D.; Buono, D.; Schoenbaum, E.E.; Klein, R.S.; Davenny, K.; and Friedland, G.H. Clinical manifestations and predictors of disease progression in drug users with human immunodeficiency virus infection. New England Journal of Medicine 327:1697–1703, 1992.1359411
Selwyn, P.A.; Budner, N.S.; Wasserman, W.C.; and Arno, P.S. Utilization of on-site primary care services by HIV-seropositive and seronegative drug users in a methadone maintenance program. Public Health Reports 108:492–500, 1993.8393579
Selwyn, P.A.; Feingold, A.R.; Iezza, A.; Satyadeo, M.; Colley, J.; Torres, R.; and Shaw, J.F. Primary care for patients with human immunodeficiency virus (HIV) infection in a methadone maintenance treatment program. Annals of Internal Medicine 111:761–763, 1989.2802435
Selwyn, P.A., and O'Connor, P.G. Diagnosis and treatment of substance users with HIV infection. Primary Care 19(1):119–156, 1992.1594693
Shaffer, N.; Bulterys, M.; and Simonds, R.J. Short courses of zidovudine and perinatal transmission of HIV. New England Journal of Medicine 340(13):1042–1043, 1999.10189284
Shelton, D. Naming names. American Medical News 41(13):11, April 6, 1998.
Sherman, D.W., and Kirton, C.A. Hazardous terrain and over the edge: The survival of HIV-positive heterosexual, minority men. Journal of the Association of Nurses AIDS Care 9(4):23–34, 1998.
Sherman, D.W., and Ouellette, S. Moving beyond fear: Lessons learned through a longitudinal review of the literature regarding health care providers and the care of people with HIV/AIDS. Nursing Clinics of North America 34(1):1–48, 1999.9922278
Siegel, K., and Meyer, I.H. Hope and resilience in suicide ideation and behavior of gay and bisexual men following notification of HIV infection. AIDS Education and Prevention 11(1):53–64, 1999.10070589
Silverman, K.; Higgins, S.T.; Brooner, R.K.; Montoya, I.D.; Cone, E.J.; Schuster, C.R.; and Preston, K.L. Sustained cocaine abstinence in methadone maintenance patients through voucher-based reinforcement therapy. Archives of General Psychiatry 53:409–415, 1996.8624184
Simon, F.; Mauclere, P.; Roques, P.; Loussert-Ajaka, I.; Muller-Trutwin, M.C.; Saragosti, S.; Georges-Courbot, M.C.; Barre-Sinoussi, F.; and Brun-Vezinet, F. Identification of a new human immunodeficiency virus type 1 distinct from group M and group O. Nature Medicine 4(9):1032–1037, 1998.
Simonsen, J.N.; Cameron, D.W.; Gakinya, M.N.; Ndinya-Achola, J.O.; D'Costa, L.J.; Karasira, P.; Cheang, M.; Ronald, A.R.; Piot, P.; and Plummer, F.A. Human immunodeficiency virus infection among men with sexually transmitted diseases. Experience from a center in Africa. New England Journal of Medicine 319(5):274–278, 1988.3393182
Singer, E.J.; Zorilla, C.; Fahy-Chandon, B.; Chi, S.; Syndulko, K.; and Tourtellote, W.W. Painful symptoms reported by ambulatory HIV-infected men in a longitudinal study. Pain 54(1):15–19, 1993.8378098
Singh, H.; Squier, C.; Sivek, C.; Wagener, M.; Nguyen, M.H.; and Yu, V.L. Determinants of compliance with antiretroviral therapy in patients with human immunodeficiency virus: Prospective assessment with implcations for enhancing compliance. AIDS Care 8:261–269, 1996.8827119
Skinner, W.F. The prevalence and demographic predictors of illicit and licit drug use among lesbians and gay men. American Journal of Public Health 84:1307–1310, 1994.8059891
Slaikeu, K., and Lawhead, S. Up From the Ashes. Grand Rapids, MI: Zondervan, 1987.
Sonsel, G.E.; Paradise, F.; and Stroup, S. Case management practice in an AIDS service organization. Social Casework: The Journal of Contemporary Social Work 69(6):388–392, 1988.
Sorensen, J.L.; Batki, S.L.; Good, P.; and Wilkinson, K. Methadone maintenance program for AIDS-affected opiate addicts. Journal of Substance Abuse Treatment 6:87–94, 1989.2746716
Sorensen, J.L.; Costantini, M.F.; Wall, T.L.; and Gibson, D.R. Coupons attract high-risk untreated heroin users into detoxification. Drug and Alcohol Dependence 31(3):247–252, 1993.8384985
Soto, B.; Sanchez-Quijano, A.; Rodrigo, L.; del Olmo, J.A.; Garcia-Bengoechea, M.; Hernandez-Quero, J.; Rey, C.; Abad, M.A.; Rodriguez, M.; Sales, G.M.; Gilabert, M.; Gonzalez, F.; Miron, P.; Caruz, A.; Relimpio, F.; Torronteras, R.; Leal, M.; and Lissen, E. Human immunodeficiency virus infection modifies the natural history of chronic parenterally-acquired hepatitis C with an unusually rapid progression to cirrhosis. Journal of Hepatology 26(1):1–5, 1997.
St. Lawrence, J.S., and Brasfield, T.L. HIV risk behavior among homeless adults. AIDS Education and Prevention 7:22–31, 1995.7772454
Stall, R.D. The prevention of HIV infection associated with drug and alcohol use during sexual activity. Adv. Alcohol Subst Abuse 7(2):73–88, 1987.3448894
Stall, R.D.; Hoff, C.; Coates, T.J.; Paul, J.; Phillips, K.A.; Ekstrand, M.; Kegeles, S.; Catania, J.; Daigle, D.; and Diaz, R. Decisions to get HIV tested and to accept antiretroviral therapies among gay/bisexual men: Implications for secondary prevention efforts. Journal of AIDS and Human Retroviruses 11:151–160, 1996.
Stall, R.D.; McKusick, L.; Wiley J.; Coates, T.J.; and Ostrow, D.G. Alcohol and drug use during sexual activity and compliance with safe sex guidelines for AIDS: The AIDS Behavior Research Project. Health Education Quarterly 13:359–371, 1986.3781860
Stall, R.D.; Paul, J.P.; Barrett, D.C.; Crosby, G.M.; and Bein, E. An outcome evaluation to measure changes in sexual risk-taking among gay men undergoing substance use disorder treatment. Journal of Studies on Alcohol 60(6):837–845, 1999.10606497
Stall, R.D., and Wiley, J. A comparison of alcohol and drug use patterns of homosexual and heterosexual men: The San Francisco Men's Health Study. Drug and Alcohol Dependency 22:63–73, 1988.
Steer, R.A.; Iguchi, M.Y.; and Platt, J.J. Hopelessness in I.V. drug users not in treatment and seeking HIV testing and counseling. Drug and Alcohol Dependence 34(2):99–103, 1994.8026306
Stein, D.S.; Graham, N.M.; Park, L.P.; Hoover, D.R.; Phair, J.P.; Detels, R.; Ho, M.; and Saah, A.J. The effect of the interaction of acyclovir with zidovudine on progression to AIDS and survival. Analysis of data in the Multicenter AIDS Cohort Study. Annals of Internal Medicine 121(2):100–108, 1994.8017721
Stein, M.D. Injected drug use: Complications and costs in the care of hospitalized HIV infected patients. Journal of AIDS 7:469–473, 1994.
Stein, M.D.; Freedberg, K.A.; Sullivan, L.M.; Savetsky, J.; Levenson, S.M.; Hingson, R.; and Samet, J.H. Sexual ethics. Disclosure of HIV-positive status to partners. Archives of Internal Medicine 158:253–257, 1998.9472205
Stein, M.D.; O'Sullivan, P.S.; Ellis, P.; Perrin, H.; and Wartenberg, A. Utilization of medical services by drug abusers in detoxification. Journal of Substance Abuse 5:187–193, 1993.8104569
Stein, M.D., and Samet, J.H. Disclosure of HIV status. AIDS Patient Care and STDs 13:265–267, 1999.10356804
Stein, M.D.; Urdaneta, M.E.; and Clarke, J. Use of antiretroviral therapies by HIV-infected persons receiving methadone maintenance. Journal of Addictive Diseases 19(1):85–94, 2000.
Stimmel, B.; Vernace, S.; and Schaffner, F. Hepatitis B surface antigen and antibody. A prospective study in asymptomatic drug abusers. JAMA 234(11):1135–1138, 1975.810605
Stitzer, M.L.; Iguchi, M.Y.; and Felch, L.J. Contingent take-home incentive: Effects on drug use of methadone maintenance patients. Journal of Consulting and Clinical Psychology 60:927–934, 1992.1460154
Storms, D. “Healing the hurt: A conference on homphobia.” Paper presented at the Parents, Families, and Friends of Lesbians and Gays (PFLAG) Conference, Houston, TX, 1994.
Stoto, M.A.; Almario, D.A.; and McCormick, M.C. Reducing the Odds: Preventing Perinatal Transmission of HIV in the United States. Washington, DC: National Academy Press, 1998.
Strain, E.C.; Stitzer, M.L.; Liebson, I.A.; and Bigelow, G.E. Dose-response effects of methadone in the treatment of opioid dependence. Annals of Internal Medicine 119:23–27, 1993.8498759
Stryker, J. Correctional systems. In: Jonsen, A.R., and Stryker, J., eds. The Social Impact of AIDS in the United States. Washington, DC: National Academy Press, 1993. pp. 176–200.
Substance Abuse and Mental Health Services Administration. Summary of Findings from the 1998 National Household Survey on Drug Abuse. HHS Pub. No. (SMA) 99–3328. Washington, DC: Government Printing Office, 1999.
Support Center for Nonprofit Management and San Francisco Department of Public Health AIDS Office. Making the Connection: Standards of Practice for Client-Centered HIV Case Management. April 1996.
Susser, E.; Valencia, E.; and Conover, S. Prevalence of HIV infection among psychiatric patients in a New York City men's shelter. American Journal of Public Health 83:568–570, 1993.8460736
Thomas, S.B., and Quinn, S.C. The Tuskegee Syphilis Study, 1932 to 1972: Implications for HIV education and AIDS risk education programs in the black community. American Journal of Public Health 81(11):1498–1505, 1991.1951814
Tiihonen, J.; Ryynanen, O.P.; Kauhanen, J.; Hakola, H.P.; and Salaspuro, M. Citalopram in the treatment of alcoholism: A double-blind placebo-controlled study. Pharmacopsychiatry 29:27–29, 1996.8852531
Tondo, L.; Baldessarini, R.J.; Hennen, J.; Minnai, G.P.; Salis, P.; Scamonatti, L.; Masia, M.; Ghiani, C.; and Mannu, P. Suicide attempts in major affective disorder patients with comorbid substance use disorders. Journal of Clinical Psychiatry 60 (Suppl):63–69, 1999.10073390
Tong, T.G.; Pond, S.M.; Kreek, M.J.; Jaffery, N.F.; and Benowitz, N.L. Phenytoin-induced methadone withdrawal. Annals of Internal Medicine 94:349–351, 1981.7224382
Tuskegee Syphilis Study Legacy Committee. Report of the Tuskegee Syphilis Study Legacy Committee: Final Report. May 20, 1996.
Umbricht-Schneiter, A.; Ginn, D.H.; Pabst, K.M.; and Bigelow, G.E. Providing medical care to methadone clinic patients: Referral vs. on-site care. American Journal of Public Health 84:207–210, 1994.8296941
Urassa, M.; Todd, J.; Boerma, J.T.; Hayes, R.; and Isingo, R. Male circumcision and susceptibility to HIV infection among men in Tanzania. AIDS 11(3):73–80, 1997.
U.S. Bureau of the Census. Resident Population of the United States: Estimates, by Sex, Race, and Hispanic Origin, With Median Age. Washington, DC: U.S. Census Bureau, 1998.
U.S. Department of Health and Human Services. Needle Exchange Programs: Part of a Comprehensive HIV Prevention Strategy. Fact Sheet. Washington, DC: U.S. Department of Health and Human Services, 1998.
U.S. Department of Health and Human Services (HHS) and the Henry J Kaiser Family Foundation. Panel on Clinical Practices for Treatment of HIV Infection. Guidelines for the Use of Antiretroviral Agents in HIV-Infected Adults and Adolescents, 1997. Washington, DC: U.S. Department of Health and Human Services, 1998.
U.S. General Accounting Office. Drug Treatment: Despite New Strategy, Few Federal Inmates Receive Treatment. Report to the Committee on Government Operations, House of Representatives. GAO/HRD-91-128. Washington, DC: U.S. Government Printing Office, 1991.
U.S. General Accounting Office. Needle Exchange Programs: Research Suggests Promise as an AIDS Prevention Strategy. Report to the Chairman, Select Committee on Narcotics Abuse and Control. GAO/HRD-93-60. Washington, DC: U.S. Government Printing Office, 1993.
U.S. General Accounting Office. Drug Abuse: Research Shows Treatment Is Effective, But Benefits May Be Overstated. GAO/HEHS-98-72. Washington, DC: U.S. Government Printing Office, 1998.
Van Howe, R.S. Circumcision and HIV infection: Review of the literature and meta-analysis. International Journal of STD and AIDS 10(1):8–16, 1999.10215123
Vittinghoff, E.; Scheer, S.; O'Malley, P.; Colfax, G.; Holmberg, S.D.; and Buchbinder, S.P. Combination antiretroviral therapy and recent declines in AIDS incidence and mortality. Journal of Infectious Diseases 179(3):717–720, 1999.9952385
Volpicelli, J.R.; Alterman, A.I.; Hayashida, M.; and O'Brien, C.P. Naltrexone in the treatment of alcohol dependence. Archives of General Psychiatry 49:876–880, 1992.1345133
Wall, T.L.; Sorensen, J.L.; Batki, S.L.; Delucchi, K.L.; London, J.A.; and Chesney, M.A. Adherence to zidovudine (AZT) among HIV-infected methadone patients: A pilot study of supervised therapy and dispensing compared to usual care. Journal of Drug and Alcohol Dependence 37(3):261–269, 1995.7796721
Walsh, S.L.; Preston, K.L.; Stitzer, M.L.; Cone, E.J.; and Bigelow, G.E. Clinical pharmacology of buprenorphine: Ceiling effects at high doses. Clinical Pharmacology and Therapeutics 55:569–580, 1994.8181201
Ward, J.W., and Duchin, J.S. The epidemiology of HIV and AIDS in the United States. AIDS Clinical Review 1997–98:1–45, 1997-1998.
Wartenberg, A.A. HIV disease in the intravenous drug user: Role of the primary care physician. Journal of General Internal Medicine 6:S35–S40, 1991.2005476
Watters, J.K.; Downing, M.; Case, P.; Lorvick, J.; Cheng, Y.; and Fergusson, B. AIDS prevention for intravenous drug users in the community: Street-based education and risk behavior. American Journal of Community Psychology 18:587–596, 1990.2075893
Watters, J.K.; Estilo, M.J.; Clark, G.L.; and Lorvick, J. Syringe and needle exchange as HIV/AIDS prevention for injection drug users. JAMA 271:115–120, 1994.8264065
Weinberg, M.S., and Williams, C.J. Male Homosexuals; Their Problems and Adaptations. New York: Oxford University Press, 1974.
Weissman, G.; Melchior, L.; Huba, G.; Altice, F.; Booth, R.; Cottler, L.; Genser, S.; Jones, A.; McCarthy, S.; Needle, R.; and Smereck, G. Women living with substance abuse and HIV disease: Medical care access issues. Journal of the American Medical Women's Association 50(3–4):115–120, 1995.
Weissman, G.; Melchior, L.; Huba, G.; Smereck, G.; Needle, R.; McCarthy, S.; Jones, A.; Genser, S.; Cottler, L.; Booth, R.; and Altice, F. Women living with drug abuse and HIV disease: Drug abuse treatment access and secondary prevention issues. Journal of Psychoactive Drugs 27(4):401–411, 1995.8788695
White, J.C. HIV risk assessment and prevention in lesbians and women who have sex with women: Practical information for clinicians. Health Care for Women International 18(2):127–138, 1997.9119789
Wiebel, W.W.; Biernacki, P.; Mulia, N.; and Levin, L. Outreach to IDUs not in treatment. In: Brown, B.S., and Beschner, G.M., eds. Handbook on Risk of AIDS: Injection Drug Users and Sexual Partners. Westport, CT: Greenwood Press, 1993. pp. 437–444.
Wiegand, M.; Moller, A.A.; Schreiber, W.; Krieg, J.C.; and Holsboer, F. Alterations of nocturnal sleep in patients with HIV infection. Acta Neurologica Scandinavica 83(2):141–142, 1991.2017899
Wiley, J., and Samuel, M. Prevalence of HIV infection in the U.S.A. AIDS 3 (Suppl) 1:71–78, 1989.2469437
Wilkinson, C.W.; Crabbe, J.C.; Keith, L.D.; Kendall, J.W.; and Dorsa, D.M. Influence of ethanol dependence on regional brain content of beta-endorphin in the mouse. Brain Research 378:107–114, 1986.2943358
Wimbush, J.; Amicarelli, A.; and Stein, M. Does HIV test result influence methadone maintenance treatment retention? Journal of Substance Abuse 8:263–269, 1996.8880665
Winiarski, M.G. HIV Mental Health for the 21st Century. New York: New York University Press, 1997.
Withum, D.J. “High HIV prevalence among female and male entrants to U.S. correctional facilities (1989–1992): Implications for prevention and treatment strategies.” Paper presented at the 121st Annual Meeting of the American Public Health Association, San Francisco, CA, October 24–28, 1993.
Wittkowski, K.M.; Susser, E.; and Dietz, K. The protective effect of condoms and nonoxynol-9 against HIV infection. American Journal of Public Health 88(4):590–596, 1998.9551000
Wolitski, R.J.; MacGowan, R.J.; Higgins, D.L.; and Jorgensen, C.M. The effects of HIV counseling and testing on risk-related practices and help-seeking behavior. AIDS Education and Prevention 9(3 Suppl.): 52–67, 1997.9241398
Woods, W.J.; Avins, A.; Lindan, C.; Hudes, E.; Boscarino, J.; and Clark, W. Predictors of HIV-related risk behaviors among heterosexuals in alcoholism treatment. Journal of Studies on Alcohol 57:486–493, 1996.8858546
Woody, G.; O'Hare, K.; Mintz, J.; and O'Brien, C. Rapid intake: A method for increasing retention rate of heroin addicts seeking methadone treatment. Comprehensive Psychiatry 16:165–169, 1975.1120417
Word, C.O., and Bowser, B. Background to crack cocaine addiction and HIV high-risk behavior: The next epidemic. American Journal of Drug and Alcohol Abuse 23(1):67–77, 1997.9048148
World Health Organization. HIV and Infant Feeding: A Review of HIV Transmission Through Breastfeeding. Joint United Nations Programme on HIV/AIDS (UNAIDS), 1998.
Yerly, S.; Schockmel, G.; and Bru, J.P. Frequency of transmission of drug-resistant variants in individuals with primary HIV-1 infection (Abstract No. 32280). 12th World AIDS Conference, Geneva, Switzerland, 1998.
Youle, M.S.; Gazzard, B.G.; Johnson, M.A.; Cooper, D.A.; Hoy, J.F.; Busch, H.; Ruf, B.; Griffiths, P.D.; Stephenson, S.L.; and Dancox, M. Effects of high-dose oral acyclovir on herpesvirus disease and survival in patients with advanced HIV disease: A double-blind, placebo-controlled study. European-Australian Acyclovir Study Group. AIDS 8(5):641–649, 1994.8060544
Zagame, S.K. Letter to Peter J. Millock, General Counsel, Department of Health, State of New York, from the Acting General Counsel to the U.S. Department of Health and Human Services, May 17, 1989. In: Center for Substance Abuse Treatment. Confidentiality of Patient Records for Alcohol and Other Drug Treatment. Technical Assistance Publication (TAP) Series, Number 13. HHS Pub. No. (SMA) 95–3018. Washington, DC: U.S. Government Printing Office, 1995.
Zhu, T.; Korber, B.T.; Nahmias, A.J.; Hooper, E.; Sharp, P.M.; and Ho, D.D. An African HIV-1 sequence from 1959 and implications for the origin of the epidemic. Nature 391(6667):594–597, 1998.9468138
Ziebold, T.O., and Mongeon, J.E., eds. Gay and Sober: Directions for Counseling and Therapy. New York: Harrington Park Press, 1985.
Zolopa, A.R.; Hahn, J.A.; Gorter, R.; Miranda, J.; Wlodarczyk, D.; Peterson, J.; Pilote, L.; and Moss, A.R. HIV and tuberculosis infection in San Francisco's homeless adults. Prevalence and risk factors in a representative sample. JAMA 272(6):455–461, 1994.8040981