# TIP Development Participants

The information given indicates participants' affiliations at the time of their participation in this TIP's original development and may no longer reflect their current affiliations.

## Consensus Panel

Each Treatment Improvement Protocol's (TIP) consensus panel is a group of primarily nonfederal addiction-focused clinical, research, administrative, and recovery support experts with deep knowledge of the TIP's topic. With the Substance Abuse and Mental Health Services Administration's Knowledge Application Program team, members of the consensus panel develop each TIP via a consensus-driven, collaborative process that blends evidence-based, best, and promising practices with the panel members' expertise and combined wealth of experience.

## Chair

William R. Miller, Ph.D.
Regents Professor of Psychology and Psychiatry
Director of Research
Center on Alcoholism, Substance Abuse, and Addictions
Department of Psychology
University of New Mexico
Albuquerque, New Mexico

## Workgroup Leaders

Edward Bernstein, M.D., F.A.C.E.P.
Associate Professor and Academic Affairs
Vice Chairman
Boston University School of Medicine
Boston, Massachusetts

Suzanne M. Colby, Ph.D.
Assistant Professor of Psychiatry and Human Behavior
Center for Alcohol and Addiction Studies
Brown University
Providence, Rhode Island

Carlo C. DiClemente, Ph.D.
Department of Psychology
University of Maryland
Baltimore County
Baltimore, Maryland

Robert J. Meyers, M.A.
Center on Alcoholism, Substance Abuse, and Addictions
University of New Mexico
Albuquerque, New Mexico

Maxine L. Stitzer, Ph.D.
Professor of Psychiatry and Behavioral Biology
Johns Hopkins University School of Medicine
Baltimore, Maryland

Allen Zweben, D.S.W.
Director and Associate Professor of Social Work
Center for Addiction and Behavioral Health Research
University of Wisconsin at Milwaukee
Milwaukee, Wisconsin

## Panelists

Ray Daw
Executive Director
Northwest New Mexico Fighting Back, Inc.
Gallup, New Mexico

Jeffrey M. Georgi, M.Div., C.S.A.C., C.G.P.
Program Coordinator
Duke Alcoholism and Addictions Program
Clinical Associate
Department of Psychiatry and Behavioral Science
Duke University Medical Center
Durham, North Carolina

Cheryl Grills, Ph.D.
Department of Psychology
Loyola Marymount University
Los Angeles, California

Rosalyn Harris-Offutt, C.R.N.A., L.P.C., A.D.S.
UNA Psychological Associates
Greensboro, North Carolina

Don M. Hashimoto, Psy.D.
Clinical Director
Ohana Counseling Services, Inc.
Hilo, Hawaii

Dwight McCall, Ph.D.
Evaluation Manager
Substance Abuse Services
Virginia Department of Mental Health
Mental Retardation and Substance Abuse Services
Richmond, Virginia

Jeanne Obert, M.F.C.C., M.S.M.
Director of Clinical Services
Matrix Center
Los Angeles, California

Carole Janis Otero, M.A., L.P.C.C.
Director
Albuquerque Metropolitan Central Intake
Albuquerque, New Mexico

Roger A. Roffman, D.S.W.
Innovative Programs Research Group
School of Social Work
Seattle, Washington

Linda C. Sobell, Ph.D.
Professor
NOVA Southeastern University
Fort Lauderdale, Florida

## Field Reviewers, Resource Panel, and Editorial Advisory Board

Field reviewers represent each TIP's intended target audiences. They work in addiction, mental health, primary care, and adjacent fields. Their direct front-line experience related to the TIP's topic allows them to provide valuable input on a TIP's relevance, utility, accuracy, and accessibility. Additional advisors to this TIP include members of a resource panel and an editorial advisory board.

## Field Reviewers

Noel Brankenhoff, L.M.F.T., L.C.D.P.
Child and Family Services
Middletown, Rhode Island

Rodolfo Briseno, L.C.D.C.
Coordinator for Cultural/Special Populations and Youth Treatment Program Services
Program Initiatives Texas Commission on Alcohol and Drug Abuse
Austin, Texas

Richard L. Brown, M.D., M.P.H.
Associate Professor
Department of Family Medicine
University of Wisconsin School of Medicine
Madison, Wisconsin

Michael Burke
Senior Substance Abuse Specialist
Student Health Rutgers University
New Brunswick, New Jersey

Kate Carey, Ph.D.
Associate Professor
Department of Psychology Syracuse
University Syracuse, New York

Anthony J. Cellucci, Ph.D.
Director of Idaho State, University Clinic Associate, Professor of Psychology
Idaho State University
Pocatello, Idaho

Gerard Connors, Ph.D.
Research Institute on Alcoholism
Buffalo, New York

John Cunningham, Ph.D.
Scientist
Addiction Research Foundation Division
Centre for Addiction and Mental Health
Toronto, Ontario

Janie Dargan, M.S.W.
Senior Policy Analyst
Office of National Drug Control Policy/Executive
Office of the President
Washington, D.C.

George De Leon, Ph.D.
Center for Therapeutic Community Research
New York, New York

Nereida Diaz-Rodriguez, L.L.M., J.D.
Project Director
Director to the Master in Health Science in Substance Abuse
Centro de Entudion on Adiccion (Altos Salud Mental)
Edif. Hosp. Regional de Bayamon
Santa Juanita, Bayamon, Puerto Rico

Thomas Diklich
Portsmouth CSR
Portsmouth, Virginia

Chris Dunn, Ph.D., M.A.C., C.D.C.
Psychologist
Psychiatry and Behavioral Science
University of Washington
Seattle, Washington

Madeline Dupree, L.P.C.
Harrisonburg-Rockingham CSB
Harrisonburg, Virginia

Gary L. Fisher, Ph.D.
Nevada Addiction Technology Transfer Center
College of Education
University of Nevada at Reno
Reno, Nevada

Cynthia Flackus, M.S.W., L.I.C.S.W.
Therapist
Camp Share Renewal Center
Walker, Minnesota

Stephen T. Higgins, Ph.D.
Professor
Departments of Psychiatry and Psychology
University of Vermont
Burlington, Vermont

Col. Kenneth J. Hoffman, M.D., M.P.H., M.C.F.S.
Preventive Medicine Consultant
HHC 18th Medical Command
Seoul, South Korea

James Robert Holden, M.A.
Program Director
Partners in Drug Abuse Rehabilitation Counseling
Washington, D.C.

Ron Jackson, M.S.W.
Executive Director
Evergreen Treatment Services
Seattle, Washington

Linda Kaplan
Executive Director
National Association of Alcoholism and Drug
Abuse Counselors
Arlington, Virginia

Matthew Kelly, Ph.D.
Clinical Director
Robert Wood Johnson Foundation
Northwest Mexico Fighting Back, Inc.
Gallup, New Mexico

Karen Kelly-Woodall, M.S., M.A.C., N.C.A.C. II
Criminal Justice Coordinator
Cork Institute
Morehouse School of Medicine
Atlanta, Georgia

Richard Laban, Ph.D.
Laban's Training
Harrisburg, Pennsylvania

Lauren Lawendowski, Ph.D.
Acting Project Director
Center on Alcoholism
Substance Abuse and Addiction
University of New Mexico
Albuquerque, New Mexico

Bruce R. Lorenz, N.C.A.C. II
Director
Thresholds, Inc.
Dover, Delaware

Russell P. MacPherson, Ph.D., C.A.P., C.A.P.P., C.C.P., D.A.C., D.V.C.
President
RPM Addiction Prevention Training
Deland, Florida

George Medzerian, Ph.D.
Pensacola, Florida

Lisa A. Melchior, Ph.D.
Vice President
The Measurement Group
Culver City, California

Paul Nagy, M.S., C.S.A.C.
Director
Duke Alcoholism and Addictions Program
Duke University Medical Center
Durham, North Carolina

Tracy A. O'Leary, Ph.D.
Clinical Supervisor
Assistant Project Coordinator
Center for Alcohol and Addiction Studies
Brown University
Providence, Rhode Island

Gwen M. Olitsky, M.S.
CEO
The Self-Help Institute for Training and Therapy
Lansdale, Pennsylvania

Michele A. Packard, Ph.D.
Executive Director
SAGE Institute Training and Consulting
Boulder, Colorado

Michael Pantalon, Ph.D.
Yale School of Medicine
New Haven, Connecticut

Joe Pereira, L.I.C.S.W., C.A.S.
Recovery Strategies Medford, Massachusetts

Harold Perl, Ph.D.
Public Health Analyst
Division of Clinical and Prevention Research
National Institute on Alcohol Abuse and Alcoholism
Bethesda, Maryland

Raul G. Rodriguez, M.D.
Medical Director La Hacienda Treatment Center
Hunt, Texas

Richard T. Suchinsky, M.D.
Associate Director for Addictive Disorders and Psychiatric Rehabilitation
Mental Health and Behavioral Sciences Services
Department of Veterans Affairs
Washington, D.C.

Suzan Swanton, M.S.W.
Clinical Director
R.E.A.C.H. Mobile Home Services
Baltimore, Maryland

Michael J. Taleff, Ph.D., C.A.C., M.A.C., N.C.A.C.II
Assistant Professor and Coordinator
Graduate Programs in Chemical Dependency
Department of Counselor Education Counseling Psychology and Rehabilitation Services
Pennsylvania State University
University Park, Pennsylvania

Nola C. Veazie, Ph.D., L.P.C., C.A.D.A.C.
Superintendent
Medical Services Department
United States Air Force
Family Therapist/Drug and Alcohol Counselor
Veazie Family Therapy
Santa Maria, California

Mary Velasquez, Ph.D.
Psychology Department
University of Houston
Houston, Texas

Christopher Wagner, Ph.D.
Division of Substance Abuse Medicine Virginia Commonwealth
University Richmond, Virginia

## Resource Panel

Peter J. Cohen, M.D., J.D.
Adjunct Professor of Law
Georgetown University Law Center
Washington, D.C.

Frances Cotter, M.A., M.P.H.
Senior Public Health Advisor
Office of Managed Care
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services, Administration
Rockville, Maryland

Dorynne Czechowicz, M.D.
Associate Director
Division of Clinical and Services Research
Treatment Research Branch National Institute on Drug Abuse
Bethesda, Maryland

James G. (Gil) Hill
Director
Office of Substance Abuse
American Psychological Association
Washington, D.C.

Linda Kaplan
Executive Director
National Association of Alcoholism and Drug Abuse
Counselors, Arlington, Virginia

Pedro Morales, J.D.
Director
Equal Employment Civil Rights Substance Abuse and Mental Health Services
Administration, Rockville, Maryland

Harold I. Perl, Ph.D.
Public Health Analyst
Division of Clinical and Prevention Research
National Institute on Alcohol Abuse and Alcoholis
Bethesda, Maryland

Barbara J. Silver, Ph.D.
Center for Mental Health Services
Substance Abuse and Mental Health Services Administration
Rockville, Maryland

Lucretia Vigil
Policy Advisor
National Coalition of Hispanic Health and Human Services Organization
Washington, D.C.

## Editorial Advisory Board

Karen Allen, Ph.D., R.N., C.A.R.N.
Professor and Chair
Department of Nursing Andrews
University Berrien
Springs, Michigan

Richard L. Brown, M.D., M.P.H.
Associate Professor
Department of Family Medicine
University of Wisconsin School of Medicine
Madison, Wisconsin

Dorynne Czechowicz, M.D.
Associate Director
Medical/Professional Affairs
Treatment Research Branch
Division of Clinical and Services Research
National Institute on Drug Abuse
Rockville, Maryland

Linda S. Foley, M.A.
Former Director
Project for Addiction Counselor
Training National Association of State Alcohol and Drug Abuse Directors
Washington, D.C.

Wayde A. Glover, M.I.S., N.C.A.C. II
Director
Commonwealth Addictions Consultants and Trainers
Richmond, Virginia

Pedro J. Greer, M.D.
Assistant
Dean for Homeless Education
University of Miami School of Medicine
Miami, Florida

Thomas W. Hester, M.D.
Former State Director
Substance Abuse Services
Division of Mental Health
Mental Retardation and Substance Abuse
Georgia Department of Human Resources
Atlanta, Georgia

James G. (Gil) Hill, Ph.D.
Director
Office of Substance Abuse American Psychological Association
Washington, D.C.

Douglas B. Kamerow, M.D., M.P.H.
Director
Office of the Forum for Quality and Effectiveness in Health Care
Agency for Healthcare Research and Quality
Rockville, Maryland

Stephen W. Long
Director
Office of Policy Analysis, National Institute on Alcohol Abuse and Alcoholism
Rockville, Maryland

Richard A. Rawson, Ph.D.
Executive Director
Matrix Center and Matrix Institute on Addiction
Deputy Director, UCLA Addiction Medicine Services
Los Angeles, California

Ellen A. Renz, Ph.D.
Former Vice President of Clinical Systems
MEDCO Behavioral Care Corporation
Kamuela, Hawaii

Richard K. Ries, M.D.
Director and Associate Professor
Outpatient Mental Health Services and Dual Disorder Programs
Harborview Medical Center Seattle, Washington

Sidney H. Schnoll, M.D., Ph.D.
Chairman
Division of Substance Abuse Medicine
Medical College of Virginia
Richmond, Virginia