# Executive Summary

Motivation for change is a key component in addressing substance misuse. This Treatment Improvement Protocol (TIP) reflects a fundamental rethinking of the concept of motivation as a dynamic process, not a static client trait. Motivation relates to the probability that a person will enter into, continue, and adhere to a specific change strategy.

Although much progress has been made in identifying people who misuse substances and who have substance use disorders (SUDs) as well as in using science-informed interventions such as motivational counseling approaches to treat them, the United States still faces many SUD challenges. For example, the National Survey on Drug Use and Health (Substance Abuse and Mental Health Services Administration, 2018) reports that, in 2017, approximately:

• 140.6 million Americans ages 12 and older currently consumed alcohol, 66.6 million reported at least 1 episode of past-month binge drinking (defined as 5 or more drinks on the same occasion on at least 1 day in the past 30 days for men and 4 or more drinks on the same occasion on at least 1 day in the past 30 days for women), and 16.7 million drank heavily in the previous month (defined as binge drinking on 5 or more days in the past 30 days).
• 30.5 million people ages 12 and older had used illicit drugs in the past month.
• 11.4 million people ages 12 and older misused opioids (defined as prescription pain reliever misuse or heroin use) in the past year.
• 8.5 million adults ages 18 and older (3.4 percent of all adults) had both a mental disorder and at least 1 past-year SUD.
• 18.2 million people who needed SUD treatment did not receive specialty treatment.
• One in three people who perceived a need for substance use treatment did not receive it because they lacked healthcare coverage and could not afford treatment.
• Two in five people who perceived a need for addiction treatment did not receive it because they were not ready to stop using substances.

Millions of people in the United States with SUDs are not receiving treatment. Many are not seeking treatment because their motivation to change their substance use behaviors is low.

The motivation-enhancing approaches and strategies this TIP describes can increase participation and retention in SUD treatment and positive treatment outcomes, including:

• Reductions in alcohol and drug use.
• Higher abstinence rates.
• Successful referrals to treatment.

This TIP shows how SUD treatment counselors can influence positive behavior change by developing a therapeutic relationship that respects and builds on the client's autonomy. Through motivational enhancement, counselors become partners in the client's change process.

The TIP also describes different motivational interventions counselors can apply to all the stages in the Stages of Change (SOC) model related to substance misuse and recovery from addiction.

A consensus panel developed this TIP's content based on a review of the literature and on panel members' extensive experience in the field of addiction treatment. Other professionals also generously contributed their time and commitment to this project.

## Intended Audience

The primary audiences for this TIP are:

• Drug and alcohol treatment service providers.
• Mental health service providers, such as psychologists, licensed clinical social workers, and psychiatric/mental health nurses.
• Peer recovery support specialists.
• Behavioral health program managers, directors, and administrators.
• Clinical supervisors.
• Healthcare providers, such as primary care physicians, nurse practitioners, general/family medicine practitioners, registered nurses, internal medicine specialists, and others who may need to enhance motivation to address substance misuse in their patients.

Secondary audiences include prevention specialists, educators, and policymakers for SUD treatment and related services.

## Overall Key Messages

Motivation is key to substance use behavior change. Counselors can support clients' movement toward positive changes in their substance use by identifying and enhancing motivation that already exists.

Motivational approaches are based on the principles of person-centered counseling. Counselors' use of empathy, not authority and power, is key to enhancing clients' motivation to change. Clients are experts in their own recovery from SUDs. Counselors should engage them in collaborative partnerships.

Ambivalence about change is normal. Resistance to change is an expression of ambivalence about change, not a client trait or characteristic. Confrontational approaches increase client resistance and discord in the counseling relationship. Motivational approaches explore ambivalence in a nonjudgmental and compassionate way.

The Transtheoretical Model (TTM) of the SOC approach is an overarching framework that helps counselors tailor specific counseling strategies to different stages. Motivational counseling strategies should be tailored to clients' level of motivation to change their substance use behaviors at each of the five stages of the SOC:

• Precontemplation
• Contemplation
• Preparation
• Action
• Maintenance

Effective motivational counseling approaches can be brief. A growing body of evidence indicates that early and brief interventions demonstrate positive treatment outcomes in a wide variety of settings including specialty SUD treatment programs, primary care offices, and emergency departments. Brief interventions emphasize reducing the health-related risk of a person's substance use and decreasing consumption as an important treatment outcome.

Motivational interviewing (MI) and other motivational counseling approaches like motivational enhancement therapy are effective ways to enhance motivation throughout the SOC. Motivational counseling approaches are based on person-centered counseling principles that focus on helping clients resolve ambivalence about changing their substance use and other health-risk behaviors.

MI is the most widely researched and disseminated motivational counseling approach in SUD treatment. The spirit of MI (i.e., partnership, acceptance, compassion, and evocation) is the foundation of the core counseling skills required for enhancing clients' motivation to change. The core counseling skills of MI are described in the acronym OARS (Open questions, Affirmations, Reflective listening, and Summarization).

Counselor empathy, as expressed through reflective listening, is fundamental to MI. Use of empathy, rather than power and authoritative approaches, is critical for helping clients achieve and maintain lasting behavior change.

Adaptations of MI enhance the implementation and integration of motivational interventions into standard treatment methods. Training, ongoing supervision, and coaching of counselors are essential for workforce development and integration of motivational counseling approaches into SUD treatment.

## Content Overview

### Chapter 1—A New Look at Motivation

This chapter lays the groundwork for understanding treatment concepts discussed later in the TIP. It is an overview of the nature of motivation and its link to changing substance use behaviors. The chapter describes changing perspectives on addiction and addiction treatment in the United States and uses the TTM of the SOC approach as an overarching framework to understand how people change their substance use behaviors.

In Chapter 1, readers will learn that:

• Motivation is essential to substance use behavior change. It is multidimensional, dynamic, and fluctuating; can be enhanced; and is influenced by the counselor's style.
• Benefits of using motivational counseling approaches include clients' enhancing motivation to change, preparing them to enter treatment, engaging and retaining clients in treatment, increasing their participation and involvement in treatment, improving their treatment outcomes, and encouraging a rapid return to treatment if they start misusing substances again.
• New perspectives on addiction treatment include focusing on clients' strengths instead of deficits, offering person-centered treatment, shifting away from labeling clients, using empathy, focusing on early and brief interventions, recognizing that there is a range of severity of substance misuse, accepting risk reduction as a legitimate treatment goal, and providing access to integrated care.
• People go through stages in the SOC approach; this concept is known as the TTM of change.
• The stages in the SOC model are:
  - Precontemplation, in which people are not considering change.
  - Contemplation, in which people are considering change but are unsure how to change.
  - Preparation, in which people have identified a change goal and are forming a plan to change.
  - Action, in which people are taking steps to change.
  - Maintenance, in which people have met their change goal and the behavior change is stable.

### Chapter 2—Motivational Counseling and Brief Intervention

This chapter is an overview of motivational counseling approaches, including screening, brief intervention, and referral to treatment (SBIRT). It describes elements of effective motivational counseling approaches, including FRAMES (Feedback, Responsibility, Advice, Menu of options, Empathy, and Self-efficacy), decisional balancing, discrepancy development, flexible pacing, and maintenance of contact with clients. The chapter describes counselors' focus in each stage of the SOC model. It addresses special applications of motivational counseling with clients from diverse cultures and with clients who have co-occurring substance use and mental disorders (CODs).

In Chapter 2, readers will learn that:

• Each stage in the SOC approach has predominant experiential and behavioral catalysts for client change on which counselors should focus.
• Counselors should adopt the principles of cultural responsiveness and adapt motivational interventions to those principles when treating clients from diverse backgrounds.
• Even mild substance misuse can impede functioning in people with CODs, including co-occurring severe mental illness. Counselors can adapt motivational interventions for these clients.
• Brief motivational interventions, including SBIRT, are effective in specialty SUD treatment facilities and opportunistic settings (e.g., primary care offices, emergency departments).
• Brief interventions emphasize risk reduction and referral to specialty addiction treatment if needed.

### Chapter 3—Motivational Interviewing as a Counseling Style

This chapter provides an overview of the spirit of MI, the principles of person-centered counseling, the core counseling skills of MI (i.e. asking open questions, affirming, reflective listening, and summarizing), and the four processes of MI (i.e., engaging, focusing, evoking, and planning). It describes what's new in MI and dispels many misconceptions about MI. The chapter discusses the components that counselors use to help clients resolve ambivalence and move toward positive substance use behavior change.

In Chapter 3, readers will learn that:

• Ambivalence about substance use and change is normal and a motivational barrier to substance use behavior change, if not explored.
• The spirit of MI embodies the principles of person-centered counseling and is the basis of an empathetic, supportive counseling style.
• Sustain talk is essentially statements the client makes for not changing (i.e., maintaining the status quo), and change talk is statements the client makes in favor of change. The key to helping the client move in the direction toward changing substance use behaviors is to evoke change talk and soften or lessen the impact of sustain talk on the client's decision-making process.
• The acronym OARS describes the core skills of MI:
  - Asking Open questions
  - Affirming the client's strengths
  - Using Reflective listening
  - Summarizing client statements
• Reflective listening is fundamental to person-centered counseling in general and MI in particular and is essential for expressing empathy.
• The four processes in MI (i.e., engaging, focusing, evoking, and planning) provide an overarching framework for employing the core skills in conversations with a client.
• The benefits of MI include its broad applicability to diverse medical and behavioral health problems and its capacity to complement other counseling approaches and to mobilize client resources.

### Chapter 4—From Precontemplation to Contemplation: Building Readiness

This chapter discusses strategies counselors can use to help clients raise doubt and concern about their substance use and move toward contemplating the possibility of change. It emphasizes the importance of assessing clients' readiness to change, providing personalized feedback to them about the effects and risks of substance misuse, involving their significant others in counseling to raise concern about clients' substance use behaviors, and addressing special considerations for treating clients who are mandated to treatment.

In Chapter 4, readers will learn that:

• A client in the Precontemplation stage is unconcerned about substance use or is not considering change.
• The counselor's focus in Precontemplation is to establish a strong counseling alliance and raise the client's doubts and concerns about substance use.
• Key strategies in this stage include eliciting the client's perception of the problem, exploring the events that led to entering treatment, and identifying the client's style of Precontemplation.
• Providing personalized feedback on assessment results and involving significant others in counseling sessions are key strategies for raising concern and moving the client toward contemplating change.
• Special considerations in motivational counseling approaches for clients mandated to treatment include acknowledging client ambivalence and emphasizing personal choice and responsibility.

### Chapter 5—From Contemplation to Preparation: Increasing Commitment

This chapter describes strategies to increase clients' commitment to change by normalizing and resolving ambivalence and enhancing their decision-making capabilities. It emphasizes decisional balancing and exploring clients' self-efficacy as important to moving clients toward preparing to change substance use behaviors. Summarizing change talk and exploring the client's understanding of change prepare clients to take action.

In Chapter 5, readers will learn that:

• In the Contemplation stage, the client acknowledges concerns about substance use and is considering the possibility of change.
• The counselor's focus in Contemplation is to normalize and resolve client ambivalence and help the client tip the decisional balance toward changing substance use behaviors.
• Key motivational counseling strategies for resolving ambivalence include reassuring the client that ambivalence about change is normal; evoking DARN (Desire, Ability, Reasons, and Need) change talk; and summarizing the client's concerns.
• To reinforce movement toward change, the counselor reinforces the client's understanding of the change process, reintroduces personalized feedback, explores client self-efficacy, and summarizes client change talk.
• The counselor encourages the client to strengthen his or her commitment to change by taking small steps, going public, and envisioning life after changing substance use behaviors.

### Chapter 6—From Preparation to Action: Initiating Change

This chapter describes the process of helping clients identify and clarify change goals. It also focuses on how and when to develop change plans with clients and suggests ways to ensure that plans are accessible, acceptable, and appropriate for clients.

In Chapter 6, readers will learn that:

• In the Preparation stage, the client is committed and planning to make a change but is unsure of what to do next. In the Action stage, the client is actively taking steps to change but has not reached stable recovery.
• In Preparation, the counselor focuses on helping the client explore change goals and develop a change plan. In Action, the counselor focuses on supporting client action steps and helping the client evaluate what is working and not working in the change plan.
• The client who is committed to change and who believes change is possible is prepared for the Action stage.
• Sobriety sampling, tapering down, and trial moderation are goal-sampling strategies that may be helpful to the client who is not committed to abstinence as a change goal.
• Creating a change plan is an interactive process between the counselor and client. The client should determine and drive change goals.
• Identifying and helping the client reduce barriers to the Action stage are important to the change-planning process.
• Counselors can support client action by reinforcing client commitment and continuing to evoke and reflect CAT (i.e., Commitment, Activation, and Taking steps) change talk in ongoing conversations.

### Chapter 7—From Action to Maintenance: Stabilizing Change

This chapter addresses ways in which motivational strategies can be used effectively to help clients maintain the gains they have made by stabilizing change, supporting lifestyle changes, managing setbacks during the Maintenance stage, and helping them reenter the cycle of change if they relapse or return to substance misuse. It emphasizes creating a coping plan to reduce the risk of recurrence in high-risk situations, identifying new behaviors that reinforce change, and establishing relapse prevention strategies.

In Chapter 7, readers will learn that:

• During the Maintenance stage, the client has achieved the initial change goals and is working toward maintaining those changes.
• In Maintenance, the counselor focuses on helping the client stabilize change and supports the client's lifestyle changes.
• During a relapse, the client returns to substance misuse and temporarily exits the change cycle. The counselor focuses on helping the client reenter the cycle of change and providing relapse prevention counseling in accordance with the principles of person-centered counseling.
• Maintenance of substance use behavior change in the SOC model must address the issue of relapse. Relapse should be reconceptualized as a return to or recurrence of substance use behaviors and viewed as a common occurrence.
• Relapse prevention counseling is a cognitive-behavioral therapy (CBT) method, but the counselor can use motivational counseling strategies to engage the client in the process and help the client resolve ambivalence about learning and practicing new coping skills.
• Strategies to help a client reenter the change cycle after a recurrence include affirming the client's willingness to reconsider positive change, exploring reoccurrence as a learning opportunity, helping the client find alternative coping strategies, and maintaining supportive contact with the client.

### Chapter 8—Integrating Motivational Approaches in SUD Treatment Settings

This chapter discusses some of the adaptations of motivational counseling approaches applicable to SUD treatment programs and workforce development issues that treatment programs should address to fully integrate and sustain motivational counseling approaches. It emphasizes blending MI with other counseling approaches. It also explores ways in which ongoing training, supervision, and coaching are essential to successful workforce development and integration.

In Chapter 8, readers will learn that:

• Integrating motivational counseling approaches into a treatment program requires a broad integration of the philosophy and underlying spirit of MI throughout the organization.
• Adapted motivational interventions may be more cost effective, accessible to clients, and easily integrated into existing treatment approaches than expected and may ease some workload demands on counselors.
• Technology adaptations, including motivational counseling and brief interventions over the phone or via text messaging, are effective, cost effective, and adaptable to different client populations.
• MI is effective when blended with other counseling approaches including group counseling, the motivational interviewing assessment, CBT, and recovery management checkups.
• The key to workforce development is to train all clinical and support staffs in the spirit of MI so that the entire program's philosophy is aligned with person-centered principles, like emphasizing client autonomy and choice.
• Program administrators should assess the organization's philosophy and where it is in the SOC model before implementing a training program.
• Training counseling staff in MI takes more than a 1- or 2-day workshop. Maintenance of skills requires ongoing training and supervision.
• Supervision and coaching in MI should be competency based. These activities require directly observing the counselor's skill level and using coding instruments to assess counselor fidelity. Supervision should be performed in the spirit of MI.
• Administrators need to balance training, supervision, and strategies to enhance counselor fidelity to MI with costs, while partnering with counseling staff to integrate a motivational counseling approach throughout the organization.