# Chapter 6—From Preparation to Action: Initiating Change

“The Preparation stage of change entails developing a plan of action and creating the commitment needed to implement that plan. Decisions do not translate automatically into action. To change a behavior, one needs to focus attention on breaking the old pattern and creating a new one. Planning is the activity that organizes the environment and develops the strategies for making change.”

—DiClemente, 2018, pp. 29–30

KEY MESSAGES

• During the Preparation stage, clients are considering possible paths toward changing substance use behaviors and beginning to take small steps to reach the final change goal.
• You can support clients' movement from Preparation to Action by exploring client change goals and helping them develop a change plan.
• You can maintain a client-centered focus by eliciting clients' change goals and not imposing goals on them.

Chapter 6 describes the process of identifying and clarifying change goals. It also focuses on how and when to develop a change plan with the client and suggests ways to ensure a sound plan by offering the client a menu of options, contracting for change, identifying and lowering barriers to action, and enlisting social support. This chapter also describes your tasks while the client moves into the Action stage, like helping the client initiate the plan and evaluating the effectiveness of the plan.

In earlier stages of the Stages of Change (SOC) approach, you use motivational strategies to increase clients' readiness. In Preparation, you use motivational strategies to strengthen clients' commitment and help them make a firm decision to change. Clients who commit to change and believe change is possible are prepared for the Action stage. Clients who are actively taking steps to change substance use behaviors have better long-term outcomes after treatment than clients who have not reached this stage of the SOC (Heather & McCambridge, 2013).

Your task is to help clients set clear goals for change in preparation for developing a change plan. Changing any longstanding behavior requires preparation and planning. Clients must see change as being in their best interest before they can move into the Action stage. Developing a change plan that is accessible, acceptable, and appropriate for each client is key. The negative consequences of ignoring the Preparation stage can be a brief course of action followed by rapid return to substance use. By the end of the Preparation stage, clients should have a plan for change that guides them into the Action stage.

Exhibit 6.1 presents counseling strategies for Preparation and Action.

EXHIBIT 6.1. Counseling Strategies for Preparation and Action

SOC | CLIENT MOTIVATION | COUNSELOR FOCUS | COUNSELING STRATEGIES
Preparation | The client is committed and planning to make a change in the near future but is still considering what to do. | • Explore client change goals.; • Develop a change plan. | • Clarify the client's own goals.; • Sample goals; encourage experimenting.; • Elicit change strategies from the client.; • Offer a menu of change options.; • Negotiate a behavioral contract.; • Explore and lower barriers to action.; • Enlist social support.
Action | The client actively takes steps to change but is not yet stable. | • Support the client's action steps.; • Evaluate the change plan. | • Help the client determine which change strategies are working and which are not.; • Change the strategies as needed.

## Explore Client Change Goals

Once the client has decided to make a positive change and the commitment is clear, goals should be set. Setting goals is part of the exploring and envisioning activities in the early and middle parts of the Preparation stage. Having summarized and reviewed the client's decisional considerations, you should now be prepared to ask about ways in which the client might want to address some of the reasons to change listed on the positive side of the decisional balance sheet. The process of talking about and setting goals strengthens commitment to change.

### Clarify the Client's Goals

Help the client set goals that are as realistic and specific as possible and that address the concerns he or she described earlier about substance use. The client may set goals in multiple areas, not just substance use. He or she may work toward goals such as regaining custody of children, getting a job, becoming financially independent, leaving an abusive relationship, and returning to school. The client who sets several goals may need help deciding which to focus on first.

Early on, goals should be short term, measurable, and realistic so that clients can begin measuring success and feeling good about themselves as well as hopeful about the change.

If goals seem unreachable to you, discuss your concerns. Use OARS (Open questions, Affirmations, Reflective listening, and Summarization) to help clients clarify their goals, decide on which goal to focus first, and identify steps to achieving their goals. For example, if one goal is to get a job, you can start with an open question: “What do you think is the first step toward meeting this goal?” The goal is the vision, and the steps are the specific tasks that clients perform to meet the goal.

Setting goals is a joint process. The counselor and client work together, moving from general ideas and visions to specific goals. Seeing how the client sets goals and the types of goals he or she sets provides information on the client's sense of self-efficacy, level of commitment, and readiness for change. The more hopeful a client feels about the future, the more likely he or she is to achieve treatment goals.

Make identifying and clarifying treatment goals a client-driven process. Doing so is consistent with the principles of person-centered counseling and the spirit of motivational interviewing (MI). It is up to the client to decide what actions to take or treatment options to seek to address a substance use problem. Matching the client to the preferred substance use disorder (SUD) treatment options can help reduce alcohol consumption and improve drug-related outcomes (Friedrichs, Spies, Härter, & Buchholz, 2016). In a systematic review, brief motivational alcohol interventions for adolescents had significantly larger effects on alcohol consumption if they included goal-setting exercises (Tanner-Smith & Lipsey, 2015).

Your task is to help clients identify their preferred change goals and to enhance their decision making by teaching them about their treatment options. (See Chapter 3 for more information about and strategies for identifying change goals using MI.)

Remember that the client's preferred treatment goals may not match what you prefer. A client might choose a course of action with which you do not agree or that is not in line with the treatment agency's policies. A decision to reduce but not completely stop substance use, for example, may go against the agency's policy of zero tolerance for illicit substance use. Exhibit 6.2 offers some strategies for addressing these types of situations.

Client refusing to listen to counselor

EXHIBIT 6.2. When Treatment Goals Differ

What do you do when the client's goals differ from yours or those of your agency? This issue arises in all behavioral health services but especially in a motivational approach, where you listen reflectively to a client and actively involve him or her in decision making. As you elicit goals for change and treatment, a client may not choose goals that you think are right for him or her.

Before exploring different ways of handling this common situation, try to clarify how the client's goals and your own (or your agency's goals) do not match. For a client, goals are by definition the objectives he or she is motivated (ready, willing, and able) to work toward. If the client is not motivated to work toward it, it is not a goal. You or your agency, however, may have specific plans or hopes for the client. You cannot push your hopes and plans onto the client. This situation can become an ethical problem if you focus too much on trying to get a client to change in the direction of your or the agency's goals (Miller & Rollnick, 2013).

What are your clinical options when goals differ? You can choose from the following strategies:

• Negotiate (i.e., figure out how to work out the differences)
  - Rework the agenda and be open about your concerns as well as your hopes for the client (Miller & Rollnick, 2013).
  - Find goals on which you and the client can agree, and work together on those.
  - Start with areas in which the client is motivated to change. Women with alcohol or drug use disorders, for example, often come to treatment with a wide range of other problems, many of which they see as more pressing than making a change in substance use.
  - Start with the problems that the client feels are most urgent, and then address substance use when its relationship to other problems becomes obvious.
• Approximate (i.e., try to find an agreed-on goal that is similar)
  - Even if a client is not willing to accept your recommendations, consider the possibility of agreeing on a goal that is still a step in the right direction. Your hope, for example, might be that the client would eventually become free from all psychoactive substance use. The client, however, is most concerned about cocaine and is not ready to talk about changing cannabis, tobacco, or alcohol use.
  - Rather than dismiss the client for not accepting a goal of immediate abstinence from all substances, focus on stopping cocaine use, and then consider next steps.
• Refer
  - If you can't help the client with treatment goals even after trying to negotiate or approximate, refer the client to another provider or program.
  - Work within state licensing and professional ethical codes to avoid suddenly ending treatment.
  - Offer a menu of options, and take an active role in linking the client to other treatment and community-based services.
  - Be open in a nonjudgmental and neutral way about the fact that you cannot help the client with his or her treatment goal (Moyers & Houck, 2011).

### Sample Goals and Encourage Experimenting

You may need to help some clients sample or try out their goals before getting them to commit to long-term change. For instance, some clients benefit from experimenting with abstinence or cutting down their substance use for a short period. The following approaches to goal sampling may be helpful for clients who are not committed to abstinence as a change goal:

• Sobriety sampling. This trial period of abstinence is commonly used with clients who (Boston Center for Treatment Development and Training [BCTDT], 2016):
  - Are not interested in abstinence as a treatment goal.
  - Express significant need or desire to address misuse but are not ready to commit to abstinence.
  - Have had many past unsuccessful attempts at moderate use.
  A successful trial of sobriety sampling can enhance clients' commitment to a goal of abstinence. Even a 2-to-3-week period of abstinence before treatment can lead to positive client outcomes, including reductions in alcohol misuse (Gueorguieva et al., 2014). However, longer periods of trial abstinence may give clients more of an opportunity to experience the benefits of abstinence, like clearer thinking, a better ability to recognize substance use triggers, and more time to experience the positive feeling of living without substance use (BCTDT, 2016).
• Tapering down. This approach has been widely used with people who smoke to reduce physical dependence and cravings before the quit date and is an option for some substances like alcohol or cannabis. This approach consists of setting increasingly lower daily and weekly limits on use of the substance while working toward a long-range goal of abstinence. The client keeps careful daily records of consumption and schedules sessions with the counselor as needed. Tapering off opioids, benzodiazepines, or multiple substances should be done under medical supervision.
• Trial moderation. Trial moderation (i.e., clients try to reduce substance use with careful monitoring) may be the only acceptable goal for some clients who are in Precontemplation. Don't assume that clients will fail at moderation; however, if the moderation experiment fails after a reasonable effort, try to get clients to reconsider abstinence as a change goal. Clients can gain insight into their ability to reduce their substance use, and many will ultimately decide to abstain if they cannot reduce their use without negative consequences. Research indicates that clients whose goal is moderation have larger social networks of people who drink daily (Gueorguieva et al., 2014). Therefore, you should address clients' drinking social network as a potential barrier to moderation as a long-term goal.

## Develop a Change Plan

Your final step in readying the client to act is to work with him or her in creating a plan for change. (Chapter 3 provides a summary of MI-specific strategies for developing a change plan.) Think of a change plan as a roadmap for the client to reach his or her change goals. A solid plan for change enhances the client's self-efficacy and provides an opportunity to consider potential barriers and the likely outcomes of each change strategy. As mentioned in Chapter 3, some clients need no structured change plan.

Use these strategies to work with clients to create a sound change plan:

• Elicit change strategies from the client.
• Offer a menu of change options.
• Negotiate a behavioral contract.
• Explore and lower barriers to action.
• Enlist social support.

### Elicit Change Strategies From the Client

Work with clients to develop a change plan by eliciting their own ideas about what will work for them. This approach is a particularly helpful if clients have made past attempts to address substance use behaviors or have been in treatment before. For example, you might begin with a reflection of commitment talk and follow with an open question: “You clearly think that giving up cocaine is the best thing for you right now. What steps do you think you can take to reach this goal?”

Help clients create plans to match their concerns and goals. Plans will differ among clients:

• The plan can be very general or very specific and can be short term or long term.
• Some clients can commit only to a very limited plan, like going home, thinking about change, and returning on a specific date to talk further. Even a small, short-term plan like this can include specific steps for helping clients avoid high-risk situations as well as identifying specific coping strategies.
• Some plans are very simple, such as stating only that clients will enter outpatient treatment and attend an Alcoholics Anonymous (AA) meeting every day.
• Other plans include details (e.g., transportation to treatment, new ways to spend weekends).
• Many plans include specific steps to overcome anticipated barriers to success (Exhibit 6.3). Some plans lay out a sequence of steps. For example, working mothers with children who must enter inpatient treatment may develop a sequenced plan for arranging for child care.

Client and counselor talking

EXHIBIT 6.3. Change Plan Worksheet

Create a change plan using a joint process in which you and the client work together. One of your most important tasks is to ensure that the plan is realistic and can be carried out. When the client offers a plan that seems unrealistic, too ambitious, or not ambitious enough, use shared decision making to rework the plan. The following areas are often part of such discussions:

• Intensity and amount of help needed. Encourage participation in community-based recovery support groups (e.g., AA, Narcotics Anonymous [NA], SMART Recovery, Women for Sobriety), enrolling in intensive outpatient treatment (IOP), or entering a 2-year therapeutic community.
• Timeframe. Choose a short-term rather than a long-term plan and a start date for the plan.
• Available social support. Discuss who will be involved in treatment (e.g., family, Women for Sobriety members, community members), where it will take place (e.g., at home, in the community), and when it will occur (e.g., after work, weekends, twice a week).
• The order of subgoals and strategies or steps in the plan. For example:
  1. Stop dealing marijuana.
  2. Stop smoking marijuana.
  3. Call friends or family to tell them about the plan.
  4. Visit friends or family who know about the plan.
  5. Learn relaxation techniques.
  6. Use relaxation techniques when feeling stressed at work.
• Ways to address multiple problems. Consider legal, financial, and health problems, among others.

Clients may ask you for information and advice about specific steps to add to the plan. You should:

• Ask permission to offer advice.
• Use the Elicit-Provide-Elicit (EPE) approach to keep the client in the center of the conversation (see the section “Developing discrepancy: A values conversation” in Chapter 3).
• Provide accurate and specific facts, and always ask whether they understand them.
• Elicit responses to such information by asking, “What do you think about this?”

The last step in EPE is key to completing the information exchange between you and the client.

How specific should you be when clients ask what you think they should do? Providing your best advice is an important part of your role. It is also appropriate to share your own views and opinions, although it is helpful to “soften” your statements and give clients permission to disagree. For example, you might soften your suggestion by saying, “This may or may not work for you, but a lot of people find it helpful to go to NA meetings to meet others who are trying to stay away from cocaine.” Other techniques of MI, such as developing discrepancy, empathizing, and avoiding arguments, also are useful during this process.

The Change Plan Worksheet in Exhibit 6.3 helps clients focus their attention on the details of the plan, increase commitment to change, enlist social support, and troubleshoot potential roadblocks to change.

Use the Importance and Confidence Rulers in Exhibit 3.9 and Exhibit 3.10 to determine the client's readiness and self-efficacy about each change goal. These tools can help you and the client determine which goals to address first and which strategies to begin with. Ideally, the top goal will be one with higher ratings on both importance and confidence. If the client rates one goal as high in importance and low in confidence, focus on exploring self-efficacy and evoking confidence talk to prepare the client for taking action.

### Offer a Menu of Change Options

Enhance clients' motivation to take action by offering them a variety of treatment choices.

Choices can be about treatment options or about other types of services. For example, clients who will not go to AA meetings might be willing to go to a Rational Recovery, SMART Recovery, or Women for Sobriety group; clients who will not consider abstinence might be willing to decrease their consumption. Encourage clients to learn about their options and make informed choices to enhance their commitment to the change plan.

EXPERT COMMENT: TREATMENT OPTIONS AND RESOURCES

In our alcohol treatment program, I found that having lists of both community resources and diverse treatment modules helps counselors and case managers engage clients, offer individualized programming, and meet clients' multiple needs. The following are some options we offer our clients:

Treatment Module Options

• Values clarification/decision making
• Social-skills training (e.g., assertiveness, communication)
• Anxiety management/relaxation
• Anger management
• Marital and family therapy
• Adjunctive medication (i.e., disulfiram, naltrexone, or acamprosate)
• Problem-solving groups
• Intensive group therapy

Community Treatment Resources

• Halfway houses
• Support groups (e.g., AA, NA, Rational Recovery, SMART Recovery, Women for Sobriety)
• Social services (e.g., child care, vocational rehabilitation, food, shelter)
• Medical care
• Transportation
• Legal services
• Psychiatric services
• Academic and technical schools

Carlo C. DiClemente, Ph.D., Consensus Panel Member

Know your community's treatment facilities and resources. This helps you provide clients with suitable options and makes you an invaluable resource for clients. Offer clients information on:

• Specific contact people.
• Program graduates.
• Typical space availability.
• Funding issues.
• Eligibility criteria.
• Program rules and characteristics.
• Community resources in other service areas, such as:
  - Food banks
  - Job training programs
  - Special programs for clients with co-occurring medical and mental disorders
  - Safe shelters for clients experiencing intimate partner violence

In addition, knowledge about clients' resources, insurance coverage, job situation, parenting responsibilities, and other factors is crucial in considering options. Initial assessment information also helps establish treatment options and priorities.

When discussing treatment options with clients, be sure to:

• Provide basic information in simple language about levels, intensities, and appropriateness of care.
• Avoid professional jargon and technical terms for treatment types or philosophies.
• Limit options to several that are appropriate, and describe these, one at a time, in language that is understandable and matches clients' concerns.
• Describe the purpose of a particular treatment, how it works, and what clients can expect.
• Ask clients to wait to make a decision about treatment until they understand all the options.
• Ask clients if they have questions, and ask their opinions about how to handle each option.
• Review the concept of the SOC; note that it is common for people to go through the stages several times as they move closer to maintaining substance use behavior change and stable recovery.
• Remind clients that not completing a treatment program and returning to substance use are not failures, but opportunities to reevaluate which change strategies are working or not working.
• Point out that, with all the options, they are certain to find some form of treatment that will work.
• Reassure clients that you are willing to work with them until they find the right choice.

Exhibit 6.4 provides a change-planning strategy for situations with many possible change options.

EXHIBIT 6.4. Mapping a Path for Change When There Are Multiple Options

• Confirm the change goal. If there are action steps to meet the change goal, decide which step to take first. For example, the client's goal might be to stop drinking completely. Some action steps might include talking with a healthcare provider about medication, going to an AA meeting, and telling a spouse about the decision. Which step does the client think is most important?
• Make a list of the change options available to the client (e.g., inpatient treatment, community-based recovery support groups, IOP treatment, a sober living house or therapeutic community, medication-assisted treatment).
• Elicit the client's feelings, preferences, or both on the best way to proceed. For example, ask, “Here are the different options we have discussed that might work for you. Which one do you like the most?” You can also discuss the pros and cons of different options (i.e., perform a decisional balance).
• Summarize the plan and strengthen commitment. Summarize the action steps and change goal, then evoke and reflect CAT (Commitment, Activation, and Taking steps) change talk.
• Troubleshoot. Explore barriers to taking steps; raise any concerns about how realistic the plan is. Avoid the expert trap (see Chapter 3), and elicit the client's own ideas about how to manage barriers to change.

Carlo C. DiClemente, Ph.D., Consensus Panel Member

### Negotiate a Behavioral Contract

Develop a written or oral contract to help clients start working on their change plans. A contract is a formal agreement between two parties. Clients may choose to make a signed statement at the bottom of the Change Plan Worksheet or may prefer a separate document. Be sure to:

• Explain that others have found contracts useful at this stage, and invite them to try writing one.
• Avoid writing contracts for clients. Composing and signing it is a small but important ritual of “going public” that can enhance commitment (Connors, DiClemente, Velasquez, & Donovan, 2013).
• Encourage clients to use their own words.
• Be flexible. With some clients, a handshake is a good substitute for a written contract, particularly with clients who have challenges with reading and writing or whose first language is not English.

Establishing a contract raises issues for discussion about the client's reasons for change. What parties does the contract involve? Some contracts include the counselor as a party in the contract, specifying the counselor's functions and responsibilities. Other clients regard the contract as a promise to themselves, to a spouse, or to other family members.

Contracts are often used in treatment programs that employ behavioral techniques, such as contingency management (CM). For many counselors, contracts mean contingencies (i.e., rewards and consequences), and programs often build contingencies into the structure of their programs. For example, in many methadone maintenance programs, take-home medications are contingent on substance-free urinalyses. Rewards or incentives have been shown to be highly effective external reinforcers. For instance, CM rewards are effective in reducing use and misuse of a range of substances including alcohol, tobacco, cannabis, and stimulants, as well as polysubstance use (Ainscough, McNeill, Strang, Calder, & Brose, 2017; Litt, Kadden, & Petry, 2013; Sayegh, Huey, Zara, & Jhaveri, 2017).

Clients may decide to include contingencies, especially rewards or positive incentives, in the contract. Rewards can:

• Be highly individual.
• Include enjoyable activities, favorite foods, desired objects, or rituals and ceremonies, all of which can be powerful objective markers of change and reinforcers of commitment.
• Be tied to length of abstinence, quit-date anniversaries, or achievement of subgoals. For instance:
  - A client may plan an afternoon at a baseball game with her son to celebrate a month of abstinence.
  - One client might go out to dinner with friends after attending his 50th AA meeting.
  - Another client may light a candle at church.
  - Still another client might hike to the top of a nearby mountain to mark an improvement in energy and health.

### Explore and Lower Barriers to Action

One category in the Change Plan Worksheet in Exhibit 6.3 addresses possible obstacles to change and ways to handle them. Identifying barriers to action is an important part of the change plan. Potential roadblocks to taking action on change goals might include:

• A lack of non-substance-using social supports.
• Unsupportive family members.
• Co-occurring medical or mental disorders.
• Distressing side effects from medication-assisted treatment or psychiatric medications.
• Physical cravings or withdrawal symptoms.
• Legal issues, money-related problems, or both.
• Lack of child care.
• Transportation issues.
• A lack of cultural responsiveness of some agencies, programs, or services.

Clients can predict some barriers better than you can, so allow them to identify and discuss possible problems. Specifically:

• Do not try to predict everything that could go wrong.
• Focus on events or situations that are likely to be problematic.
• Build alternatives and solutions into the plan.
• Before offering advice, explore clients' ideas about how they might handle issues as they arise.
• Explore the ways clients may have overcome these or similar barriers in the past. This is a way to open a conversation about their strengths and coping skills.

Some problems are evident immediately. For instance, a highly motivated client may plan to attend an IOP treatment program 50 miles away 3 times a week, even though this requires bus and train rides and late-night travel. Explore the pros and cons of this part of the change plan with the client, and brainstorm alternative solutions, like finding a program closer to home or a family member, case manager, peer support specialist, or program volunteer who can drive the client to the program. Remember, the change plan should include strategies that are accessible, acceptable, and appropriate for each client.

You may need to refer clients to another treatment program or other services following initial consultation or evaluation, but this too is another common barrier to action. When you refer clients:

• Ensure they have information about how to get to the program, whom and when to telephone, and what to expect on the call (e.g., what type of personal information may be requested).
• Give them any “insider information” you have about the program or provider, which can reduce clients' anxiety and makes the process easier. For example, you may know that the receptionist at the program is a friendly person or that many people get lost by entering the building on the wrong side or that a nearby diner serves good food.
• Use active linkage and referral interventions, which enhance client engagement and retention in SUD treatment and ancillary services and improve outcomes (Rapp, Van Den Noortgate, Broekaert, & Vanderplasschen, 2014). Strategies for active referral procedures include:
  - Helping the client make the telephone call to set up the intake appointment at the chosen program. Some clients may want to make the phone call from your office; others might wish to call from home and call you later to tell you that they made an appointment. Some clients prefer to think things over first and make the call from your office at the next session.
  - Following up with clients and the program, if possible and with client permission, to ensure that clients are connected to the new service.
  - Offering a “warm handoff,” if possible, which involves introducing clients to the new provider.
  - Linking clients to a case manager, peer recovery support specialist, program alumnus, or community-based recovery support group volunteer to act as a liaison and actively engage clients in treatment programs; social, legal, or employment services; or community-based recovery support programs.

### Enlist Social Support

Help clients enlist social support and build or enhance social networks that support recovery from SUDs. Positive social support for substance use behavior change is an important factor in clients' initiating and sustaining behavior change (Black & Chung, 2014; Fergie et al., 2018; Rhoades et al., 2018).

As a counselor, you are a central support for clients, but you cannot provide all the support they need. In general, a supportive person is someone who will listen and not be judgmental. This supportive person should have a helpful and encouraging attitude toward clients. Ideally, this person does not use or misuse substances and understands the processes of addiction and change. The Change Plan Worksheet (Exhibit 6.3) includes space for listing supportive individuals and describing how they can help. As discussed in Chapter 4, concerned significant others can offer support by learning some MI skills (e.g., offering simple reflective listening responses, becoming effective partners in change).

Encourage clients to include social support strategies in their change plans. These include:

• Engaging in activities with friends that don't involve substance use. Social support often entails participating in non-substance use activities, so close friends with whom clients have a history of shared interests other than substance use are good candidates for this helpful role. Members of social groups who drink and use drugs are not likely to offer the support clients need in recovery.
• Repairing or resuming connections with supportive family members and significant others. Clients can find supportive people among their family members and close friends as well as in faith-based and spiritual organizations, recreational centers, and community volunteer organizations. To make these connections, encourage clients to explore and discuss a time in their lives before substance use became a central focus. Ask them what gave meaning to their lives at that time.
• Participating in AA or other recovery support groups. Recovery groups provide clients with social support for behavior change, positive role models of recovery, recovering friendship networks, and hope that recovery is possible. Research confirms that participation in AA is associated with positive alcohol-related, psychological, and social outcomes (Humphreys, Blodgett, & Wagner, 2014).
• Connecting with addiction-focused peer support. Peer recovery support specialists can be recovery role models and an important source of social support for clients. Client participation in peer recovery support services with a peer specialist leads to positive social support and improved substance use outcomes, including decreased alcohol use and hospitalizations as well as better adherence to treatment goals after discharge (Bassuk, Hanson, Greene, Richard, & Laudet, 2016). Oxford Houses and similar sober living housing options have built-in social support systems.
• Connecting clients with a case manager. For some clients, especially those with chronic medical or serious mental illness, case management teams provide a sense of safety, structure, and support. A case manager can also actively link clients to community-based social services, federal and state financial assistance, and other ancillary services that support clients' recovery efforts.

When helping clients enlist social support, be particularly alert for clients who have limited social skills or social networks. Some clients may have to learn social skills and ways to structure leisure time. Add social skill-building steps into the change plan. Some clients may not be connected to any social network that is not organized around substance use. Furthermore, addiction may have so narrowed their focus to the point where they have trouble recalling activities that once held their interest or appealed to them. However, most people have unfulfilled desires to pursue an activity at some time in their lives. Ask about these wishes. One client may want to learn ballroom dancing, another to learn a martial art, or still another to take a creative writing class. Planning for change can be a particularly productive time for clients to reconnect with this desire to find fulfilling activities, and seeking such activities provides opportunities for making new friends.

Clients with a carefully drafted change plan, knowledge of both high-risk situations and potential barriers to getting started, and a group of supportive friends, family members, or recovery supports should be fully prepared and ready to move into the Action stage.

## Support the Client's Action Steps

DiClemente (2018) describes four main tasks for client in the Action stage of the SOC:

1. Breaking free of the addiction using the strategies in the change plan
2. Continuing commitment to change and establishing a new pattern of behavior
3. Managing internal/external barriers to change (e.g., physical cravings, lack of positive social support)
4. Revising and refining the change plan

Your role is to continue using motivational counseling approaches to support the client in completing these tasks and moving into the Maintenance stage and stable recovery. To support clients in breaking free of substance use behaviors:

• Encourage clients to set a specific start date for each behavior change (e.g., a smoking quit date, date to enter an inpatient addiction treatment program). Setting a start date increases commitment.
• Help clients create rituals that symbolize them leaving old behaviors behind. For example, some clients may make a ritual of burning or disposing of substance paraphernalia, cigarettes, beer mugs, or liquor. Support clients in creating personally meaningful rituals. As mentioned previously, picking up a chip at an AA meeting is a ritual that supports clients' action steps toward abstinence and a new lifestyle.

To reinforce clients' commitment to change:

• Continue to evoke and reflect CAT change talk in your ongoing conversations with clients.
• Use reflective listening, summaries, and affirmations.
• Manage barriers to change by identifying those barriers (as described above in the section “Explore and Lower Barriers to Action”), working with clients to brainstorm personally relevant strategies for lowering or reducing the impact of those barriers, and offering a menu of treatment options. For example, if a client experiences intense alcohol or drug cravings, you might explore the possibility of referring the client to a medical provider for a medication evaluation, encouraging participation in a mindfulness meditation group, or both.
• Evaluate, revise, and refine the change plan as the final step in the Action stage.

## Evaluate the Change Plan

Your goal of this stage of the change cycle is to help the client sustain successful actions for a long enough time that he or she gains stability and moves into Maintenance (Connors et al., 2013). It is not likely that you and the client will be able to predict all of the issues that will come up as the client initiates the change plan. The client's circumstances likely will change (e.g., a spouse might file for divorce), unanticipated issues arise (e.g., the client's drug-using social network might put pressure on the client to return to drug use), and change strategies may not turn out to work well for the client (e.g., the client loses his or her driver's license and has to find alternative transportation to NA meetings). These unanticipated issues can become a barrier to sustaining change plan actions and may require revisions to the change plan (Connors et al., 2013).

Your task is to work with the client at each encounter to evaluate the change plan and revise it as necessary. Ask the client, “What's working?” and “What's not working?” Miller and Rollnick (2013) suggest that counselors think about this process as “flexible revisiting.” The same strategies used in the planning process of MI apply to revising the change plan, including confirming the change goal, eliciting the client's ideas about how to change, offering a menu of options, summarizing the change plan, and exploring obstacles (see Chapter 3). Some strategies for change may need to be removed, whereas others can be adjusted. For example, one client's goal is to quit drinking, and her action steps include attending three AA meetings a week, including one women's meeting. The client stops going to the women's meeting because one of the regular attendees is a coworker who likes to gossip, and the client is afraid that the coworker will break her anonymity at work. Your first step is to identify the issue, and then elicit the client's ideas about what else might work for her.

Open questions to start this process if a change strategy is not working include (Miller & Rollnick, 2013):

• “What now?”
• “What else might work?”
• “What's your next step?”

Avoid jumping in too quickly with your own ideas. Adjusting a change plan, like creating the initial change plan, is a joint process between you and the client; the client's own ideas and resources are key (Miller & Rollnick, 2013). Finally, summarize the new change strategy and explore how the client might respond to any new obstacles that might come up while initiating the revised change plan (Miller & Rollnick, 2013).

## Conclusion

As clients move from contemplating change into preparing for change, your task is to continue to reinforce clients' commitment to change and take action. You can support clients to take this next step by working together to develop a change plan, imagining possible barriers to change that might occur, and enlisting social support for taking action. Change plans are client driven and based on clients' own goals. Continue to use motivational counseling strategies to help clients identify and clarify their change goals, develop a change plan, and refine and revise the change plan as needed. Your role is to help clients sustain their goals for change, gain stability, and move into the Maintenance stage of the SOC.