# Appendix C—Resources

## Motivational Interviewing and Motivational Enhancement Therapy

Motivational Interviewing Network of Trainers (MINT) (www.motivationalinterviewing.org). This website includes links to publications, motivational interviewing (MI) assessment and coding resources, and training resources and events.

Motivational Enhancement Therapy Manual (https://casaa.unm.edu/download/met.pdf). This manual describes the history of motivational enhancement therapy (MET) and its use in Project MATCH. It provides an overview of MET, its relationship to the stages of change, the structure of MET sessions, and a thorough review of the assessment and personalized feedback process used in MET.

Institute for Research, Education & Training in Addictions Motivational Interviewing Toolkit (https://ireta.org/resources/motivational-interviewing-toolkit). This website provides educational materials about MI and links to no-cost MI resources.

## Stages of Change

Health and Addictive Behaviors: Investigating Transtheoretical Solutions Lab at the University of Maryland, Baltimore County (https://habitslab.umbc.edu). This website provides an overview of the Transtheoretical Model of behavior change, printable assessments and scoring information, related publications, and learning tools.

## Training and Supervision

Motivational Interviewing Assessment: Supervisory Tools for Enhancing Proficiency Manual (www.motivationalinterviewing.org/sites/default/files/mia-step.pdf). This collection of tools is for mentoring counselors in MI skills used in the engagement and assessment stage of counseling people with substance use disorders (SUDs). It includes teaching tools, counselor self-assessment skill summaries, MI rating guides and forms, transcripts and ratings of sample MI interviews, and trainer instructions.

Center on Alcoholism, Substance Abuse, and Addictions (https://casaa.unm.edu). This multidisciplinary research center at the University of New Mexico provides links to alcohol and drug assessment tools, MI coding tools and therapist manuals, and audio files and uncoded transcripts of counselor role plays that can be used for training.

Motivational Interviewing Resources (https://motivationalinterviewing.org/motivational-interviewing-resources). This MINT webpage provides links to downloadable coding manuals for assessing counselor fidelity to the MI spirit and practice skills including the Manual for the Motivational Interviewing Skill Code (MISC) (https://casaa.unm.edu/download/misc.pdf), the MISC 2.5 (https://casaa.unm.edu/download/misc25.pdf), the Motivational Interviewing Treatment Integrity Coding Manual 4.2.1 (https://motivationalinterviewing.org/sites/default/files/miti42.pdf), and the Assessment of Motivational Interviewing Groups—Observer Scale (AMIGOS-v 1.2) (https://motivationalinterviewing.org/sites/default/files/amigosratingformv1.2.pdf)

## Substance Abuse and Mental Health Services Administration

Screening, Brief Intervention, and Referral to Treatment (SBIRT) (www.samhsa.gov/sbirt). This website has information on dissemination and implementation of SBIRT and additional resources.

Substance Abuse and Mental Health Services Administration-Health Resources and Services Administration Center for Integrated Health Solutions (www.integration.samhsa.gov). The Center for Integrated Health Solutions promotes development of integrated primary and behavioral health services to better address the needs of people with mental disorders and SUDs, whether they are seen in specialty behavioral health or primary care settings. This website provides information and resources on screening tools (www.integration.samhsa.gov/clinical-practice/screening-tools), motivational interviewing (www.integration.samhsa.gov/clinical-practice/motivational-interviewing), and tobacco cessation (www.integration.samhsa.gov/health-wellness/wellness-strategies/tobacco-cessation-2).

Treatment Improvement Protocol (TIP) 63: Medications for Opioid Use Disorder (https://store.samhsa.gov/product/TIP-63-Medications-for-Opioid-Use-Disorder-Full-Document-Including-Executive-Summary-and-Parts-1-5-/SMA18-5063FULLDQC). This TIP reviews the use of the three Food and Drug Administration-approved medications used to treat opioid use disorder— methadone, naltrexone, and buprenorphine—and other strategies and services to support recovery.

TIP 60: Using Technology-Based Therapeutic Tools in Behavioral Health Services (https://store.samhsa.gov/product/TIP-60-Using-Technology-Based-Therapeutic-Tools-in-Behavioral-Health-Services/SMA15-4924). This TIP provides information on implementing technology-assisted care. It discusses the importance of technology in reducing access to treatment and highlights the importance of using technology-based assessments and interventions in behavioral health services.

TIP 59: Improving Cultural Competence (https://store.samhsa.gov/product/TIP-59-Improving-Cultural-Competence/SMA15-4849). This TIP helps providers and administrators understand the role of culture in the delivery of mental health and substance use services. It describes cultural competence and discusses racial, ethnic, and cultural considerations.

TIP 57: Trauma-Informed Care in Behavioral Health Services (https://store.samhsa.gov/product/TIP-57-Trauma-Informed-Care-in-Behavioral-Health-Services/SMA14-4816). This TIP helps behavioral health professionals understand the impact of trauma on clients. It discusses patient assessment and treatment planning strategies. These strategies support recovery and building a trauma-informed care workforce.

TIP 52: Clinical Supervision and Professional Development of the Substance Abuse Counselor (https://store.samhsa.gov/product/TIP-52-Clinical-Supervision-and-Professional-Development-of-the-Substance-Abuse-Counselor/SMA14-4435.html). This TIP presents guidelines for clinical supervision in SUD treatment. It covers supervision methods and models, cultural competence, ethical and legal issues, performance monitoring, and an implementation guide for program administrators.

TIP 42: Substance Abuse Treatment for Persons With Co-Occurring Disorders (https://store.samhsa.gov/product/TIP-42-Substance-Abuse-Treatment-for-Persons-With-Co-Occurring-Disorders/SMA13-3992). This TIP gives SUD providers information on co-occurring mental and substance use disorders. It discusses terminology, assessment, and treatment strategies and models.

TIP 39: Substance Abuse Treatment and Family Therapy (https://store.samhsa.gov/product/TIP-39-Substance-Abuse-Treatment-and-Family-Therapy/SMA15-4219). This TIP describes the integration of family counseling approaches into SUD treatment. It also discusses cultural competency, considerations for specific populations, policy and program issues, and guidelines for assessing violence.