# Appendix B—Screening and Assessment Instruments

Appendix B presents the following tools:

1. U.S. Alcohol Use Disorders Identification Test (U.S. AUDIT)
2. Drug Abuse Screening Test (DAST-10)
3. Drinker Inventory of Consequences (DrInC) (Lifetime)
4. What I Want From Treatment (2.0)
5. Readiness to Change Questionnaire (Treatment Version (RCQ-TV) (Revised)
6. Stages of Change Readiness and Treatment Eagerness Scale-Alcohol (SOCRATES 8A)
7. Stages of Change Readiness and Treatment Eagerness Scale-Drugs (SOCRATES 8D)
8. University of Rhode Island Change Assessment (URICA) Scale
9. Alcohol and Drug Consequences Questionnaire (ADCQ)
10. Alcohol Decisional Balance Scale
11. Drug Use Decisional Balance Scale
12. Brief Situational Confidence Questionnaire (BSCQ)
13. Alcohol Abstinence Self-Efficacy Scale (AASES)
14. Motivational Interviewing Knowledge Test

1. U.S. Alcohol Use Disorders Identification Test (AUDIT)

2. Drug Abuse Screening Test (DAST-10)

3. Drinker Inventory of Consequences (DrInC) (Lifetime)

4. What I Want From Treatment (2.0)

5. Readiness to Change Questionnaire (Treatment Version) (RCQ-TV) (Revised)

6. Stages of Change Readiness and Treatment Eagerness Scale-Alcohol (SOCRATES 8A)

7. Stages of Change Readiness and Treatment Eagerness Scale-Drug (SOCRATES 8D)

8. University of Rhode Island Change Assessment (URICA) Scale

9. Alcohol and Drug Consequences Questionnaire (ADCQ)

10. Alcohol Decisional Balance Scale

11. Drug Use Decisional Balance Scale

12. Brief Situational Confidence Questionnaire (BSCQ)

13. Alcohol Abstinence Self-Efficacy Scale (AASES)

14. Motivational Interviewing Knowledge Test