# Appendix A—Bibliography

Ager, R., Roahen-Harrison, S., Toriello, P. J., Kissinger, P., Morse, P., Morse, E. … Rice, J. (2010). Predictors of adopting motivational enhancement therapy. Research on Social Work Practice, 27(1), 65–76. doi:10.1177/1049731509353170
Ainscough, T. S., McNeill, A., Strang, J., Calder, R., & Brose, L. S. (2017). Contingency management interventions for non-prescribed drug use during treatment for opiate addiction: A systematic review and meta-analysis. Drug and Alcohol Dependence, 178, 318–339.28688295
Alcoholics Anonymous. (2001). Alcoholics Anonymous: The story of how many thousands of men and women have recovered from alcoholism (4th ed.). New York, NY: Alcoholics Anonymous World Services.
Aldridge, A., Dowd, W. & Bray, J. (2017). The relative impact of brief treatment versus brief intervention in primary health-care screening programs for substance use disorders. Addiction, 112, 54–64. doi:10.1111/add.13653 28074568
Aldridge, A., Linford, R., & Bray, J. (2017). Substance use outcomes of patients served by a large U.S. implementation of screening, brief intervention and referral to treatment (SBIRT). Addiction, 112, 43–53.28074561
Alperstein, D., & Sharpe, L. (2016). The efficacy of motivational interviewing in adults with chronic pain: A meta-analysis and systematic review. Journal of Pain, 77(4), 393–403. doi:10.1016/j.jpain.2015.10.021
American Psychiatric Association. (2013). Diagnostic and statistical manual of mental disorders (5th ed.). Washington, DC: Author.
American Psychiatric Association. (1994). Diagnostic and statistical manual of mental disorders (4th ed.). Washington, DC: Author.
Amodeo, M. (2015). The addictive personality. Substance Use and Misuse, 50(8-9), 1031–1036. doi:10.3109/10826084.2015.1007646 25774829
Anderson, T., Crowley, M. E., Himawan, L., Holmberg, J. K., & Uhlin, B. D. (2016). Therapist facilitative interpersonal skills and training status: A randomized clinical trial on alliance and outcome. Psychotherapy Research, 26(5), 511–529. doi:10.1080/10503307.2015.1049671 26344392
Apodaca, T. R., Borsari, B., Jackson, K. M., Magill, M., Longabaugh, R., Mastroleo, N. R., & Barnett, N. P. (2014). Sustain talk predicts poorer outcomes among mandated college student drinkers receiving a brief motivational intervention. Psychology of Addictive Behaviors, 28(3), 631–638. doi:10.1037/a0037296 25222170
Apodaca, T. R., Jackson, K. M., Borsari, B., Magill, M., Longabaugh, R., Mastroleo, N. R., & Barnett, N. P. (2016). Which individual therapist behaviors elicit client change talk and sustain talk in motivational interviewing? Journal of Substance Abuse Treatment, 61, 60–65. doi:10.1016/j.jsat.2015.09.001 26547412
Apodaca, T. R., & Longabaugh, R. (2009). Mechanisms of change in motivational interviewing: A review and preliminary evaluation of the evidence. Addiction, 104(5), 705–715. doi:10.1111/j.1360-0443.2009.02527.X 19413785
Apodaca, T. R., Magill, M., Longabaugh, R., Jackson, K. M., & Monti, P. M. (2013). Effect of a significant other on client change talk in motivational interviewing. Journal of Consulting and Clinical Psychology, 87(1), 35–46. doi:10.1037/a0030881
Appiah-Brempong, E., Okyere, P., Owusu-Addo, E., & Cross, R. (2014). Motivational interviewing interventions and alcohol abuse among college students: A systematic review. American Journal of Health Promotion, 29(1). doi:10.4278/ajhp.130502-lit-222
Arkowitz, H., Miller, W. R. & Rollnick, S. (2015). Motivational interviewing in the treatment of psychological problems (2nd ed.). New York, NY: Guilford Publications.
Babor, T. F., Del Boca, F. D., & Bray, J. W. (2017). Screening, brief intervention and referral to treatment: Implications of SAMHSA's SBIRT initiative for substance abuse policy and practice. Addiction, 112, 110–117. doi:10.1111/add.13675 28074569
Babor, T. F., Higgins-Biddle, J. C., & Robaina, K. (2016). USAUDIT: The Alcohol Use Disorders Identification Test, Adapted for use in the United States: A guide for primary care practitioners. Retrieved from www.ct.gov/dmhas/lib/dmhas/publications/USAUDIT-2017.pdf
Babor, T. F., Higgins-Biddle, J. C., Saunders, J. B., & Monteiro, M. G. (2001). The Alcohol Use Disorders Identification Test: Guidelines for use in primary care (2nd ed.). Geneva, Switzerland: World Health Organization.
Bachiller, D., Grau-López, L., Barrai, C., Daigre, C., Alberich, C., Rodríguez-Cintas, L., … Roncero, C. (2015). Motivational interviewing group at inpatient detoxification: Its influence in maintaining abstinence and treatment retention after discharge. Adicciones, 27(2), 109–118.26132300
Baker, A. L., Kavanagh, D. J., Kay-Lambkin, F. J., Hunt, S. A., Lewin, T. J., Carr, V. J., & McElduff, P. (2014). Randomized controlled trial of MICBT for co-existing alcohol misuse and depression: Outcomes to 36-months. Journal of Substance Abuse Treatment, 46(3), 281–290.24210534
Baker, A. L., Thornton, L. K., Hiles, S., Hides, L., & Lubman, D. I. (2012). Psychological interventions for alcohol misuse among people with co-occurring depression or anxiety disorders: A systematic review. Journal of Affective Disorders, 139(3), 217–229. doi:10.1016/j.jad.2011.08.004 21890213
Bandura, A. (1977). Self-efficacy: Toward a unifying theory of behavioral change. Psychological Review, 84, 191–215.847061
Barata, I. A., Shandro, J. R., Montgomery, M., Polansky, R., Sachs, C. J., Duber, H. C., … Macias-Konstantopoulos, W. (2017). Effectiveness of SBIRT for alcohol use disorders in the emergency department: A systematic review. Western Journal of Emergency Medicine, 18(6), 1143–1152.29085549
Barbosa, C., Cowell, A., Dowd, W., Landwehr, J., Aldridge, A., & Bray, J. (2017). The cost-effectiveness of brief intervention versus brief treatment of screening, brief intervention and referral to treatment (SBIRT) in the United States. Addiction, 112, 73–81. doi:10.1111/add.13658
Barnes, R. D., & Ivezaj, V. (2015). A systematic review of motivational interviewing for weight loss among adults in primary care. Obesity Reviews, 16(4), 304–318. doi:10.1111/obr.12264 25752449
Barnett, E., Moyers, T. B., Sussman, S., Smith, C., Rohrbach, L. A., Sun, P., & Spruijt-Metz, D. (2014). From counselor skill to decreased marijuana use: Does change talk matter? Journal of Substance Abuse Treatment, 46, 498–505.24462244
Barnett, E., Spruijt-Metz, D., Moyers, T. B., Smith, C., Rohrbach, L. A., Sun, P., & Sussman, S. (2014). Bidirectional relationships between client and counselor speech: The importance of reframing. Psychology of Addictive Behaviors, 28(4), 1212–1219. doi:10.1037/a0036227 24955660
Barrio, P., & Gual, A. (2016). Patient-centered care interventions for the management of alcohol use disorders: A systematic review of randomized controlled trials. Patient Preference and Adherence, 10, 1823–1845. doi:10.2147/PPA.S109641 27695301
Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9. doi:10.1016/j.jsat.2016.01.003 26882891
Bedard-Gilligan, M., Garcia, N., Zoellner, L. A., & Feeny, N. C. (2018). Alcohol, cannabis, and other drug use: Engagement and outcome in PTSD treatment. Psychology of Addictive Behaviors, 32(3), 277–288.29595297
Belmontes, K. C. (2018). When family gets in the way of recovery. Family Journal, 26(1), 99–104. doi:10.1177/1066480717753013
Bernstein, S. L., & D'Onofrio, G. (2017). Screening, treatment initiation, and referral for substance use disorders. Addiction Science and Clinical Practice, 12(1). doi:10.1186/s13722-017-0083-z
Bertholet, N., Palfai, T., Gaume, J., Daeppen, J., & Saitz, R. (2013). Do brief alcohol motivational interventions work like we think they do? Alcoholism: Clinical and Experimental Research, 38(3), 853–859. doi:10.1111/acer.12274 24125097
Beutler, L. E., Harwood, T. M., Michelson, A., Song, A., & Holman, J. (2011). Resistance/reactance level. Journal of Clinical Psychology, 67(2), 133–142.21108314
Black, J. J., & Chung, T. (2014). Mechanisms of change in adolescent substance use treatment: How does treatment work? Substance Abuse, 35(4), 344–351.24901750
Blow, F. C., Walton, M. A., Bohnert, A. S., Ignacio, R. V., Chermack, S., Cunningham, R. M., … Barry, K. L. (2017). A randomized controlled trial of brief interventions to reduce drug use among adults in a low-income urban emergency department: The HealthiER You study. Addiction, 112(8), 1395–1405. doi:10.1111/add.13773 28127808
Bohnert, A. S. B., Bonar, E. E., Cunningham, R., Greenwald, M. K., Thomas, L., Chermack, S., … Walton, M. (2016). A pilot randomized clinical trial of an intervention to reduce overdose risk behaviors among emergency department patients at risk for prescription drug overdose. Drug and Alcohol Dependence, 163, 40–47.27062245
Borsari, B., Apodaca, T. R., Jackson, K. M., Fernandez, A., Mastroleo, N. R., Magill, M., … Carey, K. B. (2018). Trajectories of in-session change language in brief motivational interventions with mandated college students. Journal of Consulting and Clinical Psychology, 86(2), 158–168. doi:10.1037/ccp0000255 29172594
Boston Center for Treatment Development and Training. (2016). Module 10: Sobriety sampling. Retrieved from www.mass.gov/fìles/documents/2016/07/ty/bt-manual-module10.pdf
Bourke, E., Magill, M., & Apodaca, T. R. (2016). The in-session and long-term role of a significant other in motivational enhancement therapy for alcohol use disorders. Journal of Substance Abuse Treatment, 64, 35–43. doi:10.1016/j.jsat.2016.01.008 26951920
Bray, J. W., Aden, B., Eggman, A. A., Hellerstein, L., Wittenberg, E., Nosyk, B., … Schackman, B. R. (2017). Quality of life as an outcome of opioid use disorder treatment: A systematic review. Journal of Substance Abuse Treatment, 76, 88–93.28190543
Breslin, F. C., Sobell, L. C., Sobell, M. B., & Agrawal, S. (2000). A comparison of a brief and long version of the Situational Confidence Questionnaire. Behaviour Research and Therapy, 38(12), 1211–1220.11104185
Brorson, H. H., Arnevik, E. A., Rand-Hendriksen, K., & Duckert, F. (2013). Drop-out from addiction treatment: A systematic review of risk factors. Clinical Psychology Review, 33(8), 1010–1024. doi:10.1016/j.cpr.2013.07.007 24029221
Caperton, D. D., Atkins, D. C., & Imel, Z. E. (2018). Rating motivational interviewing fidelity from thin slices. Psychology of Addictive Behaviors, 32(4), 434–441. doi:10.1037/adb0000359 29723012
Carey, K. B., Leontieva, L., Dimmock, J., Maisto, S. A., & Batki, S. L. (2007). Adapting motivational interventions for comorbid schizophrenia and alcohol use disorders. Clinical Psychology, 14(1), 39–57.19081784
Carroll, K. M., Ball, S. A., Nich, C., Martino, S., Frankforter, T. L., Farentinos, C., … Woody, G. E. (2006). Motivational interviewing to improve treatment engagement and outcome in individuals seeking treatment for substance abuse: A multisite effectiveness study. Drug and Alcohol Dependence, 81, 301–312.16169159
Caviness, C. M., Hagerty, C. E., Anderson, B. J., Dios, M. A., Hayaki, J., Herman, D., & Stein, M. D. (2013). Self-efficacy and motivation to quit marijuana use among young women. American Journal on Addictions, 22(4), 373–380. doi:10.1111/j.1521-0391.2013.12030 23795877
Chariyeva, Z., Golin, C. E., Earp, J. A., Maman, S., Suchindran, C., & Zimmer, C. (2013). The role of self-efficacy and motivation to explain the effect of motivational interviewing time on changes in risky sexual behavior among people living with HIV: A mediation analysis. AIDS and Behavior, 17(2), 813–823. doi:10.1007/s10461-011-0115-8 22228069
Coffin, P. O., Santos, G.-M., Matheson, T., Behar, E., Rowe, C., Rubin, T., … Vittinghoff, E. (2017). Behavioral intervention to reduce opioid overdose among high-risk persons with opioid use disorder: A pilot randomized controlled trial. PLOS One, 12(10), 1–15. Retrieved from www.ncbi.nlm.nih.gov/pubmed/29049282
Connors, G. J., DiClemente, C. C., Velasquez, M. M., & Donovan, D. M. (2013). Substance abuse treatment and the stages of change: Selecting and planning interventions. New York, NY: Guilford Press.
Copeland, J., Gates, P., & Pokorski, I. (2017). A narrative review of psychological cannabis use treatments with and without pharmaceutical adjunct. Current Pharmaceutical Design, 22(42), 6397–6408. doi:10.2174/1381612822666.160831094811
Copeland, L., McNamara, R., Kelson, M., & Simpson, S. (2015). Mechanisms of change within motivational interviewing in relation to health behaviors outcomes: A systematic review. Patient Education and Counseling, 98(4), 401–411. doi:10.1016/j.pec.2014.11.022 25535015
Cunningham, J. A., Sobell, L. C., Gavin, D. R., Sobell, M. B., & Breslin, F. C. (1997). Assessing motivation for change: Preliminary development and evaluation of a scale measuring the costs and benefits of changing alcohol or drug use. Psychology of Addictive Behaviors, 11(2), 107–114.
D'Amico, E. J., Houck, J. M., Hunter, S. B., Miles, J. N., Osilla, K. C., & Ewing, B. A. (2015). Group motivational interviewing for adolescents: Change talk and alcohol and marijuana outcomes. Journal of Consulting and Clinical Psychology, 83(1), 68–80. doi:10.1037/a0038155 25365779
Davis, J. P., Houck, J. M., Rowell, L. N., Benson, J. G., & Smith, D. C. (2015). Brief motivational interviewing and normative feedback for adolescents: Change language and alcohol use outcomes. Journal of Substance Abuse Treatment, 65, 66–73.26710670
Deci, E. L., & Ryan, R. M. (2012). Overview of self-determination theory: An organismic dialectical perspective. In E. Deci & R. M. Ryan (Eds.), Handbook of self-determination research (pp. 3–38). Rochester, NY: University of Rochester Press.
Dennis, M. L., & Scott, C. K. (2012). Four-year outcomes from the Early Re-Intervention (ERI) experiment using Recovery Management Checkups (RMCs). Drug and Alcohol Dependence, 121(1-2), 10–17. doi:10.1016/j.drugalcdep.2011.07.026 21903347
Dennis, M. L., Scott, C. K., & Laudet, A. (2014). Beyond bricks and mortar: Recent research on substance use disorder recovery management. Current Psychiatry Reports, 16(4). doi:10.1007/s11920-014-0442-3
de Roten, Y., Zimmermann, G., Ortega, D., & Despland, J.-N. (2013). Meta-analysis of the effects of MI training on clinicians' behavior. Journal of Substance Abuse Treatment, 45(2), 155–162. Retrieved from www.ncbi.nlm.nih.gov/pubmed/23537923 23537923
DiClemente, C. C. (2018). Addiction and change: How addictions develop and addicted people recover (2nd ed.). Guilford, NY: Guilford Publications.
DiClemente, C. C., Carbonari, J. P., Montgomery, R. P. G., & Hughes, S. O. (1994). The Alcohol Abstinence Self-Efficacy Scale. Journal of Studies on Alcohol, 55(2), 141–148.8189734
DiClemente, C. C., Corno, C. M., Graydon, M. M., Wiprovnick, A. E., & Knoblach, D. J. (2017). Motivational interviewing, enhancement, and brief interventions over the last decade: A review of reviews of efficacy and effectiveness. Psychology of Addictive Behaviors, 31(8), 862–887. doi:10.1037/adb0000318 29199843
Dillard, P. K., Zuniga, J. A., & Holstad, M. M. (2017). An integrative review of the efficacy of motivational interviewing in HIV management. Patient Education and Counseling, 100(4), 636–646. doi:10.1016/j.pec.2016.10.029 27838113
Drapkin, M. L., Wilbourne, P., Manuel, J. K., Baer, J., Karlin, B., & Raffa, S. (2016). National dissemination of motivation enhancement therapy in the Veterans Health Administration: Training program design and initial outcomes. Journal of Substance Abuse Treatment, 65, 83–87. doi:10.1016/j.jsat.2016.02.002 26951921
Dufett, I., & Ward, C. I. (2015). Can a motivational-interviewing-based outpatient substance abuse treatment achieve success? A theory-based evaluation. African Journal of Drug and Alcohol Studies, 14(1), 1–12.
Ekong, G., & Kavookjian, J. (2016). Motivational interviewing and outcomes in adults with type 2 diabetes: A systematic review. Patient Education and Counseling, 99(6), 944–952. doi:10.1016/j.pec.2015.11.022 26699083
Elliott, J. C., & Carey, K. B. (2013). Pros and cons: Prospective predictors of marijuana use on a college campus. Psychology of Addictive Behaviors, 27(1), 230–235. doi:10.1037/a0029835 22985053
Elliott, R., Bohart, A. C., Watson, J. C., & Murphy, D. (2018). Therapist empathy and client outcome: An updated meta-analysis. Psychotherapy, 55(4), 399–410. Retrieved from www.researchgate.net/publication/324562138TherapistEmpathyandClientOutcomeAnUpdatedMeta-Analysis 30335453
Ewing, S. W., Wray, A. M., Mead, H. K., & Adams, S. K. (2012). Two approaches to tailoring treatment for cultural minority adolescents. Journal of Substance Abuse Treatment, 43(2), 190–203. doi:10.1016/j.jsat.2011.12.005 22301086
Feldstein Ewing, S. W., Walters, S., & Baer, J. C. (2013). Motivational interviewing groups for adolescents and emerging adults. In C. C. Wagner & K. S. Ingersoll (Eds.), Motivational interviewing in groups (pp. 387–406). New York, NY: Guilford Press.
Fergie, L., Campbell, K. A., Coleman-Haynes, T., Ussher, M., Cooper, S., & Coleman, T. (2018). Identifying effective behavior change techniques for alcohol and illicit substance use during pregnancy: A systematic review. Annals of Behavioral Medicine. doi:10.1093/abm/kay085
Field, C. A., Adinoff, B., Harris, T. R., Ball, S. A., & Carroll, K. M. (2009). Construct, concurrent and predictive validity of the URICA: Data from two multi-site clinical trials. Drug and Alcohol Dependence, 101(1-2), 115–123.19157723
Field, C., Walters, S., Marti, C. N., Jun, J., Foreman, M., & Brown, C. (2014). A multisite randomized controlled trial of brief intervention to reduce drinking in the trauma care setting. Annals of Surgery, 259(5), 873–880. doi:10.1097/sla.0000000000000339 24263324
Fiszdon, J. M., Kurtz, M. M., Choi, J., Bell, M. D., & Martino, S. (2015). Motivational interviewing to increase cognitive rehabilitation adherence in schizophrenia. Schizophrenia Bulletin, 42(2), 327–334.26420905
Flannery, M. (2017). Self-determination theory: Intrinsic motivation and behavioral change. Oncology Nursing Forum, 44(2), 155–156. Retrieved from www.ncbi.nlm.nih.gov/pubmed/28222078 28222078
Forman, D. P., & Moyers, T. B. (2019). With odds of a single session, motivational interviewing is a good bet. Psychotherapy. doi:10.1037/pst0000199
Foster, D., & Neighbors, C. (2013). A review of decisional balance research and directions for brief alcohol intervention among college students. OA Alcohol, 1(1). doi:10.13172/2053-0285-1-1-575
Foster, D. W., Neighbors, C., & Pai, A. (2015). Decisional balance: Alcohol decisional balance intervention for heavy drinking undergraduates. Substance Use and Misuse, 50(13), 1717–1727.26555004
Friedrichs, A., Spies, M., Härter, M., & Buchholz, A. (2016). Patient preferences and shared decision making in the treatment of substance use disorders: A systematic review of the literature. PLOS One, 11(1). doi:10.1371/journal.pone.0145817
Gates, P. J., Sabioni, P., Copeland, J., Foll, B. L., & Gowing, L. (2016). Psychosocial interventions for cannabis use disorder. Cochrane Database of Systematic Reviews. doi:10.1002/14651858.cd005336.pub4
Gaume, J., Magill, M., Mastroleo, N. R., Longabaugh, R., Bertholet, N., Gmel, G., & Daeppen, J. (2016). Change talk during brief motivational intervention with young adult males: Strength matters. Journal of Substance Abuse Treatment, 65, 58–65. doi:10.1016/j.jsat.2016.01.005 26947118
Gelberg, L., Andersen, R., Vahidi, M., Rico, M., Baumeister, S., & Leake, B. (2017). A multi-component brief intervention for risky drug use among Latino patients of a federally qualified health center in East Los Angeles: A randomized controlled trial of the quit using drugs intervention trial (quit) brief intervention. Drug and Alcohol Dependence, 171. Retrieved from https://eurekamag.com/research/064/949/064949750.php
Glozah, F. N., Adu, N. A., & Komesuor, J. (2015). Assessing alcohol abstinence self-efficacy in undergraduate students: Psychometric evaluation of the alcohol abstinence self-efficacy scale. Health and Quality of Life Outcomes, 13(1). doi:10.1186/s12955-015-0387-1
Gordon, T. (1970). Parent effectiveness training: The nolose program for raising responsible children. New York, NY: Wyden.
Granfield, R., & Cloud, W. (1999). Coming clean: Overcoming addiction without treatment. New York, NY: New York University Press.
Grant, S., Colaiaco, B., Motala, A., Shanman, R., Booth, M., Sorbero, M., & Hempel, S. (2017). Mindfulness-based relapse prevention for substance use disorders: A systematic review and meta-analysis. Journal of Addiction Medicine, 11(5), 386–396. doi:10.1097/adm.0000000000000338 28727663
Gueorguieva, R., Wu, R., O'Connor, P. G., Weisner, C., Fucito, L. M., Hoffmann, S., … O'Malley, S. S. (2014). Predictors of abstinence from heavy drinking during treatment in COMBINE and external validation in PREDICT. Alcoholism: Clinical and Experimental Research, 38(10), 2647–2656.25346505
Hall, K., Staiger, P. K., Simpson, A., Best, D., & Lubman, D. I. (2015). After 30 years of dissemination, have we achieved sustained practice change in motivational interviewing? Addiction, 111(7), 1144–1150. doi:10.1111/add.13014 26216706
Harley, D. A. (2017). Motivational interviewing and motivational enhancement therapy: Cultural implications in addiction intervention for African Americans. SciFed Journal of Addiction and Therapy, 1(1). doi:10.23959/sfjat-1000005
Harrell, P. T., Trenz, R., Scherer, M., Martins, S., & Latimer, W. (2013). A latent class approach to treatment readiness corresponds to a transtheoretical (“Stages of Change”) model. Journal of Substance Abuse Treatment, 45(3), 249–256. doi:10.1016/j.jsat.2013.04.004 23706606
Hausotter, W. (2006). Motivational interviewing assessment: Supervisory tools for enhancing proficiency. Salem, OR: Northwest Frontier Addiction Technology Transfer Center, Oregon Health and Science University. Retrieved from www.motivationalinterviewing.org/sites/default/files/mia-step.pdf
Heather, N., & Honekopp, J. (2008). A revised edition of the readiness to change questionnaire (treatment version). Addiction Research and Theory, 16(5), 421–433.
Heather, N., & McCambridge, J. (2013). Post-treatment stage of change predicts 12-month outcome of treatment for alcohol problems. Alcohol and Alcoholism, 48(3), 329–336. doi:10.1093/alcalc/agt006 23408241
Hennessy, E. A. (2017). Recovery capital: A systematic review of the literature. Addiction Research and Theory, 25(5), 349–360. doi:10.1080/16066359.2017.1297990
Hennessy, E. A., Tanner-Smith, E. E., & Steinka-Fry, K. T. (2015). Do brief alcohol interventions reduce tobacco use among adolescents and young adults? A systematic review and meta-analysis. Journal of Behavioral Medicine, 38(6), 899–911.26130030
Hester, R. K., Delaney, H. D., & Campbell, W. (2012). The college drinker's check-up: Outcomes of two randomized clinical trials of a computer-delivered intervention. Psychology of Addictive Behaviors, 26(1), 1–12.21823769
Hingson, R., & Compton, W. M. (2014). Screening and brief intervention and referral to treatment for drug use in primary care: Back to the drawing board. JAMA, 312(5), 488. doi:10.1001/jama.2014.7863 25096687
Holstad, M. M., Diiorio, C., Kelley, M. E., Resnicow, K., & Sharma, S. (2010). Group motivational interviewing to promote adherence to antiretroviral medications and risk reduction behaviors in HIV infected women. AIDS and Behavior, 15(5), 885–896. doi:10.1007/s10461-010-9865-y
Houck, J. M., Hunter, S. B., Benson, J. G., Cochrum, L. L., Rowell, L. N., & Damico, E. J. (2015). Temporal variation in facilitator and client behavior during group motivational interviewing sessions. Psychology of Addictive Behaviors, 29(4), 941–949. doi:10.1037/adb0000107 26415055
Houck, J. M., Manuel, J. K., & Moyers, T. B. (2018). Short- and long-term effects of within-session client speech on drinking Outcomes in the COMBINE study. Journal of Studies on Alcohol and Drugs, 79(2), 217–222. doi:10.15288/jsad.2018.79.217 29553348
Houck, J. M., & Moyers, T. B. (2015). Within-session communication patterns predict alcohol treatment outcomes. Drug and Alcohol Dependence, 157, 205–209. doi:10.1016/j.drugalcdep.2015.10.025 26573732
Humphreys, K., Blodgett, J. C., & Wagner, T. H. (2014). Estimating the efficacy of Alcoholics Anonymous without self-selection bias: An instrumental variables re-analysis of randomized clinical trials. Alcoholism: Clinical and Experimental Research, 38(11), 2688–2694. doi:10.1111/acer.12557 25421504
Hunt, G. E., Siegfried, N., Morley, K., Sitharthan, T., & Cleary, M. (2013). Psychosocial interventions for people with both severe mental illness and substance misuse. Cochrane Database of Systematic Reviews, 10. Art. No.: CD001088. doi:10.1002/14651858.CD001088.pub3
Ingersoll, K. S., Ceperich, S. D., Hettema, J. E., Farrell-Carnahan, L., & Penberthy, J. K. (2013). Preconceptional motivational interviewing interventions to reduce alcohol-exposed pregnancy risk. Journal of Substance Abuse Treatment, 44(4), 407–416. doi:10.1016/j.jsat.2012.10.001 23192220
Jackson, L. A., Buxton, J. A., Dingwell, J., Dykeman, M., Gahagan, J., Gallant, K., … Davison, C. (2014). Improving psychosocial health and employment outcomes for individuals receiving methadone treatment: A realist synthesis of what makes interventions work. BMC Psychology, 2(1), 26. doi:10.1186/s40359-014-0026-3 25566385
Janis, L. L., & Mann, L. (1977). Decision making: A psychological analysis of conflict, choice, and commitment. London, England: Cassel and Collier Macmillan.
Jason, L. A., Salina, D., & Ram, D. (2016). Oxford recovery housing: Length of stay correlated with improved outcomes for women previously involved with the criminal justice system. Substance Abuse, 37(1), 248–254. doi:10.1080/08897077.2015.1037946 25962090
Jiang, S., Wu, L., & Gao, X. (2017). Beyond face-to-face individual counseling: A systematic review on alternative modes of motivational interviewing in substance abuse treatment and prevention. Addictive Behaviors, 73, 216–235 28554033
Joseph, J., & Basu, D. (2016). Efficacy of brief interventions in reducing hazardous or harmful alcohol use in middle-income countries: Systematic review of randomized controlled trials. Alcohol and Alcoholism, 52(1), 56–64. doi:10.1093/alcalc/agw054 27567270
Kadden, R. M., & Litt, M. D. (2011). The role of self-efficacy in the treatment of substance use disorders. Addictive Behaviors, 36(12), 1120–1126.21849232
Kahler, C. W., Pantalone, D. W., Mastroleo, N. R., Liu, T., Bove, G., Ramratnam, B., … Mayer, K. J. (2018). Motivational interviewing with personalized feedback to reduce alcohol use in HIV-infected men who have sex with men: A randomized controlled trial. Journal of Consulting and Clinical Psychology, 86(8), 645–656.30035581
Kanfer, F. H., & Schefft, B. K. (1988). Guiding the process of therapeutic change. Champaign, IL: Research Press.
Kelly, J. F., Bergman, B. G., Hoeppner, B., Vilsaint, C., & White, W. L. (2017). Prevalence and pathways of recovery from drug and alcohol problems in the United States population: Implications for practice, research, and policy. Drug and Alcohol Dependence, 181, 162–169.29055821
Kiluk, B. D., Serafini, K., Malin-Mayor, B., Babuscio, T. A., Nich, C., & Carroll, K. M. (2015). Prompted to treatment by the criminal justice system: Relationships with treatment retention and outcome among cocaine users. American Journal on Addictions, 24(3), 225–232. doi:10.1111/ajad.12208 25809378
Klimas, J., Field, C., Cullen, W., O'Gorman, C., Glynn, L., Keenan, E., … Dunne, C. (2014). Psychosocial interventions to reduce alcohol consumption in concurrent problem alcohol and illicit drug users: Cochrane Review. Drug and Alcohol Dependence, 140. doi:10.1016/j.drugalcdep.2014.02.305
Kohler, S., & Hofmann, A. (2015). Can motivational interviewing in emergency care reduce alcohol consumption in young people? A systematic review and meta-analysis. Alcohol and Alcoholism, 50(2), 107–117. doi:10.1093/alcalc/agu098 25563299
Korcha, R. A., Polcin, D. L., Evans, K., Bond, J. C., & Galloway, G. P. (2015). Intensive motivational interviewing for women with alcohol problems. Counselor (Deerfield Beach), 16(3), 62–69.26236173
Krawczyk, N., Feder, K. A., Saloner, B., Crum, R. M., Kealhofer, M., & Mojtabai, R. (2017). The association of psychiatric comorbidity with treatment completion among clients admitted to substance use treatment programs in a U.S. national sample. Drug and Alcohol Dependence, 175, 157–163. doi:10.1016/j.drugalcdep.2017.02.006 28432939
Krigel, S. W., Grobe, J. E., Goggin, K., Harris, K. J., Moreno, J. L., & Catley, D. (2017). Motivational interviewing and the decisional balance procedure for cessation induction in smokers not intending to quit. Addictive Behaviors, 64, 171–178. doi:10.1016/j.addbeh.2016.08.036 27619008
Kuerbis, A., Armeli, S., Muench, F., & Morgenstern, J. (2013). Motivation and self-efficacy in the context of moderated drinking: Global self-report and ecological momentary assessment. Psychology of Addictive Behaviors, 27(4), 934–943. doi:10.1037/a0031194 23276318
Kuusisto, K., Knuuttila, V., & Saarnio, P. (2011). Clients' self-efficacy and outcome expectations. Addictive Disorders and Their Treatment, 10(4), 157–168. doi:10.1097/adt.0b013e31820dd4ec
Kwasnicka, D., Dombrowski, S. U., White, M., & Sniehotta, F. (2016). Theoretical explanations for maintenance of behaviour change: A systematic review of behaviour theories. Health Psychology Review, 10(3), 277–296. doi:10.1080/17437199.2016.1151372 26854092
Lee, W. W., Choi, K., Yum, R. W., Yu, D. S., & Chair, S. (2016). Effectiveness of motivational interviewing on lifestyle modification and health outcomes of clients at risk or diagnosed with cardiovascular diseases: A systematic review. International Journal of Nursing Studies, 53, 331–341. doi:10.1016/j.ijnurstu.2015.09.010 26493130
Lenz, A. S., Rosenbaum, L., & Sheperis, D. (2016). Meta-analysis of randomized controlled trials of motivational enhancement therapy for reducing substance use. Journal of Addictions and Offender Counseling, 37(2), 66–86. doi:10.1002/jaoc.12017
Lindqvist, H., Forsberg, L., Enebrink, P., Andersson, G., & Rosendahl, I. (2017). Relational skills and client language predict outcome in smoking cessation treatment. Substance Use and Misuse, 52(1), 33–42. doi:10.1080/10826084.2016.1212892 27617700
Litt, M. D., & Kadden, R. M. (2015). Willpower versus “skillpower”: Examining how self-efficacy works in treatment for marijuana dependence. Psychology of Addictive Behaviors, 29(3), 532–540. doi:10.1037/adb0000085 25938628
Litt, M. D., Kadden, R. M., & Petry, N. M. (2013). Behavioral treatment for marijuana dependence: Randomized trial of contingency management and self-efficacy enhancement. Addictive Behaviors, 38(3), 1764–1775. doi:10.1016/j.addbeh.2012.08.011 23254227
Lord, S. P., Can, D., Yi, M., Marin, R., Dunn, C. W., Imel, Z. E., … Atkins, D. C. (2014). Advancing methods for reliably assessing motivational interviewing fidelity using the motivational interviewing skills code. Journal of Substance Abuse Treatment, 49, 50–57.25242192
Lozano, B. E., Larowe, S. D., Smith, J. P., Tuerk, P., & Roitzsch, J. (2013). Brief motivational feedback may enhance treatment entry in veterans with comorbid substance use and psychiatric disorders. American Journal on Addictions, 22(2), 132–135. doi:10.1111/j.1521-0391.2013.00315.x 23414498
Lundahl, B., Moleni, T., Burke, B. L., Butters, R., Tollefson, D., Butler, C., & Rollnick, S. (2013). Motivational interviewing in medical care settings: A systematic review and meta-analysis of randomized controlled trials. Patient Education and Counseling, 93(2), 157–168. doi:10.1016/j.pec.2013.07.012 24001658
Magill, M., Apodaca, T. R., Borsari, B., Gaume, J., Hoadley, A., Gordon, R. E. F., … Moyers, T. (2018). A meta-analysis of motivational interviewing process: Technical, relational, and conditional process models of change. Journal of Consulting and Clinical Psychology, 86(2), 140–157.29265832
Magill, M., Gaume, J., Apodaca, T. R., Walthers, J., Mastroleo, N. R., Borsari, B., & Longabaugh, R. (2014). The technical hypothesis of motivational interviewing: A meta-analysis of MI's key causal model. Journal of Consulting and Clinical Psychology, 82(6), 973–983.24841862
Magill, M., Stout, R. L., & Apodaca, T. R. (2013). Therapist focus on ambivalence and commitment: A longitudinal analysis of motivational interviewing treatment ingredients. Psychology of Addictive Behaviors, 27(3), 754–762. doi:10.1037/a0029639 22905897
Magill, M., Walthers, J., Mastroleo, N. R., Gaume, J., Longabaugh, R., & Apodaca, T. R. (2016). Therapist and client discussions of drinking and coping: A sequential analysis of therapy dialogues in three evidence-based alcohol use disorder treatments. Addiction, 111(6), 1011–1020. doi:10.1111/add.13313 26780564
Mahmoodabad, S. S., Tonekaboni, N. R., Farmanbar, R., Fallahzadeh, H. & Kamalikhah, T. (2017). The effect of motivational interviewing-based intervention using self-determination theory on promotion of physical activity among women in reproductive age: A randomized clinical trial. Electronic Physician, 9(5), 4461–4472. doi:10.19082/4461 28713522
Manuel, J. K., Satre, D. D., Tsoh, J., Moreno-John, G., Ramos, J. S., McCance-Katz, E. F., & Satterfield, J. M. (2015). Adapting screening, brief intervention, and referral to treatment for alcohol and drugs to culturally diverse clinical populations. Journal of Addiction Medicine, 1. doi:10.1097/adm.0000000000000150
Marlatt, G. A., Parks, G. A., & Witkiewitz, K. (2002). Clinical guidelines for implementing relapse prevention therapy: A guideline developed for behavioral health recovery management project. Chicago, IL: University of Chicago. Retrieved from www.researchgate.net/publication/235326763 Clinical Guidelines for Implementing RelapsePrevention Therapy A Guideline Developed for the Behavioral Health Recovery Management Project
Martin, G. W. & Rehm, J. (2012). The effectiveness of psychosocial modalities in the treatment of alcohol problems in adults: A review of the evidence. Canadian Journal of Psychiatry, 57(6), 350–358. doi:10.1177/070674371205700604 22682572
Martino, S., Ball, S. A., Gallon, S. L., Hall, D., Garcia, M., Ceperich, S., … Hausotter, W. (2006). Motivational interviewing assessment: Supervisory tools for enhancing proficiency. Salem, OR: Northwest Frontier Addiction Technology Transfer Center, Oregon Health and Science University. Retrieved from www.motivationalinterviewing.org/sites/default/files/mia-step.pdf
Martino, S., Paris, M., Añez, L., Nich, C., Canning-Ball, M., Hunkele, K., … Carroll, K. M. (2016). The effectiveness and cost of clinical supervision for motivational interviewing: A randomized controlled trial. Journal of Substance Abuse Treatment, 68, 11–23.27431042
Mattoo, S. K., Prasad, S. & Ghosh, A. (2018). Brief intervention in substance use disorders. Indian Journal of Psychiatry, 60(Suppl 4), S466–S472.29540915
McCance-Katz, E. F., & Satterfield, J. (2012). SBIRT: A key to integrate prevention and treatment of substance abuse in primary care. American Journal on Addictions, 21(2), 176–177. doi:10.1111/j.1521-0391.2011.00213.x 22332862
McConnaughy, E. A., Prochaska, J. O., & Velicer, W. F. (1983). Stages of change in psychotherapy: Measurement and sample profiles. Psychotherapy: Theory, Research and Practice, 20, 368–375.
McDevitt-Murphy, M. E., Murphy, J. G., Williams, J. L., Monahan, C. J., Bracken-Minor, K. L., & Fields, J. A. (2014). Randomized controlled trial of two brief alcohol interventions for OEF/OIF veterans. Journal of Consulting and Clinical Psychology, 82(4), 562–568. doi:10.1037/a0036714 24773573
McQueen, J., Howe, T. E., Allan, L., Mains, D., & Hardy, V. (2011). Brief interventions for heavy alcohol users admitted to general hospital wards. Cochrane Database of Systematic Reviews, (8).
McQueen, J. M., Howe, T. E., Ballinger, C., & Godwin, J. (2015). Effectiveness of alcohol brief intervention in a general hospital: A randomized controlled trial. Journal of Studies on Alcohol and Drugs, 76(6), 838–844. doi:10.15288/jsad.2015.76.838 26562591
Merchant, R. C., Romanoff, J., Zhang, Z., Liu, T., & Baird, J. R. (2017). Impact of a brief intervention on reducing alcohol use and increasing alcohol treatment services utilization among alcohol-and drug-using adult emergency department patients. Alcohol, 65, 71–80. doi:10.1016/j.alcohol.2017.07.003 29084632
Miller, M. B., Leffingwell, T., Ciaborn, K., Meier, E., Walters, S., & Neighbors, C. (2013). Personalized feedback interventions for college alcohol misuse: An update of Walters & Neighbors (2005). Psychology of Addictive Behaviors, 27(4), 909–920.23276309
Miller, W. R., Benefield, R. G. & Tonigan, J. S. (1993). Enhancing motivation for change in problem drinking: A controlled comparison of two therapist styles. Journal of Consulting and Clinical Psychology, 61(3), 455–461.8326047
Miller, W. R. & Brown, J. M. (1994). What I want from treatment (2.0). Retrieved from https://casaa.unm.edu/inst/What%20l%20Want%20From%20Treatment.pdf
Miller, W. R., Forcehimes, A. A., & Zweben, A. (2011). Treating addiction: A guide for professionals. New York, NY: Guilford Press.
Miller, W. R. & Moyers, T. B. (2017). Motivational interviewing and the clinical science of Carl Rogers. Journal of Consulting and Clinical Psychology, 85(8), 757–766. doi:10.1037/ccp0000179 28726479
Miller, W. R. & Moyers, T. B. (2015). The forest and the trees: Relational and specific factors in addiction treatment. Addiction, 110(3), 401–413.25066309
Miller, W. R., Moyers, T. B., Ernst, D. B., & Amrhein, P. C. (2008). Manual for the Motivational Interviewing Code (version 2.1). Albuquerque, NM: Center on Alcoholism, Substance Abuse, and Addictions, University of New Mexico. Retrieved from https://casaa.unm.edu/download/misc.pdf
Miller, W. R., & Rollnick, S. (2014). The effectiveness and ineffectiveness of complex behavioral interventions: Impact of treatment fidelity. Contemporary Clinical Trials, 37(2), 234–241. doi:10.1016/j.cct.2014.01.005 24469237
Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). New York, NY: Guilford Press.
Miller, W. R., & Rollnick, S. (2010). Looking forward to MI-3: A work in progress [PowerPoint slides]. Retrieved from http://motivationalinterviewing.org/sites/default/files/Forum_2010_Plenary_Bill.ppt
Miller, W. R., & Rollnick, S. (2002). Motivational interviewing: Preparing people for change (2nd ed.). New York, NY: Guilford Press.
Miller, W. R., & Rollnick, S. (1991). Motivational interviewing: Preparing people to change addictive behavior. New York, NY: Guilford Press.
Miller, W. R., & Rose, G. S. (2013). Motivational interviewing and decisional balance: Contrasting responses to client ambivalence. Behavioural and Cognitive Psychotherapy, 43(02), 129–141. doi:10.1017/s1352465813000878 24229732
Miller, W. R., & Sanchez, V. C. (1994). Motivating young adults for treatment and lifestyle change. In G. Howard & Nathan (Eds.), Alcohol use and misuse by young adults (pp. 55–82). Notre Dame, IN: University of Notre Dame Press.
Miller, W. R., & Tonigan, J. S. (1996). Assessing drinkers' motivation for change: The Stages of Change Readiness and Treatment Eagerness Scale (SOCRATES). Psychology of Addictive Behaviors, 10(2), 81–89.
Miller, W. R., Tonigan, J. S., & Longabaugh, R. (1995). The Drinker Inventory of Consequences (DrInC): An instrument for assessing adverse consequences of alcohol abuse, Test manual (vol. 4). Project MATCH Monograph Series. Rockville, MD: National Institute on Alcohol Abuse and Alcoholism. Retrieved from https://pubs.niaaa.nih.gov/publications/projectmatch/match04.pdf
Miller, W. R., & Wilbourne, P. L. (2002). Mesa Grande: A methodological analysis of clinical trials of treatments for alcohol use disorders. Addiction, 97(3), 265–277. doi:10.1046/j.1360-0443.2002.00019.x 11964100
Montgomery, L., Robinson, C., Seaman, E. L., & Haeny, A. M. (2017). A scoping review and meta-analysis of psychosocial and pharmacological treatments for cannabis and tobacco use among African Americans. Psychology of Addictive Behaviors, 31(8), 922–943. www. ncbi.nlm.nih.gov/pubmed/2919984429199844
Monti, P. M., Colby, S. M., Mastroleo, N. R., Barnett, N. P., Gwaltney, C. J., Apodaca, T. R., … Cioffi, W. G. (2014). Individual versus significant-other-enhanced brief motivational intervention for alcohol in emergency care. Journal of Consulting and Clinical Psychology, 82(6), 936–948. doi:10.1037/a0037658 25111430
Moore, M., Flamez, B., & Szirony, G. M. (2017). Motivational interviewing and dual diagnosis clients: Enhancing self-efficacy and treatment completion. Journal of Substance Use, 23(3), 247–253. doi:10.1080/14659891.2017.1388856
Moos, R. H. (2012). Iatrogenic effects of psychosocial interventions: Treatment, life context, and personal risk factors. Substance Use and Misuse, 47(13-14), 1592–1598. doi:10.3109/10826084.2012.705710 23186483
Morgenstern, J., Kuerbis, A., Houser, J., Muench, F. J., Shao, S., & Treloar, H. (2016). Within-person associations between daily motivation and self-efficacy and drinking among problem drinkers in treatment. Psychology of Addictive Behaviors, 30(6), 630–638. doi:10.1037/adb0000204 27560995
Mowbray, O., Quinn, A., & Cranford, J. A. (2014). Social networks and alcohol use disorders: Findings from a nationally representative sample. American Journal of Drug and Alcohol Abuse, 40(3), 181–186. doi:10.3109/00952990.2013.860984 24405256
Moyers, T. B. (2014). The relationship in motivational interviewing. Psychotherapy, 51(3), 358–363. Retrieved from https://www.researchgate.net/publication/264396087 The Relationship in Motivational Interviewing25068193
Moyers, T. B., & Houck, J. (2011). Combining motivational interviewing with cognitive-behavioral treatments for substance abuse: Lessons from the COMBINE research project. Cognitive and Behavioral Practice, 18(1), 38–45. doi:10.1016/j.cbpra.2009.09.005
Moyers, T. B., Houck, J., Glynn, L. H., Hallgren, K. A., & Manuel, J. K. (2017). A randomized controlled trial to influence client language in substance use disorder treatment. Drug and Alcohol Dependence, 172, 43–50. doi:10.1016/j.drugalcdep.2016.11.036 28122270
Moyers, T. B., Houck, J., Rice, S. L., Longabaugh, R., & Miller, W. R. (2016). Therapist empathy, combined behavioral intervention, and alcohol outcomes in the COMBINE research project. Journal of Consulting and Clinical Psychology, 84(3), 221–229. doi:10.1037/ccp0000074 26795938
Moyers, T. B., Manuel, J. K., & Ernst, D. (2014). Motivational Interviewing Treatment Integrity Coding Manual 4.1. Unpublished manual. Retrieved from https://motivationalinterviewing.org/sites/default/files/miti4_2.pdf
Moyers, T. B., Martin, T., & Christopher, P. (2005). Motivational interviewing knowledge test. Albuquerque, NM: Center on Alcoholism, Substance Abuse, and Addictions, University of New Mexico. Retrieved from https://casaa.unm.edu/download/ELICIT/MI%20Knowledge%20Test.pdf
Moyers, T. B., & Miller, W. R. (2013). Is low therapist empathy toxic? Psychology of Addictive Behaviors, 273, 878–884. doi:10.1037/a0030274
Mumba, M. N., Findlay, L. J., & Snow, D. E. (2018). Treatment options for opioid use disorders. Journal of Addictions Nursing, 29(3), 221–225.30180011
Naar-King, S., Safren, S. A., & Miller, W. R. (2017). Motivational interviewing and CBT: Combining strategies for maximum effectiveness. New York, NY: Guilford Press.
Navidian, A., Kermansaravi, F., Tabas, E. E., & Saeedinezhad, F. (2016). Efficacy of group motivational interviewing in the degree of drug craving in the addicts under the methadone maintenance treatment (MMT) in South East of Iran. Archives of Psychiatric Nursing, 30(2), 144–149. doi:10.1016/j.apnu.2015.08.002 26992862
Norcross, J. C., Krebs, P. M., & Prochaska, J. O. (2011). Stages of Change. Journal of Clinical Psychology, 67(2), 143–154. Retrieved from www.researchgate.net/publication/49683193StagesofChange 21157930
Novins, D. K., Croy, C. D., Moore, L. A., & Rieckmann, T. (2016). Use of evidence-based treatments in substance abuse treatment programs serving American Indian and Alaska Native communities. Drug and Alcohol Dependence, 161, 214–221.26898185
Nunes, A. P., Richmond, M. K., Marzano, K., Swenson, C. J., & Lockhart, J. (2017). Ten years of implementing screening, brief intervention, and referral to treatment (SBIRT): Lessons learned. Substance Abuse, 38(4), 508–512. doi:10.1080/08897077.2017.1362369 28762888
Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. Washington, DC: U.S. Department of Health and Human Services. Retrieved from https://addiction.surgeongeneral.gov/sites/default/files/surgeon-generals-report.pdf
Osilla, K. C., Ortiz, J. A., Miles, J. N., Pedersen, E. R., Houck, J. M., & Damico, E. J. (2015). How group factors affect adolescent change talk and substance use outcomes: Implications for motivational interviewing training. Journal of Counseling Psychology, 62(1), 79–86. doi:10.1037/cou0000049 25602608
Osterman, R., Lewis, D., & Winhusen, T. (2017). Efficacy of motivational enhancement therapy to decrease alcohol and illicit-drug use in pregnant substance users reporting baseline alcohol use. Journal of Substance Abuse Treatment, 77, 150–155. doi:10.1016/j.jsat.2017.02.003 28254158
Pace, B. T., Dembe, A., Soma, C. S., Baldwin, S. A., Atkins, D. C., & Imel, Z. E. (2017). A multivariate meta-analysis of motivational interviewing process and outcome. Psychology of Addictive Behaviors, 31(5), 524–533. doi:10.1037/adb0000280 28639815
Panebianco, D., Gallupe, O., Carrington, P. J., & Colozzi, I. (2016). Personal support networks, social capital, and risk of relapse among individuals treated for substance use issues. International Journal of Drug Policy, 27, 146–153. doi:10.1016/j.drugpo.2015.09.009 26520237
Polcin, D. L., Mulia, N., & Jones, L. (2012). Substance users' perspectives on helpful and unhelpful confrontation: Implications for recovery. Journal of Psychoactive Drugs, 44(2), 144–152.22880542
Prochaska, J. O. (1979). Systems of psychotherapy: A transtheoretical analysis. Homewood, IL: Dorsey Press.
Prochaska, J. O., & DiClemente, C. C. (1984). The transtheoretical approach: Crossing traditional boundaries of therapy. Malabar, FL: R. E. Krieger.
Prochaska, J., Norcross, J., & DiClemente, C. (2013). Applying the Stages of Change. Psychotherapy in Australia, 19, 10–15. doi:10.1093/med:psych/9780199845491.003.0034
Prochaska, J. O., Velicer, W. F., Rossi, J. S., Goldstein, M. G., Marcus, B.H., Rakowski, W., … Rossi, S.R. (1994). Stages of Change and decisional balance for 12 problem behaviors. Health Psychology, 13, 39–46.8168470
Rapp, R. C., Van Den Noortgate, W., Broekaert, E., & Vanderplasschen, W. (2014). The efficacy of case management with persons who have substance abuse problems: A three-level meta-analysis of outcomes. Journal of Consulting and Clinical Psychology, 82(4), 605–618. Retrieved from www.ncbi.nlm.nih.gov/books/NBK241643/ 24821097
Raylu, N., & Kaur, I. (2012). Factors that affect treatment expectations of outpatients with substance use problems. International Journal of Mental Health and Addiction, 10(6), 804–817. doi:10.1007/s11469-012-9377-2
Rhoades, H., Motte-Kerr, W. L., Duan, L., Woo, D., Rice, E., Henwood, B., … Wenzel, S. L. (2018). Social networks and substance use after transitioning into permanent supportive housing. Drug and Alcohol Dependence, 191, 63–69. doi:10.1016/j.drugalcdep.2018.06.027 30086424
Riper, H., Andersson, G., Hunter, S. B., Wit, J. D., Berking, M., & Cuijpers, P. (2014). Treatment of comorbid alcohol use disorders and depression with cognitive-behavioural therapy and motivational interviewing: A meta-analysis. Addiction, 109(3), 394–406. doi:10.1111/add.12441 24304463
Rodriguez, M., Walters, S. T., Houck, J. M., Ortiz, J. A., & Taxman, F. S. (2017). The language of change among criminal justice clients: Counselor language, client language, and client substance use outcomes. Journal of Clinical Psychology, 74(4), 626–636. doi:10.1002/jclp.22534 28940435
Rogers, C. R. (1980). A way of being. Boston, MA: Houghton Mifflin.
Rogers, C. R. (1965). Client-centered therapy. New York, NY: Houghton Mifflin.
Rollnick, S., Heather, N., Gold, R., & Hall, W. (1992). Development of a short “readiness to change” questionnaire for use in brief, opportunistic interventions among excessive drinkers. British Journal of Addiction, 87, 743–754.1591525
Rollnick, S., Miller, W. R., & Butler, C. C. (2008). Motivational interviewing in health care: Helping patients change behavior. New York, NY: Guilford.
Romano, M., & Peters, L. (2016). Understanding the process of motivational interviewing: A review of the relational and technical hypotheses. Psychotherapy Research, 26(2), 220–240. doi:10.1080/10503307.2014.954154 25204407
Rosengren, D. B. (2018). Building motivational interviewing skills: A practitioner workbook (2nd ed.). New York, NY: Guilford Press.
Running Bear, U. R., Beals, J., Novins, D. K., & Manson, S. M. (2017). Alcohol detoxification completion, acceptance of referral to substance abuse treatment, and entry into substance abuse treatment among Alaska Native people. Addictive Behaviors, 65, 25–32. doi:10.1016/j.addbeh.2016.09.009 27705843
Samson, J. E., & Tanner-Smith, E. E. (2015). Single-session alcohol interventions for heavy drinking college students: A systematic review and meta-analysis. Journal of Studies on Alcohol and Drugs, 76(4), 530–543.26098028
Sarpavaara, H. (2015). Significant others in substance abusers change talk during motivational interviewing sessions in the Finnish Probation Service. Nordic Studies on Alcohol and Drugs, 32(1), 91–103. doi:10.1515/nsad-2015-0010
Satre, D. D., Delucchi, K., Lichtmacher, J., Sterling, S. A., & Weisner, C. (2013). Motivational interviewing to reduce hazardous drinking and drug use among depression patients. Journal of Substance Abuse Treatment, 44(3), 323–329.22999815
Satre, D. D., Leibowitz, A., Sterling, S. A., Lu, Y., Travis, A., & Weisner, C. (2016). A randomized clinical trial of motivational interviewing to reduce alcohol and drug use among patients with depression. Journal of Consulting and Clinical Psychology, 84(7), 571–579.26985728
Satre, D. D., Manuel, J. K., Larios, S., Steiger, S., & Satterfield, J. (2015). Cultural adaptation of screening, brief intervention and referral to treatment using motivational interviewing. Journal of Addiction Medicine, 9(5), 352–357. doi:10.1097/adm.0000000000000149 26428360
Sayegh, C. S., Huey, S. J., Zara, E. J., & Jhaveri, K. (2017). Follow-up treatment effects of contingency management and motivational interviewing on substance use: A meta-analysis. Psychology of Addictive Behaviors, 31(4), 403–414. doi:10.1037/adb0000277 28437121
Schonfeld, L., King-Kallimanis, B. L., Duchene, D. M., Etheridge, R. L., Herrera, J. R., Barry, K. L., & Lynn, N. (2010). Screening and brief intervention for substance misuse among older adults: The Florida BRITE project. American Journal of Public Health, 100(1), 108–114.19443821
Schumacher, J. A., Williams, D. C., Burke, R. S., Epler, A. J., Simon, P., & Coffey, S. F. (2018). Competency-based supervision in motivational interviewing for advanced psychology trainees: Targeting an a priori benchmark. Training and Education in Professional Psychology, 12(3), 149–153. doi:10.1037/tep0000177 30275924
Schwalbe, C. S., Oh, H. Y., & Zweben, A. (2014). Sustaining motivational interviewing: A meta-analysis of training studies. Addiction, 109(8), 1287–1294. Retrieved from https://onlinelibrary.wiley.com/doi/abs/10.1111/add.12558 24661345
Scott, C. K., Dennis, M. L., & Lurigio, A. J. (2017). The effects of specialized probation and recovery management checkups (RMCs) on treatment participation, substance use, HIV risk behaviors, and recidivism among female offenders: Main findings of a 3-year experiment using subject by intervention interaction analysis. Journal of Experimental Criminology, 13(1), 53–77.28966568
Shepard, D. S., Lwin, A. K., Barnett, N. P., Mastroleo, N., Colby, S. M., Gwaltney, C., & Monti, P. M. (2016). Cost-effectiveness of motivational intervention with significant others for patients with alcohol misuse. Addiction, 111(5), 832–839. doi:10.1111/add.13233 26574195
Skinner, H. A. (1982). The Drug Abuse Screening Test. Addictive Behavior, 7(4), 363–371.
Smedslund, G., Berg, R. C., Hammerstrom, K. T., Steiro, A., Leiknes, K. A., Dahl, H. M., & Karlsen, K. (2011). Motivational interviewing for substance abuse. Cochrane Database of Systematic Reviews, 5, CD008063
Smeerdijk, M., Keet, R., Raaij, B. V., Koeter, M., Linszen, D., Haan, L. D., & Schippers, G. (2015). Motivational interviewing and interaction skills training for parents of young adults with recent-onset schizophrenia and co-occurring cannabis use: 15-month follow-up. Psychological Medicine, 45(13), 2839–2848. doi:10.1017/s0033291715000793 25959502
Soderlund, P. D. (2017). Effectiveness of motivational interviewing for improving physical activity self-management for adults with type 2 diabetes: A review. Chronic Illness, 14(1), 54–68. doi:10.1177/1742395317699449 29226694
Steinberg, M. L., Williams, J. M., Stahl, N. F., Budsock, P. D., & Cooperman, N. A. (2015). An adaptation of motivational interviewing increases quit attempts in smokers with serious mental illness. Nicotine and Tobacco Research, 18(3), 243–250. doi:10.1093/ntr/ntv043 25744954
Stinson, J. D., & Clark, M. D. (2017). Motivational interviewing with offenders: Engagement, rehabilitation, and reentry. New York, NY: Guilford Press.
Substance Abuse and Mental Health Services Administration. (2019). Mental health and substance use disorders. Retrieved from www.samhsa.gov/find-help/disorders
Substance Abuse and Mental Health Services Administration. (2018). Key substance use and mental health indicators in the United States: Results from the 2017 National Survey on Drug Use and Health. HHS Publication No. (SMA) 18-5068, NSDUH Series H-53. Rockville, MD: Center for Behavioral Health Statistics and Quality, Substance Abuse and Mental Health Services Administration: Center for Behavioral Health Statistics and Quality, Substance Abuse and Mental Health Services Administration. Retrieved from www.samhsa.gov/data/
Substance Abuse and Mental Health Services Administration. (2016). Criteria for the demonstration program to improve community mental health centers and to establish certified community behavioral health clinics. Retrieved from Retrieved from www.samhsa.gov/sites/default/files/programscampaigns/ccbhc-criteria.pdf
Substance Abuse and Mental Health Services Administration. (2015a). Substance abuse treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. HHS Publication No. (SMA) 15-4219. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/TIP-39-Substance-Abuse-Treatment-and-Family-Therapy/SMA15-4219
Substance Abuse and Mental Health Services Administration. (2015b). Using technology-based therapeutic tools in behavioral health services. Treatment Improvement Protocol (TIP) Series 60. HHS Publication No. (SMA) 15-4924. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/TIP-60-Using-Technology-Based-Therapeutic-Tools-in-Behavioral-Health-Services/SMA15-4924
Substance Abuse and Mental Health Services Administration. (2014a). Improving cultural competence. Treatment Improvement Protocol (TIP) Series 59. HHS Publication No. (SMA) 14-4849. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/TIP-59-Improving-Cultural-Competence/SMA15-4849
Substance Abuse and Mental Health Services Administration. (2014b). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 60. HHS Publication No. (SMA) 14-4816. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/TIP-57-rauma-Informed-Care-in-Behavioral-Health-Services/SMA14-4816
Substance Abuse and Mental Health Services Administration. (2013). Substance abuse treatment for persons with co-occurring disorders. Treatment Improvement Protocol (TIP) Series 42. HHS Publication No. (SMA) 13-3992. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/TIP-42-Substance-Abuse-Treatment-for-Persons-With-Co-Occurring-Disorders/SMA13-3992
Substance Abuse and Mental Health Services Administration. (2009). Clinical supervision and professional development of the substance abuse counselor. Treatment Improvement Protocol (TIP) Series 52. HHS Publication (SMA) 14-4435. Rockville, MD: Substance Abuse and Mental Health Services Administration. Retrieved from https://store.samhsa.gov/product/TIP-52-Clinical-Supervision-and-Professional-Development-of-the-Substance-Abuse-Counselor/SMA14-4435.html
Substance Abuse and Mental Health Services Administration. (planned). Treating addiction in older adults. Treatment Improvement Protocol (TIP) Series. Rockville, MD: Substance Abuse and Mental Health Services Administration.
Substance Abuse and Mental Health Services Administration, Center for the Application of Prevention Technologies. (2017). Words matter: How language choice can reduce stigma. Retrieved from https://facesandvoicesofrecovery.org/wp-content/uploads/2019/06/Words-Matter-How-Language-Choice-Can-Reduce-Stigma.pdf
Substance Abuse and Mental Health Services Administration & National Institute on Alcohol Abuse and Alcoholism. (2015). Medication for the treatment of alcohol use disorder: A brief guide. HHS Publication No. (SMA) 15-4907. Retrieved from Rockville, MD. Retrieved from https://store.samhsa.gov/product/Medication-for-the-Treatment-of-Alcohol-Use-Disorder-A-Brief-Guide/SMA15-4907
Taleff, M.J. (1997). A handbook to assess and treat resistance in chemical dependency. Dubuque, IA: Kendall/Hunt.
Tanner-Smith, E. E., & Lipsey, M. W. (2015). Brief alcohol interventions for adolescents and young adults: A systematic review and meta-analysis. Journal of Substance Abuse Treatment, 51, 1–18.25300577
Teeson, M., Marel, C., Darke, S., Ross, J., Slade, T., Burns, L., … Mills, K. L. (2015). Long-term mortality, remission, criminality and psychiatric comorbidity of heroin dependence: 11-year indings from the Australian Treatment Outcome Study. Addiction, 110(6), 986–983.25619110
Timko, C., Kong, C., Vittorio, L., & Cucciare, M. A. (2016). Screening and brief intervention for unhealthy substance use in patients with chronic medical conditions: A systematic review. Journal of Clinical Nursing, 25(21-22), 3131–3143. doi:10.1111/jocn.13244 27140392
Truax, C. B., & Carkhuff, R. R. (1967). Toward effective counseling and psychotherapy. Chicago, IL: Aldine.
Turner, B., & Deane, F. P. (2016). Length of stay as a predictor of reliable change in psychological recovery and well-being following residential substance abuse treatment. Therapeutic Communities, 37(3), 112–120. doi:10.1108/tc-09-2015-0022
Van Horn, D. H., Drapkin, M., Lynch, K. G., Rennert, L., Goodman, J. D., Thomas, T., … McKay, J. R. (2015). Treatment choices and subsequent attendance by substance-dependent patients who disengage from intensive outpatient treatment. Addiction Research and Theory, 23(5), 391–403.27667970
Vella-Zarb, R. A., Mills, J. S., Westra, H. A., Carter, J. C., & Keating, L. (2014). A randomized controlled trial of motivational interviewing self-help versus psychoeducation self-help for binge eating. International Journal of Eating Disorders, 48(3), 328–332. doi:10.1002/eat.22242 24753120
Venner, K. L., Feldstein, S. W., & Tafoya, N. (2006). Native American motivational interviewing: Weaving Native American and Western practices. Retrieved from www.integration.samhsa.gov/clinical-practice/NativeAmerican_MI_Manual.pdf
Venner, K. L., Sánchez, V., Garcia, J., Williams, R. L., & Sussman, A. L. (2018). Moving away from the tip of the pyramid: Screening and brief intervention for risky alcohol and opioid use in underserved patients. Journal of the American Board of Family Medicine, 31(2), 243–251.29535241
Wagner, A. J., Garbers, R., Lang, A., Borgert, A. J., & Fisher, M. (2016). Increasing follow-up outcomes of at-risk alcohol patients using motivational interviewing. Journal of Trauma Nursing, 23(3), 165–168. doi:10.1097/jtn.0000000000000200 27163224
Wagner, C. C., & Ingersoll, K. S. (2017). Development and initial validation of the Assessment of Motivational Interviewing Groups—Observer Scales (AMIGOS). International Journal of Group Psychotherapy, 68(1), 69–79. doi:10.1080/00207284.2017.1315587
Wagner, C. C., & Ingersoll, K. S. (2013). Motivational interviewing in groups. New York, NY: Guilford Press.
Walker, D. D., Walton, T. O., Neighbors, C., Kaysen, D., Mbilinyi, L., Darnell, J., … Roffman, R. A. (2017). Randomized trial of motivational interviewing plus feedback for soldiers with untreated alcohol abuse. Journal of Consulting and Clinical Psychology, 85(2), 99–110. doi:10.1037/ccp0000148 27736113
White, W. L. (2014). Slaying the dragon: The history of addiction treatment and recovery in America (2nd ed.). Bloomington, IL: Chestnut Health Systems/Lighthouse Institute.
White, W., & Miller, W. (2007). The use of confrontation in addiction treatment: History, science and time for change. Counselor, 8(4), 12–30.
Wild, T. C., Yuan, Y., Rush, B. R., & Urbanoski, K. A. (2016). Client engagement in legally mandated addiction treatment: A prospective study using self-determination theory. Journal of Substance Abuse Treatment, 69, 35–43. doi:10.1016/j.jsat.2016.06.006 27568508
Witkiewitz, K., & Marlatt, G. A. (Eds.). (2007). Therapist's guide to evidence-based relapse prevention. Boston, MA: Elsevier Academic Press.
Wong-Anuchit, C., Chantamit-O-Pas, C., Schneider, J. K., & Mills, A. C. (2018). Motivational interviewing-based compliance/adherence therapy interventions to improve psychiatric symptoms of people with severe mental illness: Meta-analysis. Journal of the American Psychiatric Nurses Association, 107839031876179. doi:10.1177/1078390318761790
Woolard, R., Baird, J., Longabaugh, R., Nirenberg, T., Lee, C. S., Mello, M. J., & Becker, B. (2013). Project Reduce: Reducing alcohol and marijuana misuse, Effects of a brief intervention in the emergency department. Addictive Behaviors, 38(3), 1732–1739. doi:10.1016/j.addbeh.2012.09.006 23261491
Yeh, M., Tung, T., Horng, F., & Sung, S. (2017). Effectiveness of a psychoeducational programme in enhancing motivation to change alcohol-addictive behaviour. Journal of Clinical Nursing, 26(21-22), 3724–3733. doi:10.1111/jocn.13744 28122409
Yudko, E., Lozhkina, O., & Fouts, A. (2007). A comprehensive review of the psychometric properties of the Drug Abuse Screening Test. Journal of Substance Abuse Treatment, 32, 189–198.17306727