# TIP Development Participants

Note: The information given for participants in the TIP's development indicates their affiliations at the time of their participation and may not reflect their current affiliations.

## Consensus Panel

Each Treatment Improvement Protocol's (TIP) consensus panel is a group of primarily nonfederal addiction-focused clinical, research, administrative, and recovery support experts with deep knowledge of the TIP's topic. With the Substance Abuse and Mental Health Services Administration's Knowledge Application Program team, members of the consensus panel develop each TIP via a consensus-driven, collaborative process that blends evidence-based, best, and promising practices with the panel members' expertise and combined wealth of experience.

### Chair

Richard A. Rawson, Ph.D.
Executive Director
Matrix Center and Matrix Institute on Addiction
Deputy Director
UCLA Addiction Medicine Services
Los Angeles, CA

### Workgroup Leaders

Felipe G. Castro, Ph.D., M.S.W.
Professor
Hispanic Research Center
Department of Psychology
Arizona State University
Tempe, AZ

James W. Cornish, M.D.
Assistant Professor of Psychiatry
Director
Division of Pharmacotherapy
Treatment Research Center
University of Pennsylvania
Department of Veterans Affairs Medical Center
Philadelphia, PA

Frances R. Levin, M.D.
Assistant Professor
Clinical and Educational Activities
Division on Substance Abuse
Columbia University
New York, NY

Michael J. McCann, M.A.
Research Coordinator
Matrix Center
Los Angeles, CA

### Panelists

Arlene Hall, RN, M.S., CD
Director of Nursing
Hope House
Crownsville, MD

Stephen Higgins, Ph.D.
Professor
Departments of Psychiatry and Psychology
Ira Allen School
University of Vermont
Burlington, VT

Kyle M. Kampman, M.D.
Assistant Professor of Psychiatry
Treatment Research Center
University of Pennsylvania
Philadelphia, PA

Quintin Kingfisher
Medical Resources
Tribal Health
Lame Deer, MT

Judy Knobbe, M.S.W., LISW, CADC
Director
Heart of Iowa
Area Substance Abuse Council
Cedar Rapids, IA

Wendy Lay
Program Specialist
Bureau of Alcohol and Drug Abuse
State of Nevada
Carson City, NV

Scott M. Reiner, M.S., CAC, CCS
Substance Abuse Program Supervisor
Substance Abuse Services Unit
Virginia Department of Juvenile Justice
Richmond, VA

Ewa Szumotalska Stamper, Ph.D.
Police Psychologist
Honolulu Police Department
Private Practice, Clinical and Addictions Psychology
Honolulu, HI

Arnold M. Washton, Ph.D.
Private Practice of Addiction Psychology
Parkland, FL

Dennis A. Weis, M.D.
Medical Director
Powell Center for Disease Control
Iowa Lutheran Hospital
President, Iowa Chapter
American Society of Addiction Medicine
Des Moines, IA

## Field Reviewers

Field reviewers represent each TIP's intended target audiences. They work in addiction, mental health, primary care, and adjacent fields. Their direct frontline experience related to the TIP's topic allows them to provide valuable input on a TIP's relevance, utility, accuracy, and accessibility. Additional advisors to this TIP include members of a resource panel and an editorial advisory board.

### Original Field Reviewers

Patricia Bradford, LISW, LMFT, CTS
P.A. Bradford and Associates
Columbia, SC

Peter J. Cohen, M.D., J.D.
Special Expert
Medications Development Division
National Institute on Drug Abuse
National Institutes of Health
Bethesda, MD

Carol L. DeRosa, RN
Registered Nurse Consultant
Child Advocacy Unit
Anne Arundel County Department of Social Services
Severna Park, MD

Karen Kelly-Woodall, M.S., MAC, NCAC II
Criminal Justice Coordinator
Cork Institute
Georgia Addiction Technology Transfer Center
Morehouse School of Medicine
Atlanta, GA

Mitchell Markinem, M.A., NCAC II
Drug Court Program Coordinator
Fifth Circuit Solicitor's Office
Columbia, SC

Bonnie I. Pipe, B.S., CCDC
Clinical Director
Northern Cheyenne Recovery Center
Northern Cheyenne Board of Health
Lame Deer, MT

Lynda A. Price, Ph.D., ICADC
Treatment Coordinator
Global House
National Drug Commission
Hamilton, BD

Margaret M. Salinger, M.S.N., RN, CARN
National Nurses Society on Addiction
Department of Veterans Affairs Medical Center
Coatesville, PA

Richard E. Steinberg, M.S.
President
WestCare
Las Vegas, NV

Christopher J. Stock, Pharm.D.
Clinical Pharmacist
Substance Abuse Program
Veterans Medical Center
Salt Lake City, UT

Richard T. Suchinsky, M.D.
Associate Director for Addictive Disorders and Psychiatric Rehabilitation
Department of Veterans Affairs
Mental Health and Behavioral Sciences Services
Washington, DC

Sushma Taylor, Ph.D.
Executive Director
Administrative Office
Center Point, Inc.
San Rafael, CA

Elizabeth Wells, Ph.D.
Research Associate Professor
Department of Psychiatry and Behavioral Sciences
University of Washington
Seattle, WA

### 2021 Update Field Reviewers

Justin Alves, RN, MSN, ACRN, CARN, CNE
Addiction Nurse Educator
Office-Based Addiction Treatment Training and Technical Assistance
Boston Medical Center
Clinical Instructor, Public Health
Northeastern University
Boston, MA

Amelia M. Arria, Ph.D.
Professor
Department of Behavioral and Community Health
Director
Center on Young Adult Health and Development
University of Maryland School of Public Health
College Park, MD

Wanda Barnett, M.S.
Primary Therapist – Addiction/Co-Occurring Disorders
Retreat at Lancaster County
Retreat Behavioral Health
Ephrata, PA

Adam D. Bloom, M.S., LCPC, LPC, NCC, MAC
Clinical Director
Kolmac Outpatient Recovery Centers
Burtonsville, MD

Lucy R. Cannon, Ed.D., M.S.W., LCSW, LICSW, CCDP-D, MATS
Owner/Chief Executive Officer
LEJ Behavioral Health Services, LLC
Redan, GA
Adjunct Professor
Clark Atlanta University
Atlanta, GA

Mark Depman, M.D.
Attending Physician
Department of Emergency Medicine
Central Vermont Medical Center – University of Vermont Health Network
Berlin, VT

Thomas E. Freese, Ph.D.
Co-Director
UCLA Integrated Substance Abuse Programs
Adjunct Professor
UCLA David Geffen School of Medicine
Los Angeles, CA

Peggy J. Gemperline, RN, B.S.N., M.B.A.
Vice President of Residential and Ambulatory Services
Pinnacle Treatment Centers
Mt. Laurel, NJ

Amy Jeppesen, M.S.W., LCSW, ACADC
Behavioral Health Director Idaho/Iowa
Trivium Life Services
Adjunct Faculty
Boise State University
Boise, ID

Philip T. McCabe, CSW, CAS, CDVC, DRCC
President, NALGAP
The Association of Lesbian, Gay, Bisexual, Transgender Addiction Professionals and their Allies
Health Educator
Center for Public Health Workforce Development
Rutgers School of Public Health
Piscataway, NJ

Mary McCarty-Arias, M.A.
Rehabilitation Counselor and Trainer
Northeast Caribbean Addiction Treatment and Transfer Center
New York State Psychiatric Institute
Department of Psychiatry
Columbia University Medical Center
New York, NY

Larissa Mooney, M.D.
Director
University of California, Los Angeles
Addiction Psychiatry Division
Associate Professor of Psychiatry
University of California Los Angeles
Los Angeles, CA

Diana Padilla, RCR, CASAC-T
Research Project Manager
Northeast Caribbean Addiction Treatment and Transfer Center
Division on Substance Use Disorders, New York State Psychiatric Institute
Department of Psychiatry
Columbia University Medical Center
New York, NY

Jacynth (Jass) Pelland, M.S.W., LCSW, ACSW, LCADC, CJC
Program Coordinator
Intensive Recovery Treatment Support (IRTS)
Rutgers University Behavioral Health Center—Community Based Services
Rutgers School of Public Health
Piscataway, NJ

Saverio (Sam) Pirozzi, Ed.D., Ed.S., LMFT, LCADC, LPC
Private Practitioner & Consultant/Trainer
Stanhope, NJ, and Myrtle Beach, SC

John M. Roll, Ph.D.
Professor and Vice Dean of Research
Elson S. Floyd College of Medicine and College of Nursing
Washington State University
Spokane, WA

Kenneth Andrew Saffier, M.D.
President
Medical Education & Research Foundation for the Treatment of Addiction
Medical Director
National Coalition Against Prescription Drug Abuse
Medical Director
Bi-Bett, Inc.
Independent contractor/consultant
UCLA Integrated Substance Abuse Programs
University of California Los Angeles
Los Angeles, CA

Lisa L. Weyandt, Ph.D.
Licensed Psychologist
Director, Interdisciplinary Neuroscience Program
Professor, Department of Psychology
University of Rhode Island
Kingston, RI

## Resource Panel

Patrick Carpenter
Policy Analyst
Executive Office of the President
Office of National Drug Control Policy
Washington, DC

Johanna Clevenger, M.D.
Chief
Alcoholism and Substance Abuse Program Branch
Indian Health Service
Rockville, MD

Peter J. Cohen, M.D., J.D.
Special Expert
Medications Development Division
National Institute on Drug Abuse
National Institutes of Health
Bethesda, MD

Jerome Jaffe, M.D.
Director
Office of Evaluation, Scientific Analysis and Synthesis
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, MD

George Kanuck
Office of Policy Coordination and Planning
Center for Substance Abuse Treatment
Substance Abuse and Mental Health Services Administration
Rockville, MD

Kate Malliarakis, CNP, M.S.M., NCADC II
Executive Office of the President
Office for Demand Reduction
Office of National Drug Control Policy
Washington, DC

Eleanor Sargent, CAC, NCAC, M.A.
Director
Clinical Issues
NAADAC, The Association for Addiction Professionals
Arlington, VA

## Editorial Advisory Board

Karen Allen, Ph.D., RN, CARN
Professor and Chair
Department of Nursing
Andrews University
Berrien Springs, MI

Richard L. Brown, M.D., M.P.H.
Associate Professor
Department of Family Medicine
University of Wisconsin School of Medicine
Madison, WI

Dorynne Czechowicz, M.D.
Associate Director
Medical/Professional Affairs
Treatment Research Branch
Division of Clinical and Services Research
National Institute on Drug Abuse
National Institutes of Health
Rockville, MD

Linda S. Foley, M.A.
Former Director
Project for Addiction Counselor Training
National Association of State Alcohol and Drug Abuse Directors
Washington, DC

Wayde A. Glover, M.I.S., NCAC II
Director
Commonwealth Addictions Consultants and Trainers
Richmond, VA

Pedro J. Greer, M.D.
Assistant Dean for Homeless Education
University of Miami School of Medicine
Miami, FL

Thomas W. Hester, M.D.
Former State Director
Substance Abuse Services
Division of Mental Health, Mental Retardation and Substance Abuse
Georgia Department of Human Resources
Atlanta, GA

James G. (Gil) Hill, Ph.D.
Director
Office of Substance Abuse
American Psychological Association
Washington, DC

Douglas B. Kamerow, M.D., M.P.H.
Director
Office of the Forum for Quality and Effectiveness in Health Care
Agency for Healthcare Research and Quality
Rockville, MD

Stephen W. Long
Director
Office of Policy Analysis
National Institute on Alcohol Abuse and Alcoholism
National Institutes of Health
Rockville, MD

Richard A. Rawson, Ph.D.
Executive Director
Matrix Center and Matrix Institute on Addiction
Deputy Director
UCLA Addiction Medicine Services
Los Angeles, CA

Ellen A. Renz, Ph.D.
Former Vice President of Clinical Systems
MEDCO Behavioral Care Corporation
Kamuela, HI

Richard K. Ries, M.D.
Director and Associate Professor
Outpatient Mental Health Services and Dual Disorder Programs
Harborview Medical Center
Seattle, WA

Sidney H. Schnoll, M.D., Ph.D.
Chairman
Division of Substance Abuse Medicine
Medical College of Virginia
Richmond, VA